# Methods

## Methods for Developing the RoC Monograph

This RoC monograph on HAAs Found as Water Disinfection By-products evaluates the available, relevant scientific information and assesses its quality, for each individual HAA or for potential evaluation of the HAAs as a chemical class or subclass, applies the RoC listing criteria to the scientific information, and recommends an RoC listing status (see Figure 1). The draft monograph submitted for peer review also included draft profiles containing NTP’s preliminary listing recommendation, a summary of the scientific evidence considered key to reaching that recommendation, and data on properties, use, production, exposure, and federal regulations and guidelines to reduce exposure to haloacetic acids in the public water supply and from other potential exposures. As noted above in the Peer Review section, the draft profiles are not part of the final monograph.

Figure 1

Organization of Information in the RoC Monograph for Haloacetic Acids

BMD = benchmark dose, which is a dose or concentration that produces a predetermined change in response rate of an adverse effect compared to background; HAAs = haloacetic acids; MOAs = modes of action; RoC = Report on Carcinogens; TK = toxicokinetics; TD_50_s = chronic dose rate that would induce tumors in half the animals tested.

### Monograph Contents

The process of applying the RoC listing criteria to the body of evidence includes an assessment of the level of evidence from cancer studies in humans and experimental animals on haloacetic acids. In addition, an assessment is made on the available mechanistic and other relevant data (such as disposition and toxicokinetics), and the final listing recommendations are based on an integration of all the relevant information. A key question is whether the scientific information supports listing haloacetic acids as a class, as subclasses, or as individual haloacetic acids. Read-across principles were used in this assessment based on discussions with information groups. In addition, listing in the RoC requires that a significant number of people residing in the United States are exposed to haloacetic acids and the monograph provides information on the relevant exposure information. This information is captured in different sections of the monograph as outlined below.

- Properties (Section 1)
- Human Exposure (Section 2)
- Disposition and Toxicokinetics (Section 3)
- Studies of Cancer in Experimental Animals (Section 4)
- Human Cancer Studies (Section 5)
- Mechanistic and Other Relevant Data (Section 6)
- Evaluation of HAAs as a Class or Subclass (Section 7)
- Overall Cancer Evaluation and Preliminary Listing Recommendation (Section 8)

The latter sections (Sections 7 and 8) of the monograph are informed by the information and assessments of the data reported in the earlier sections, especially Sections 1, 3, 4, and 6 (see Figure 1). The information must come from publicly available sources. The appendices in the RoC monograph contain important supplementary information, including the literature search strategy, disposition data tables, tables with results of animal studies and/or study quality tables for cancer studies in experimental animals, and results from the mechanism studies (e.g., genotoxicity studies).

### Key Scientific Questions for Each Type of Evidence Stream

The monograph provides information relevant to the following questions for each type of evidence stream or section topic. Only one human cancer study on exposure specific to haloacetic acids was identified. The study was summarized and reviewed; however, the data were inadequate to conduct a formal assessment.

#### Questions Related to the Evaluation of Properties and Human Exposure Information

- What are the physicochemical properties of HAAs and how do they differ with number and type of halogen substitutions?
- Are a significant number of people residing in the United States exposed to haloacetic acids found in disinfected drinking water?
- In what ways can the population be exposed to HAAs?
- What are the levels of HAAs in drinking water and what federal regulations and guidelines limit exposures?
- How is exposure controlled; what remediation methods are used or proposed?

#### Questions Related to the Evaluation of Disposition and Toxicokinetics

- How are HAAs absorbed, distributed, metabolized, and excreted (ADME)?
- What are the primary metabolites? What is their relative distribution in blood and/or urine? What parent compounds or metabolites may have a role in carcinogenesis?
- What are the differences/similarities between humans and experimental animals for ADME?
- Can existing data on ADME or toxicokinetics inform the potential outcomes for HAAs with insufficient data? For example, can information on chlorinated and brominated HAAs be used to predict outcomes for iodinated species?

#### Questions Related to the Evaluation of Cancer Studies in Experimental Animals

- What is the level of evidence (sufficient or not sufficient) of carcinogenicity of HAAs from animal studies?
- What are the methodological strengths and limitations of the studies?
- What are the tissue sites and are there any trends in tissue sites with number or type of halogen substitutions?

#### Questions Related to the Evaluation of Mechanistic Data and Other Relevant Data

- What are the genotoxic effects due to exposure to HAAs? Does genotoxicity vary by individual HAA or by number or type of halogen substitutions? Do findings from in vitro studies correlate with those from in vivo studies?
- What are the cytotoxic or toxic effects of individual HAA exposure? Does cytotoxicity or toxicity vary by HAA, such as, by type or number of halogen substitutions?
- What are the major mechanistic modes of action for the carcinogenicity of HAAs?
- What are the common key steps or potential molecular initiating events of toxicity or carcinogenicity across different HAAs?
- What factors influence biological or carcinogenic effects?

#### Questions Related to Evaluation of HAAs as a Class

- Is there evidence that supports grouping HAAs as a class or as a subclass in the assessment?

## Methods for Preparing the Monograph

The methods for preparing the RoC monograph on HAAs are described in the “Haloacetic acids: RoC Protocol (https://ntp.niehs.nih.gov/go/790113),” (available at https://ntp.niehs.nih.gov/go/790113) which incorporated a systematic review approach for identification and selection of the literature (see Appendix A), using inclusion/exclusion criteria, extraction of data and evaluation of study quality using specific guidelines, and assessment of the level of evidence for carcinogenicity using established criteria. Links are provided within the document to the appendices, and specific tables or sections can be selected from the table of contents.

General procedures: (See the RoC Protocol (https://ntp.niehs.nih.gov/go/790113) for a detailed description of methods).

Selection of the literature: The preparation of this RoC monograph on HAAs began with development of a literature search strategy to obtain information relevant to the topics listed above for Sections 1 through 7 using search terms outlined in the Protocol. The 6,630^1^ citations identified from these searches were uploaded to web-based systematic review software for evaluation by two separate reviewers using inclusion/exclusion criteria, and 336^2^ references were selected for final inclusion in the monograph using these criteria. Literature searches were updated to May 2017 and additional references recommended by the peer reviewers were added to the final bibliography.

1 ERRATUM: Errors were identified in the Report on Carcinogens Monograph on Haloacetic Acids Found as Water Disinfection By-products. The number of citations was incorrect in the original text. These errors have been corrected; 11,600 was changed to 6,630 and italicized.

2 ERRATUM: Errors were identified in the Report on Carcinogens Monograph on Haloacetic Acids Found as Water Disinfection By-products. The number of references selected for final inclusion was incorrect in the original text. These errors have been corrected; 328 was changed to 336 and italicized.

Data extraction and quality assurance procedures: Information for the relevant cancer and mechanistic sections was systematically extracted in tabular format and/or summarized in the text from studies selected for inclusion in the monograph. All sections of the monograph underwent scientific review and quality assurance (QA, i.e., assuring that all the relevant data and factual information extracted from the publications have been reported accurately) by a separate reviewer. Any discrepancies between the writer and the reviewer were resolved by mutual discussion in reference to the original data source.

Evaluation of cancer studies in experimental animals: Evaluation of the potential for biases as well as other elements were assessed based on a series of a priori considerations (questions and guidelines for answering the questions), which are available in the protocol (available at https://ntp.niehs.nih.gov/go/790113). Two reviewers evaluated the quality of each study. Any disagreements between the two reviewers were resolved by mutual discussion or consultation with a third reviewer in reference to the original data source. The approach for synthesizing the evidence across studies and reaching a level of evidence conclusion is outlined in the protocol. Level of evidence conclusions were made by applying the RoC criteria (see above) to the body of evidence. Because one of the objectives of the monograph was to determine whether haloacetic acids could be evaluated as a class or subclasses, level of evidence conclusions for carcinogenicity (sufficient, not sufficient) were made after the evaluation of the mechanistic data and reported in the overall evaluation.

Evaluation of mechanistic and other relevant data and approaches for evaluating HAAs as a class or subclasses: As mentioned in the protocol, the mechanistic data were organized by characteristics of carcinogens (such as genotoxicity, oxidative stress, altered energy metabolism, and epigenetic alterations) to help inform the relevant modes of action, identify key events or molecular initiation events or adverse pathways. Mechanistic data and toxicokinetic data are discussed across the haloacetic acids to determine if there are any patterns between effects and the number and type of halogen substitutions. This information (e.g., key events and differences in potency for key events and toxicokinetics across haloacetic acids) as well as information on physical properties, and animal carcinogenicity data were used in a read-across-like analysis to determine whether haloacetic acids could be evaluated as a class or subclass (see Figure 1). Details on these methods are reported in Section 7 of this monograph.

Overall evaluation and preliminary listing recommendation: The evidence from the cancer studies in experimental animals was integrated with the assessment of the mechanistic and other relevant data, as well as the conclusions of the assessments of HAAs as a class or subclass (see Figure 1). The RoC listing criteria were then applied to the body of knowledge to reach listing recommendation(s) regarding HAA exposures.

RoC Listing Criteria

#### Known to Be Human Carcinogen

There is sufficient evidence of carcinogenicity from studies in humans*, which indicates a causal relationship between exposure to the agent, substance, or mixture, and human cancer.

#### Reasonably Anticipated to Be Human Carcinogen

There is limited evidence of carcinogenicity from studies in humans*, which indicates that causal interpretation is credible, but that alternative explanations, such as chance, bias, or confounding factors, could not adequately be excluded, OR

there is sufficient evidence of carcinogenicity from studies in experimental animals, which indicates there is an increased incidence of malignant and/or a combination of malignant and benign tumors (1) in multiple species or at multiple tissue sites, or (2) by multiple routes of exposure, or (3) to an unusual degree with regard to incidence, site, or type of tumor, or age at onset, OR

there is less than sufficient evidence of carcinogenicity in humans or laboratory animals; however, the agent, substance, or mixture belongs to a well-defined, structurally related class of substances whose members are listed in a previous Report on Carcinogens as either known to be a human carcinogen or reasonably anticipated to be a human carcinogen, or there is convincing relevant information that the agent acts through mechanisms indicating it would likely cause cancer in humans.

Conclusions regarding carcinogenicity in humans or experimental animals are based on scientific judgment, with consideration given to all relevant information. Relevant information includes, but is not limited to, dose response, route of exposure, chemical structure, metabolism, pharmacokinetics, sensitive sub-populations, genetic effects, or other data relating to mechanism of action or factors that may be unique to a given substance. For example, there may be substances for which there is evidence of carcinogenicity in laboratory animals, but there are compelling data indicating that the agent acts through mechanisms which do not operate in humans and would therefore not reasonably be anticipated to cause cancer in humans.

*This evidence can include traditional cancer epidemiology studies, data from clinical studies, and/or data derived from the study of tissues or cells from humans exposed to the substance in question that can be useful for evaluating whether a relevant cancer mechanism is operating in people.