# Glossary

Abscission: A process by which flowers, fruit, or leaves naturally separate from the plant at a special separation layer.
Alkylating potential: The likelihood that a hydrogen will be replace by an alkyl group, especially in a biologically important molecule.
Ames assay: The Ames Salmonella/microsome mutagenicity assay is a short-term bacterial reverse mutation assay specifically designed to detect a wide range of chemical substances that can produce genetic damage that leads to gene mutations.
Amniotic fluid: The protective fluid surrounding the developing fetus within the amniotic sac of a pregnant female.
Aneuploidy: An abnormality involving a chromosome number that is not an exact multiple of the haploid number (one chromosome set is incomplete).
Apoptosis: Cell deletion by fragmentation into membrane-bound particles, which are phagocytosed by other cells.
Apurinic site: A location in DNA (also in RNA but much less likely) that has neither a purine nor a pyrimidine base, either spontaneously or due to DNA damage.
Arabinose resistance: The L-arabinose resistance test with Salmonella typhimurium (Ara test) is a forward mutation assay that selects a single phenotypic change (from L-arabinose sensitivity to L-arabinose resistance) in a unique tester strain (an araD mutant).
ARE-bla: Activation of oxidative stress response pathway in human hepatocellular carcinoma HepG2 cell line.
AREc32: Activation of Nrf2-ARE oxidative stress response pathway in a human breast cancer cell line MCF7.
Aroclor 1254-induced liver: Liver tissue treated with the polychlorinated biphenyl mixture Aroclor 1254 used as a source of S9 fraction for mutagenic and genotoxic effects testing.
Atomic size: The size of an atom measured as the atomic radius or the mean distance from the center of the nucleus to the outer boundary of the electron cloud.
Attrition bias: Systematic differences between comparison groups in withdrawals or exclusions of participants from the results of a study.
Basal-cell adenoma: A benign tumor of major or minor salivary glands or other organs composed of small cells showing peripheral palisading.
Basal-cell carcinoma: The most common type of skin cancer. It begins in the lowest layer of the epidermis (the outer layer of the skin), called the basal cell layer. It usually develops on sun-exposed areas, especially the head and neck. Basal cell cancer grows slowly and is not likely to spread to distant parts of the body.
Biexponential process: A process of drug (or xenobiotic) clearance with two phases with different rates. The first phase often involves rapid distribution of a drug to peripheral tissues, while the second phase represents clearance mechanisms that eliminate the drug from the body. (See “Two-compartment pharmacokinetic model.”)
Bioavailability: The degree to which a drug or other substance becomes available to the target tissue after administration.
Biodegradation: Biotransformation; the conversion within an organism of molecules from one form to another. A change often associated with change in pharmacologic activity.
Biotransformation: The chemical conversion of substances by living organisms or enzyme preparations.
Boiling point: The boiling point of the anhydrous substance at atmospheric pressure (101.3 kPa) unless a different pressure is stated. If the substance decomposes below or at the boiling point, this is noted (dec). The temperature is rounded off to the nearest °C.
Bond dissociation energy: The amount of energy needed to cause homolytic cleavage of a covalent bond. It is one of numerous measures of bond strength.
Carbon nanotubes: A tube-shaped material, made of carbon, having a diameter measuring on the nanometer scale. A nanometer is one-billionth of a meter.
Carcinoma: Cancer that begins in the skin or in tissues that line or cover internal organs.
Cell cycle arrest: A regulatory process that halts progression through the cell cycle during one of the normal phases (G1, S, G2, M).
Chemical Data Reporting Rule: Chemical Data Reporting (CDR) is the new name for Inventory Update Reporting (IUR). The purpose of Chemical Data Reporting is to collect quality screening-level, exposure-related information on chemical substances and to make that information available for use by the U.S. Environmental Protection Agency (EPA) and, to the extent possible, to the public. The IUR/CDR data are used to support risk screening, assessment, priority setting and management activities and constitute the most comprehensive source of basic screening-level, exposure-related information on chemicals available to EPA. The required frequency of reporting currently is once every four years.
Coagulation and flocculation: Addition of chemicals to source water to allow particles to bind together and form larger particles called floc.
Cochran-Armitage trend test: A statistical test used in categorical data analysis when the aim is to assess for the presence of an association between a variable with two categories and a variable with k categories. It modifies the chi-square test to incorporate a suspected ordering in the effects of the k categories of the second variable.
Comet assay: Single cell gel electrophoresis for assessment of DNA damage in presumptive target tissues.
Congenital lactic acidosis: A rare disease caused by mutations in mitochondrial DNA (mtDNA) that affect the ability of cells to use energy and cause too much lactic acid to build up in the body, a condition called lactic acidosis. The word “congenital” means that the underlying condition that increases risk of developing lactic acidosis is present at birth.
Connexin proteins: A group of transmembrane proteins that form the intermembrane channels of gap junctions. They are used by inorganic ions and most small organic molecules to pass through cell interiors.
Conversion factor: A numerical factor used to multiply or divide a quantity when converting from one system of units to another.
CpG island: A short region of DNA in which the frequency of the CG sequence is higher than in other regions. “p” indicates that “C” and “G” are connected by a phosphodiester bond.
Critical temperature: The temperature at and above which a gas cannot be liquefied, no matter how much pressure is applied.
Delocalization of electron cloud: The spatial distribution of electrons shared among the atoms in a molecule.
Differential selection: Selective pressure for self renewal. Gene mutations that confer a growth or survival advantage on the cells that express them will be selectively enriched in the genome of tumors.
Dihaloacetic acids: Carboxylic acids in which two halogen atom takes the place of two hydrogen atoms in acetic acid.
Disinfection: Application of oxidants to water (chlorine, chloramine, chlorine dioxide, or ozone) or ultraviolet (UV) light to kill disease-causing microorganisms or to render them inactive.
Disposition: The description of absorption, distribution, metabolism, and excretion of a chemical in the body.
Dominant lethal mutation assay: The dominant lethal assay identifies germ cell mutagens by measuring the ability of a chemical to penetrate gonadal tissue and produce embryonic death due to chromosomal breakage in parent germ cells.
Double acid conjugate: A compound formed by the joining of two acids.
Ecological study: A study in which the units of analysis are populations or groups of people rather than individuals.
Electronegativity: A measure of the tendency of an atom to attract a bonding pair of electrons.
Electrophilic reactivity: The tendency of a charge or neutral molecule to be attracted to an electron rich center.
Electrophilic substitution reaction: A substitution reaction in which the new group introduced into the molecule was an electrophile.
Epigenetic mechanisms: Changes in gene function that do not involve a change in DNA sequence but are nevertheless mitotically and/or meiotically heritable. Examples include DNA methylation, alternative splicing of gene transcripts, and assembly of immunoglobulin genes in cells of the immune system.
FDA Good Laboratory Practice Regulations: A quality system codified by the U.S. Food and Drug Administration that prescribes operating procedures for conducting nonclinical laboratory studies that support or are intended to support applications for research or marketing permits for products regulated by the Food and Drug Administration.
Filtration: Passage of water through porous media to remove particles remaining from sedimentation.
Fisher’s exact test: The test for association in a two-by-two table that is based on the exact hypergeometric distribution of the frequencies within the table.
Floc: A mass formed in a liquid through precipitation or aggregation of suspended particles.
Follow-up: Observation over a period of time of a person, group, or initially defined population whose appropriate characteristics have been assessed to observe changes in health status or health-related variables.
Fulvic acid: A family of organic acids, natural compounds, components of the humus, which is a fraction of soil organic matter.
Gap junctional cell communication: Intercellular communications through specialized connection between adjacent cells that directly connect the cytoplasm of the two cells, allowing molecules, ions, and electrical impulses to pass through.
Genomic instability: An increased propensity for genomic alterations that often occurs in cancer cells. During the process of cell division (mitosis) the inaccurate duplication of the genome in parent cells or the improper distribution of genomic material between daughter cells can result from genomic instability.
Glioma: A cancer of the brain that begins in glial cells (cells that surround and support nerve cells).
Haloacetic acids: Carboxylic acids in which one or more hydrogen atoms on the alpha carbon of acetic acid is replaced by halogen atoms. Haloacetic acids are commonly formed as disinfection by-products during water purification with chlorine-based disinfectants.
Halogen: One of a class of reactive nonmetallic chemical elements that form strongly acidic compounds with hydrogen and simple salts with cationic elements. Members of the class of halogens in order of increasing atomic weight are fluorine, chlorine, bromine, iodine, and astatine.
Harderian gland: An orbital gland of the majority of land vertebrates.
Hard nucleophile: A molecule that is highly polarized and tend to react with oxygen atoms in DNA or RNA.
Healthy worker hire effect: Initial selection of healthy individuals at time of hire so that their disease risks differ from the disease risks in the source (general) population.
Healthy worker survival effect: A continuing selection process such that those who remain employed tend to be healthier than those who leave employment.
Hemangiosarcoma: A type of cancer that begins in the cells that line blood vessels.
Henry’s Law constant: The ratio of the aqueous-phase concentration of a chemical to its equilibrium partial pressure in the gas phase. The larger the Henry’s law constant the less soluble it is (i.e., greater tendency for vapor phase). The relationship is defined for a constant temperature, e.g., 25°C.
Hepatoblastoma: An uncommon malignant liver cancer composed of tissue resembling fetal liver cells, mature liver cells, or bile duct cells.
Hepatocellular adenoma: A benign tumor that starts from hepatocytes, i.e., liver cells.
Hepatocellular carcinoma: A malignant tumor that starts from hepatocytes, i.e., liver cells.
Hepatoma: A liver tumor.
Hereditary tyrosinemia type 1: A metabolic disease caused by a deficiency of the enzyme involved in the last step of tyrosine catabolism.
Historical control range: Tumor rates found in control animals, usually those of the same species and strain as the test animals and exposed by the same route of administration.
Host-mediated assay: This assay evaluates the genotoxicity of a substance to microbial cells introduced (e.g., by intravenous injection) into a host animal. The host animal receives the test compound orally, and therefore acts as a source of chemical metabolism, distribution and excretion of the test compound.
Humic acid: A brown, melanin-tinted mixture of polymers, found in soils and water and resulting from breakdown of organic matter.
Immersion cleaning: A process in which a tank containing cleaning solvent at a temperature below its boiling point is used for metal parts cleaning. To use the vapor degreaser, the operator places the parts to be cleaned in a metal wire basket, removes the cover, and lowers the basket of parts by hand into the cleaning solvent. After a brief period of time, the operator raises the basket and allows the parts to drip-dry inside the degreaser.
Ionizability: The ability of an atom or molecule to lose or gain an electron, just becoming either positively or negatively charged.
Keratoacanthoma: A low-grade, or slow-growing, benign skin tumor that looks like a tiny dome or crater.
Keratosis: A localized horny overgrowth of the skin, such as a wart or callus.
Leaving group: A fragment that leaves a molecule as either an anion or neutral molecule.
Loss of heterozygosity: If there is one normal and one abnormal allele at a particular locus, as might be seen in an inherited autosomal dominant cancer susceptibility disorder, loss of the normal allele produces a locus with no normal function. When the loss of heterozygosity involves the normal allele, it creates a cell that is more likely to show malignant growth if the altered gene is a tumor suppressor gene.
Lung adenoma: A benign tumor of the lung.
Lymphoma: Cancer of the lymph nodes.
Lymphokine-activated killer cell: Killer cell lymphocytes activated in the presence of interleukin-2 (IL-2). Lymphokine-activated killer cells (LAKs) are cytotoxic effector cells with an exceptionally wide target cell spectrum including normal and malignant cells of different origins. LAKs exhibit a profound heterogeneity with regard to phenotype surface marker expression; it remains to be determined if they represent a unique cell lineage.
Malignant mesothelioma: A rare, aggressive form of cancer that develops in the lining of the lungs, abdomen, or heart.
Melting point: The melting point of the substance at atmospheric pressure (101.3 kPa). When there is a significant difference between the melting point and the freezing point, a range is given. In case of hydrated substances (i.e., those with crystal water), the apparent melting point is given. If the substance decomposes at or below its melting point, this is noted (dec). The temperature is rounded off to the nearest °C.
Metabolic activation: The chemical alteration of an exogenous substance by or in a biological system. The alteration may inactivate the compound or it may result in the production of an active metabolite of an inactive parent compound.
Metaplasia: A change of cells to a form that does not normally occur in the tissue in which it is found.
Methemoglobin: A form of hemoglobin found in the blood in small amounts. Unlike normal hemoglobin, methemoglobin cannot carry oxygen. Injury or certain drugs, chemicals, or foods may cause a higher-than-normal amount of methemoglobin to be made. This causes a condition called methemoglobinemia.
Micronuclei: Small nuclei separate from, and additional to, the main nucleus of a cell, produced during the telophase of mitosis or meiosis by lagging chromosomes or chromosome fragments derived from spontaneous or experimentally induced chromosomal structural changes.
Miscible: A physical characteristic of a liquid that forms one liquid phase with another liquid (e.g., water) when they are mixed in any proportion.
Molecular chaperone: Any of a diverse group of proteins that oversee the correct intracellular folding and assembly of polypeptides without being components of the final structure.
Molecular weight: The molecular weight of a substance is the weight in atomic mass units of all the atoms in a given formula. The value is rounded to the nearest tenth.
Monohaloacetic acids: Haloacetic acids containing only one halogen on the alpha carbon of acetic acid; one of fluoracetic acid, chloroacetic acid, bromoacetic acid, or iodoacetic acid.
Mononuclear-cell leukemia: The most common type of leukemia in rats, also known as large cell granular lymphocyte leukemia (LGL) .
Morphologically transformed foci: Groups of cells transformed so they lose contact inhibition for their group and multiply to forms foci.
Multiple myeloma: A type of cancer that begins in plasma cells (white blood cells that produce antibodies). Also called Kahler disease, myelomatosis, and plasma cell myeloma.
Mutations: A change in the structure of a gene, resulting from the alteration of single base units in DNA, or the deletion, insertion, or rearrangement of larger sections of genes or chromosomes. The genetic variant can be transmitted to subsequent generations.
National Health and Nutrition Examination Survey: A program of studies designed to assess the health and nutritional status of adults and children in the United States. The survey is unique in that it combines interviews and physical examinations.
Natural killer cells: A type of white blood cell that contains granules with enzymes that can kill tumor cells or microbial cells. Also called large granular lymphocytes.
NF-_K_B activation: Activation of a protein complex (nuclear factor kappa-light-chain-enhancer of activated B cells) that controls transcription of DNA, cytokine production and cell survival.
Non-differential misclassification: The probability of erroneous classification of an individual, a value, or an attribute into a category other than that to which it should be assigned is the same in all study groups.
Non-Hodgkin lymphoma: A heterogeneous group of malignant lymphomas; the only common feature being an absence of the giant Reed-Sternberg cells characteristic of Hodgkin disease.
Normochromatic erythrocyte: A mature erythrocyte that lacks ribosomes and can be distinguished from immature, polychromatic erythrocytes by stains selective for RNA.
Nrf2: A protein that controls how certain genes are expressed. These genes help protect the cell from damage caused by free radicals (unstable molecules made during normal cell metabolism). Also called NFE2L2 and nuclear factor (erythroid-derived 2)-like 2.
Octanol/water partition coefficient (log Kow): A measure of the equilibrium concentration of a compound between octanol and water.
One-compartment model: A pharmacokinetic modeling approach that models the entire body as a single compartment into which a drug is added by a rapid single dose, or bolus. It is assumed that the drug concentration is uniform in the body compartment at all times and is eliminated by a first order process that is described by a first order rate constant.
Ozone-depleting substance: A family of man-made compounds that includes, but are not, foot and eye protection, protective hearing devices (earplugs, muffs) hard hats, respirators and full body suits.
Phase I metabolism: Metabolism of drugs or other xenobiotic molecules, usually by oxidation or hydrolysis and involving a cytochrome P450 monooxygenase.
Phase II metabolism: A conjugation reaction that forms a covalent linkage between a functional group on a xenobiotic molecule and glucuronic acid, sulfate, glutathione, amino acid, or acetate.
p53 haploinsufficient mice: Mice in which one copy of the p53 gene has been lost.
Papilloma: A small solid benign tumor with a clear-cut border that projects above the surrounding tissue.
Personal breathing zone: A sampling area as close as practical to an employee’s nose and mouth, (i.e., in a hemisphere forward of the shoulders within a radius of approximately nine inches) so that it does not interfere with work performance or safety of the employee.
Peroxisome proliferation: The process by which multifunctional cellular organelles increase in number within the cell.
Personal protective equipment: Specialized clothing or equipment, worn by an employee to minimize exposure to a variety of hazards. Examples of PPE include such items as gloves
Physiological pH: The normal pH of blood; it is generally considered to be 7.4.
Placental barrier: The semipermeable layer of tissue in the placenta that serves as a selective membrane to substances passing from maternal to fetal blood.
Plaque assay: An assay for antibody production by single lymphocytes using cells isolated from the spleen or lymph nodes of animals injected with sheep red blood cells as an antigen. Incubation of the antibody-forming cells together with sheep red cells in an agar layer with exposure to guinea pig serum as complement results in formation of microscopic plaques (i.e., circular areas of hemolytic clearance around a lymphoid cell) due to release of hemolysin.
Plate incorporation: A commonly used procedure for performing a bacterial reverse mutation test. Suspensions of bacterial cells are exposed to the test substance in the presence and in the absence of an exogenous metabolic activation system. In the plate-incorporation method, these suspensions are mixed with an overlay agar and plated immediately onto minimal medium. After two or three days of incubation, revertant colonies are counted and compared with the number of spontaneous revertant colonies on solvent control plates.
Point emission: A release that can be identified with a single discharge source or attributed to a specific physical location.
Poly-3 trend test: A survival-adjusted statistical test that takes survival differences into account by modifying the denominator in the numerical (quantal) estimate of lesion incidence to reflect more closely the total number of animal years at risk.
Poly-3 trend test: A survival-adjusted statistical test that takes survival differences into account by modifying the denominator in the numerical (quantal) estimate of lesion incidence to reflect more closely the total number of animal years at risk.
Polychromatic erythrocyte: A newly formed erythrocyte (reticulocyte) containing RNA.
Polyethylene terephthalate: A synthetic resin made by copolymerizing ethylene glycol and terephthalic acid, widely used to make polyester fibers.
Prophage lambda (λ): A virus in Escherichia coli (E. coli) bacteria that has integrated itself into the host E. coli DNA.
Proto-oncogene: A gene involved in normal cell growth. Mutations (changes) in a proto-oncogene may cause it to become an oncogene, which can cause the growth of cancer cells.
P_trend_: Level of statistical significance of a change over time in a group selected to represent a larger population.
Renal clearance: A pharmacokinetic measurement of the volume of plasma from which a substance is completely removed per unit time.
Reverse osmosis: A process of water purification in which water passes through a porous membrane by application of hydrostatic pressure greater than the osmotic pressure removing ions, molecules, and larger particles from drinking water.
Sarcoma: A malignant tumor of connective or other nonepithelial tissue.
Saturable asymmetric transport: A process by which a molecule is carried across a cell membrane or cell barrier in one direction by a process that can be saturated at high concentrations.
Sebaceous gland adenoma: A benign epithelial neoplasm composed of sebaceous gland–like structures or tumors with well-recognized sebaceous differentiation by microscopic examination.
Sedimentation: Transfer of floc particles to basins where they either settle to the bottom or are removed by skimming.
Selection bias: An error in choosing the individuals or groups to take part in a study. Ideally, the subjects in a study should be very similar to one another and to the larger population from which they are drawn (for example, all individuals with the same disease or condition). If there are important differences, the results of the study may not be valid.
Sister-chromatid exchange: The exchange during mitosis of homologous genetic material between sister chromatids; increased as a result of inordinate chromosomal fragility due to genetic or environmental factors.
SKF-525A: An inhibitor of drug metabolism and cytochrome P-450 activity.
Soft nucleophile: A molecule with lower polarization that tends to bind with thiol or amino groups on proteins.
Soft tissue sarcoma: A cancer that begins in the muscle, fat, fibrous tissue, blood vessels, or other supporting tissue of the body.
Solubility: The ability of a substance to dissolve in another substance and form a solution. The Report on Carcinogens uses the following definitions (and concentration ranges) for degrees of solubility: (1) miscible (see definition), (2) freely soluble- capable of being dissolved in a specified solvent to a high degree (>1,000 g/L), (3) soluble- capable of being dissolved in a specified solvent (10–1,000 g/L), (4) slightly soluble- capable of being dissolved in a specified solvent to a limited degree (1-10 g/L), and (5) practically insoluble- incapable of dissolving to any significant extent in a specified solvent (<1 g/L).
SOS umuC assay: An assay using Salmonella typhimurium TA1535/pSK1002 that is used to evaluate the ability of testing substance or sample to induce DNA damage. The system is based on alterations in the induction of SOS response as a consequence of DNA damage.
Specific gravity: The ratio of the density of a material to the density of a standard material, such as water at a specific temperature; when two temperatures are specified, the first is the temperature of the material and the second is the temperature of water.
Spot test: Qualitative assay in which a small amount of test chemical is added directly to a selective agar medium plate seeded with the test organism, e.g., Salmonella. As the chemical diffuses into the agar, a concentration gradient is formed. A mutagenic chemical will give rise to a ring of revertant colonies surrounding the area where the chemical was applied; if the chemical is toxic, a zone of growth inhibition will also be observed.
Squamous-cell carcinoma: A type of malignant skin cancer that begins in the squamous cells. Squamous cells are the thin, flat cells that make up the epidermis, or the outermost layer of the skin.
Squamous-cell papilloma: A generally benign papilloma that arises from the stratified squamous epithelium of the skin, lip, oral cavity, tongue, pharynx, larynx, esophagus, cervix, vagina or anal canal. Squamous cell papillomas are a result of infection with human papillomavirus (HPV).
Steric bulk: An indicator of the stability of the spatial arrangement of atoms in a molecule.
T-helper cell: A type of immune cell that stimulates killer T cells, macrophages, and B cells to make immune responses. A helper T cell is a type of white blood cell and a type of lymphocyte. Also called CD4-positive T lymphocyte.
Tg.AC: A transgenic mouse model with the ability to mount a tumorigenic response within 6 months in skin paint assays when dosed topically with nonmutagenic carcinogens.
Time-weighted average: The average exposure concentration of a chemical measured over a period of time (not an instantaneous concentration).
Tissue:blood partition coefficient: The ratio of tissue chemical concentration to that of the venous outflow of the tissue when at equilibrium; it is an important parameter required for physiological based pharmacokinetic models.
Toxicokinetics: The mathematical description (toxicokinetic models) of the time course of disposition of a chemical in the body.
Transitions: DNA nucleotide substitution mutation in which a purine base is substituted for another purine base (adenine → guanine or guanine → adenine) or a pyrimidine base for another pyrimidine base (cytosine → thymine or thymine → cytosine).
Transversions: DNA nucleotide substitution mutation in which a purine base (adenine or guanine) is substituted for a pyrimidine base (cytosine or thymine) or vice versa.
TR_DNA_: Toxic ratio of EC_50_ of E. coli DNA repair +/DNA repair ⎼, TR >1.2 indicates reaction with hard nucleophiles.
TR_GSH_: Toxic ratio of EC_50_ of E. coli GSH+/GSH⎼, TR >1.2 indicates reaction with soft nucleophiles.
Trihaloacetic acids: Molecules in which all three hydrogens on the alpha carbon of acetic acid have been replaced by halogen atoms of either the same halogen or mixed halogens.
Trihalomethanes: Compounds in which three halogen atoms replace hydrogen atoms in a molecule of methane.
Tubular reabsorption: The process by which the nephron removes water and solutes from the tubular fluid (pre-urine) and returns them to the circulating blood.
Tubular secretion: The transfer of materials from peritubular capillaries to the renal tubular lumen; it is the opposite process of reabsorption. This secretion is caused mainly by active transport and passive diffusion.
Two-compartment pharmacokinetic model: A two-compartment pharmacokinetic model resolves the body into a central compartment and a peripheral compartment. The central compartment generally comprises tissues that are highly perfused such as heart, lungs, kidneys, liver and brain. The peripheral compartment comprises less well-perfused tissues such as muscle, fat and skin. A two-compartment model assumes that, following drug administration into the central compartment, the drug distributes between that compartment and the peripheral compartment. However, the drug does not achieve instantaneous distribution (i.e., equilibrium), between the two compartments. After a time interval (t), distribution equilibrium is achieved between the central and peripheral compartments, and elimination of the drug is assumed to occur from the central compartment.
Type-I error: The error of rejecting a true null hypothesis, i.e., declaring that a difference exists when it does not.
Type-II error: The error of failing to reject a false null hypothesis, i.e., declaring that a difference does not exist when in fact it does.
Vapor density, relative: A value that indicates how many times a gas (or vapor) is heavier than air at the same temperature. If the substance is a liquid or solid, the value applies only to the vapor formed from the boiling liquid.
Vapor pressure: The pressure of the vapor over a liquid (and some solids) at equilibrium, usually expressed as mm Hg at a specific temperature (°C).
Volume of distribution: The theoretical volume that would be necessary to contain the total amount of an administered drug at the same concentration that it is observed in the blood plasma.
Xenobiotic metabolism: A set of metabolic pathways that modify the chemical structure of compounds foreign to an organism's normal biochemistry, such any drug or poison.