# Abbreviations

  ^1^H NMR: proton nuclear magnetic resonance
  8-OHdG: 8-hydroxydeoxyguanosine
  ACGIH: American Conference of Governmental Industrial Hygienists
  ADD: average daily dose
  ADME: absorption, distribution, metabolism, and excretion
  AEG: Acute Exposure Guideline Level
  AhR: aryl hydrocarbon receptor
  ALL: acute lymphocytic leukemia
  ALT: serum alanine aminotransferase, alanine aminotransferase
  ANOVA: analysis of variance
  AOP: adverse outcome pathway
  ARE: antioxidant response element
  ARNT: aryl hydrocarbon nuclear translocator
  AST: serum aspartate aminotransferase, aspartate aminotransferase
  atm: atmosphere
  ATSDR: Agency for Toxic Substances and Disease Registry
  AWWA: American Water Works Association
  BCA: bromochloroacetic acid
  BDCA: bromodichloroacetic acid
  BDL: below detection limit
  BIA: bromoiodoacetic acid
  BMD: benchmark dose
  BMDL: benchmark dose low
  CA: chromosomal aberration
  CASRN: Chemical Abstracts Service registry number
  CDBA: chlorodibromoacetic acid
  CDC: Centers for Disease Control and Prevention
  CDR: Chemical Data Reporting Rule
  CEBS: Chemical Effects in Biological Systems database
  CERHR: Center for the Evaluation of Risks to Human Reproduction
  CHO: Chinese hamster ovary
  CIA: chloroiodoacetic acid
  CIN: chromosomal instability
  cm^2^: centimeters squared
  CO_2_: carbon dioxide
  CT: chlorine concentration (C) times contact time (T)
  Cx: connexin
  Cx32: gap junction beta 1-protein
  connexin32
  DBA: dibromoacetic acid
  DBP: disinfection by-product
  DBPR: Disinfectants and Disinfection By-products Rule
  DCA: dichloroacetic acid
  DIA: diiodoacetic acid
  DLMI: dominant lethal mutation index
  DLMR: dominant lethal mutation rate
  DNA: deoxyribonucleic acid
  dw: drinking water
  EASE: Estimation and Assessment of Substance Exposure
  EC_50_: concentration of a drug that gives a half-maximal response
  E_HOMO_: energy of the highest occupied molecular orbital
  E_LUMO_: energy of the lowest unoccupied molecular orbital
  EPA, USEPA: Environmental Protection Agency, United States Environmental Protection Agency
  EQ: exposure quartiles model
  Erk MAPK: extracellular signal-regulated kinase mitogen activated pathway
  EUSES: European Union System for the Evaluation of Substances
  EWG: Environmental Working Group
  Exp.: exposed
  F: female
  FDA: Food and Drug Administration
  FLARE: fragment length analysis with repair enzyme
  FR: Federal Register
  ft: feet
  FTE: full-time equivalent
  FU: follow-up
  G: guanine
  GAC: Genetic Alterations in Cancer
  GC/MS: gas chromatography/mass spectroscopy
  GFR: glomerular filtration rate
  GI: gastrointestinal
  GIS: Geographic Information System
  GM: geometric mean
  GSH: glutathione
  GSSH: oxidized glutathione
  GST: glutathione S-transferase
  GST- ζ: glutathione S-transferase zeta
  HAA: haloacetic acid
  HAA5: sum of five haloacetic acids (bromoacetic acid, dibromoacetic acid, chloroacetic acid, dichloroacetic acid, and trichloroacetic acid)
  HAA9: sum of nine haloacetic acids (bromoacetic acid, dibromoacetic acid, chloroacetic acid, dichloroacetic acid, and trichloroacetic acid, bromochloroacetic acid, bromodichloroacetic acid, dibromochloroacetic acid, and tribromoacetic acid)
  Hb: hemoglobin
  HBV: Hepatitis B virus
  HCB: hexachlorobenzene
  HCL: hairy-cell leukemia
  HCV: Hepatitis C virus
  HETA: Health Hazard Evaluation and Technical Assistance
  HGPRT: hypoxanthine-guanine phosphoribosyltransferase
  HHE: Health Hazard Evaluation
  HHS: Department of Health and Human Services
  HIC: highest ineffective concentration
  HID: highest ineffective dose
  HIV: Human immunodeficiency virus
  HOBr: hypobromous acid
  HOCl: hypochlorous acid
  HOI: hypoiodous acid
  HPLC: high-performance liquid chromatography
  hr: hour
  HWE: healthy worker (hire or survival) effect
  I: inconclusive
  i.p.: intraperitoneal
  i.v.: intravenous
  IARC: International Agency for Research on Cancer
  ICD-9: International Classification of Diseases, Ninth Revision
  ICD-O-2: International Classification of Diseases for Oncology (revision 2)
  IDLH: immediately dangerous to life and health
  in: inch
  IOM: Institute of Medicine
  IRIS: Integrated Risk Information System
  IUR: Inventory Update Rule
  JEM: job-exposure matrix
  kg: kilogram
  L: liter
  LEC: lowest effective concentration
  LED: lowest effective dose
  LHC: lymphohematopoietic cancer
  LoD: limit of detection
  Log D: logarithm of the n-octanol/buffer solution (pH 7.4 or 4.0) distribution coefficient
  Log K_ow_, logP: logarithm of octanol/water partition coefficient
  LOH: loss of heterozygosity
  M: male
  m^3^: cubic meter
  MAAI: maleylacetoacetate isomerase
  MAPK: mitogen activated protein kinases
  MBA: monobromoacetic acid
  MCA: monochloroacetic acid
  MCL: maximum contaminant level
  MG: methylguanine
  mg: milligram
  MIA: monoiodoacetic acid
  MIE: molecular initiating event
  mL: milliliter
  mL/kg: milliliters per kilogram
  MM: multiple myeloma
  MN: micronuclei
  MOA: mode of action
  mol: mole
  MS: mass spectrometry
  N: number
  NA: not available
  not applicable
  NCE: normochromatic erythrocyte
  NCTR: National Center for Toxicological Research
  ND: not detected
  not determined
  not done
  ng: nanogram
  NHANES: National Health and Nutrition Examination Survey
  NHL: non-Hodgkin lymphoma
  NIEHS: National Institute of Environmental Health Sciences
  NIH3T3: mouse fibroblast cell line
  NIH: National Institutes of Health
  NIOSH: National Institute for Occupational Safety and Health
  NLM: National Library of Medicine
  NOES: National Occupational Exposure Survey
  NOM: natural organic matter
  NOS: not otherwise specified
  NPL: National Priorities List
  NR: not reported, none reported
  Nrf2: nuclear factor (erythroid derived-2)-like 2, nuclear factor E2-related factor 2
  ns: not specified
  NS: not significant
  nt: nucleotides
  NT: not tested
  NTP: National Toxicology Program
  OHAT: Office of Health Assessment and Translation
  OR: odds ratio
  OSHA: Occupational Safety and Health Administration
  OTM: olive tail moment
  pK_a_: acid dissociation constant
  p.o.: per os (oral administration)
  PBZ: personal breathing zone
  PCE: polychromatic erythrocyte
  PCNA: proliferating cell nuclear antigen
  PDH: pyruvate dehydrogenase
  PDK: pyruvate dehydrogenase (PDH) kinase
  PEL: permissible exposure limit
  PGE_2_: prostaglandin E_2_
  PPARα: peroxisome proliferator-activated receptor alpha
  ppm: parts per million
  ppt: parts per trillion
  QSAR: quantitative structure-activity relationship
  R: estimated daily production of adducts
  r: correlation coefficient
  RAHC: Reasonably anticipated to be a human carcinogen
  RBC: red blood cell
  REL: recommended exposure limit
  RLV: Rauscher-leukemia virus
  RoC: Report on Carcinogens
  ROS: reactive oxygen species
  RQ: reportable quantity
  RR: relative risk
  RTG: relative total growth
  s.c.: subcutaneous
  SAFE: significance analysis of function and expression
  SCE: sister-chromatid exchange
  SCGE: single cell gel electrophoresis (Comet assay)
  SD: standard deviation
  SDWA: Safe Drinking Water Act
  SIC: Standard Industrial Classification
  sig: statistically significant
  SIR: standardized incidence ratio
  SMR: standardized mortality ratio
  S_N_2: substitution, nucleophilic, with 2 molecules in the rate-determining step
  SOCMI: synthetic organic chemical manufacturing industry
  SRR: standardized rate ratio, standardized relative risk
  SSB: single strand break
  STS: soft tissue sarcoma
  TBA: tribromoacetic acid
  TBARS: thiobarbituric acid-reactive substances
  TCA: trichloroacetic acid
  TD_50_s: chronic dose rate that would induce tumors in half the animals tested
  TDS: Total Diet Study
  THAAs: total haloacetic acids
  TL: tail length
  TLC: thin-layer chromatography
  TLV-TWA: threshold limit value time-weighted average
  TM: tail moment
  t_max_: time to maximum concentration in plasma
  TMD: tail moment dispersion coefficient
  TRI: Toxics Release Inventory
  TSCA: Toxic Substances Control Act
  TSFE: time since first employment
  TTHMs: total trihalomethanes
  UCMR4: Fourth Unregulated Contaminant Monitoring Rule
  UDS: unscheduled DNA synthesis
  UK: United Kingdom
  V_D_: apparent volume of distribution
  VOC: volatile organic compound
  WBC: white blood cell
  WHO: World Health Organization
  wt%: weight percent
  yr: year or years
  µg: microgram