# References

Aasen T, Mesnil M, Naus CC, Lampe PD, Laird DW. 2016. Gap junctions and cancer: Communicating for 50 years. Nat Rev Cancer. 16(12):775–788. 10.1038/nrc.2016.105 27782134
Abbas R, Fisher JW. 1997. A physiologically based pharmacokinetic model for trichloroethylene and its metabolites, chloral hydrate, trichloroacetate, dichloroacetate, trichloroethanol, and trichloroethanol glucuronide in B6C3F1 mice. Toxicol Appl Pharmacol. 147(1):15–30. 10.1006/taap.1997.8190 9356303
Ali A, Kurzawa-Zegota M, Najafzadeh M, Gopalan RC, Plewa MJ, Anderson D. 2014. Effect of drinking water disinfection by-products in human peripheral blood lymphocytes and sperm. Mutat Res. 770:136–143. 10.1016/j.mrfmmm.2014.08.003 25771880
Allen BC, Fisher JW. 1993. Pharmacokinetic modeling of trichloroethylene and trichloroacetic acid in humans. Risk Anal. 13(1):71–86. 10.1111/j.1539-6924.1993.tb00730.x 8451462
American Chemistry Council.2016. Chlorine and Drinking Water.https://chlorine.americanchemistry.com/DrinkingWaterFAQ/. [accessed: 2/1/16]
Anderson WB, Board PG, Anders MW. 2004. Glutathione transferase zeta-catalyzed bioactivation of dichloroacetic acid: Reaction of glyoxylate with amino acid nucleophiles. Chem Res Toxicol. 17(5):650–662. 10.1021/tx034099 15144222
Anderson WB, Board PG, Gargano B, Anders MW. 1999. Inactivation of glutathione transferase zeta by dichloroacetic acid and other fluorine-lacking α-haloalkanoic acids. Chem Res Toxicol. 12(12):1144–1149. 10.1021/tx990085l 10604862
Anna CH, Maronpot RR, Pereira MA, Foley JF, Malarkey DE, Anderson MW. 1994. Ras protooncogene activation in dichloroacetic acid-induced, trichloroethylene-induced and tetrachloroethylene-induced liver-tumors in B6C3F1 mice. Carcinogenesis. 15(10):2255–2261. 10.1093/carcin/15.10.2255 7955063
Ates N, Kaplan SS, Sahinkaya E, Kitis M, Dilek FB, Yetis U. 2007. Occurrence of disinfection by-products in low DOC surface waters in Turkey. J Hazard Mater. 142(1-2):526–534. 10.1016/j.jhazmat.2006.08.076 17034942
Attene-Ramos MS, Wagner ED, Plewa MJ. 2010. Comparative human cell toxicogenomic analysis of monohaloacetic acid drinking water disinfection byproducts. Environ Sci Technol. 44(19):7206–7212. 10.1021/es1000193 20540539
Austin EW, Bull RJ. 1997. Effect of pretreatment with dichloroacetate or trichloroacetate on the metabolism of bromodichloroacetate. J Toxicol Environ Health. 52(4):367–383. 10.1080/00984109708984071 9354181
Austin EW, Okita JR, Okita RT, Larson JL, Bull RJ. 1995. Modification of lipoperoxidative effects of dichloroacetate and trichloroacetate is associated with peroxisome proliferation. Toxicology. 97(1-3):59–69. 10.1016/0300-483X(94)02926-L 7716793
Austin EW, Parrish JM, Kinder DH, Bull RJ. 1996. Lipid peroxidation and formation of 8-hydroxydeoxyguanosine from acute doses of halogenated acetic acids. Fundam Appl Toxicol. 31(1):77–82. 10.1006/faat.1996.0078 8998956
Bader EL, Hrudey SE, Froese KL. 2004. Urinary excretion half life of trichloroacetic acid as a biomarker of exposure to chlorinated drinking water disinfection by-products. Occup Environ Med. 61(8):715–716. 10.1136/oem.2003.008698 15258281
Barton HA, Bull R, Schultz I, Andersen ME. 1999. Dichloroacetate (DCA) dosimetry: Interpreting DCA-induced liver cancer dose response and the potential for DCA to contribute to trichloroethylene-induced liver cancer. Toxicol Lett. 106(1):9–21. 10.1016/S0378-4274(99)00016-8 10378446
Becalski A, Lau BP, Schrader TJ, Seaman SW, Sun WF. 2006. Formation of iodoacetic acids during cooking: Interaction of iodized table salt with chlorinated drinking water. Food Addit Contam. 23(10):957–962. 10.1080/02652030600838407 16982516
Benane SG, Blackman CF, House DE. 1996. Effect of perchloroethylene and its metabolites on intercellular communication in clone 9 rat liver cells. J Toxicol Environ Health. 48(5):427–428. 10.1080/009841096161168 8751833
Blackburn AC, Coggan M, Tzeng HF, Lantum H, Polekhina G, Parker MW, Anders MW, Board PG. 2001. GSTZ1d: A new allele of glutathione transferase zeta and maleylacetoacetate isomerase. Pharmacogenetics. 11(8):671–678. 10.1097/00008571-200111000-00005 11692075
Blackburn AC, Matthaei KI, Lim C, Taylor MC, Cappello JY, Hayes JD, Anders MW, Board PG. 2006. Deficiency of glutathione transferase zeta causes oxidative stress and activation of antioxidant response pathways. Mol Pharmacol. 69(2):650–657. 10.1124/mol.105.018911 16278372
Blackburn AC, Tzeng HF, Anders MW, Board PG. 2000. Discovery of a functional polymorphism in human glutathione transferase zeta by expressed sequence tag database analysis. Pharmacogenetics. 10(1):49–57. 10.1097/00008571-200002000-00007 10739172
Board PG, Anders MW. 2011. Glutathione transferase zeta: Discovery, polymorphic variants, catalysis, inactivation, and properties of Gstz1-/- mice. Drug Metab Rev. 43(2):215–225. 10.3109/03602532.2010.549132 21303221
Bond T, Goslan EH, Parsons S, Jefferson B.2012. A critical review of trihalomethane and haloacetic acid formation from natural organic matter surrogates. Environ Tech Rev. 1(1):93-113. 10.1080/09593330.2012.705895
Bond T, Goslan EH, Parsons SA, Jefferson B. 2011. Treatment of disinfection by-product precursors. Environ Technol. 32(1):1–25. 10.1080/09593330.2010.495138 21473265
Bruchelt G, Handgretinger R, Weckenmann M, Hahn T. 2014. Glucose metabolism and the antioxidative defense system in cancer cells: Options for the application of ROS-based anticancer drugs. In: Kanner S, editor. Tumor Metabolome Targeting and Drug Development. Totowa, NJ: Humana Press Inc.; p. 109–130. 10.1007/978-1-4614-9545-1_5
Bull R. 1989. Importance of dichloroacetate and trichloroacetate to the hepatocarcinogenic response to trichloroeylene in B6C3F1 mice. Washington, DC: U.S. Air Force. AFOSR-TR (US, Air Force, Off Sci Res). •••:89–1325.
Bull RJ. 2000. Mode of action of liver tumor induction by trichloroethylene and its metabolites, trichloroacetate and dichloroacetate. Environ Health Perspect. 108:241–259. 10.1289/ehp.00108s2241 10807555
Bull RJ, Orner GA, Cheng RS, Stillwell L, Stauber AJ, Sasser LB, Lingohr MK, Thrall BD. 2002. Contribution of dichloroacetate and trichloroacetate to liver tumor induction in mice by trichloroethylene. Toxicol Appl Pharmacol. 182(1):55–65. 10.1006/taap.2002.9427 12127263
Bull RJ, Sanchez IM, Nelson MA, Larson JL, Lansing AJ. 1990. Liver tumor induction in B6C3F1 mice by dichloroacetate and trichloroacetate. Toxicology. 63(3):341–359. 10.1016/0300-483X(90)90195-M 2219130
Cai P, Boor PJ, Khan MF, Kaphalia BS, Ansari GA, Konig R. 2007. Immuno- and hepato-toxicity of dichloroacetic acid in MRL(+/+) and B6C3F1 mice. J Immunotoxicol. 4(2):107–115. 10.1080/15476910701337225 18958719
Calderon RL. 2000. The epidemiology of chemical contaminants of drinking water. Food Chem Toxicol. 38(1) Suppl:S13–S20. 10.1016/S0278-6915(99)00133-7 10717366
Cantor KP, Villanueva CM, Silverman DT, Figueroa JD, Real FX, Garcia-Closas M, Malats N, Chanock S, Yeager M, Tardon A, et al. 2010. Polymorphisms in GSTT1, GSTZ1, and CYP2E1, disinfection by-products, and risk of bladder cancer in Spain. Environ Health Perspect. 118(11):1545–1550. 10.1289/ehp.1002206 20675267
Cardador MJ, Gallego M. 2011. Haloacetic acids in swimming pools: Swimmer and worker exposure. Environ Sci Technol. 45(13):5783–5790. 10.1021/es103959d 21648437
Cardador MJ, Gallego M. 2015. Haloacetic acids content of fruit juices and soft drinks. Food Chem. 173:685–693. 10.1016/j.foodchem.2014.10.105 25466077
Cardador MJ, Gallego M. 2017. Control of disinfection by-products in canned vegetables caused by water used in their processing. Food Addit Contam Part A Chem Anal Control Expo Risk Assess. 34(1):10–23. 10.1080/19440049.2016.1241897 27689419
Carter JH, Carter HW, Deddens JA, Hurst BM, George MH, DeAngelo AB. 2003. A 2-year dose-response study of lesion sequences during hepatocellular carcinogenesis in the male B6C3F(1) mouse given the drinking water chemical dichloroacetic acid. Environ Health Perspect. 111(1):53–64. 10.1289/ehp.5442 12515679
Celik I. 2007. Determination of toxicity of trichloroacetic acid in rats: 50 days drinking water study. Pestic Biochem Physiol. 89(1):39–45.10.1016/j.pestbp.2007.02.006
Celik I, Temur A, Isik I. 2009. Hepatoprotective role and antioxidant capacity of pomegranate (Punica granatum) flowers infusion against trichloroacetic acid-exposed in rats. Food Chem Toxicol. 47(1):145–149. 10.1016/j.fct.2008.10.020 19022327
Cemeli E, Wagner ED, Anderson D, Richardson SD, Plewa MJ. 2006. Modulation of the cytotoxicity and genotoxicity of the drinking water disinfection byproduct iodoacetic acid by suppressors of oxidative stress. Environ Sci Technol. 40(6):1878–1883. 10.1021/es051602r 16570611
Centers for Disease Control and Prevention (CDC).2015. Water Treatment. https://www.cdc.gov/healthywater/drinking/public/water_treatment.html.
Centers for Disease Control and Prevention (CDC).2016. Disinfection By-products. https://www.cdc.gov/safewater/chlorination-byproducts.html.
Chang EE, Guo HC, Li IS, Chiang PC, Huang CP. 2010 a. Modeling the formation and assessing the risk of disinfection by-products in water distribution systems. J Environ Sci Health Part A Tox Hazard Subst Environ Eng. 45(10):1185–1194. 10.1080/10934529.2010.493776 20563912
Chang HH, Tung HH, Chao CC, Wang GS. 2010 b. Occurrence of haloacetic acids (HAAs) and trihalomethanes (THMs) in drinking water of Taiwan. Environ Monit Assess. 162(1-4):237–250. 10.1007/s10661-009-0792-1 19277887
Channel SR, Latendresse JR, Kidney JK, Grabau JH, Lane JW, Steel-Goodwin L, Gothaus MC. 1998. A subchronic exposure to trichloroethylene causes lipid peroxidation and hepatocellular proliferation in male B6C3F1 mouse liver. Toxicol Sci. 43(2):145–154. 10.1093/toxsci/43.2.145 9710956
Chemical Effects in Biological Systems (CEBS).2017. National Toxicology Program. https://manticore.niehs.nih.gov/cebssearch/.
ChemIDplus.2017. ChemIDplus Advanced. National Library of Medicine.https://chem.nlm.nih.gov/chemidplus/chemidheavy.jsp and select Registry Number and search on CAS number. [Accessed: 5/5/17]
Choi SY, Park OJ. 1996. Differential display analysis of gene expression induced under DCA treatment in rat liver. J Biochem Mol Biol. 29(3):272–275.
Chowdhury S, Alhooshani K, Karanfil T. 2014. Disinfection byproducts in swimming pool: Occurrences, implications and future needs. Water Res. 53:68–109. 10.1016/j.watres.2014.01.017 24509344
Colell A, Green DR, Ricci JE. 2009. Novel roles for GAPDH in cell death and carcinogenesis. Cell Death Differ. 16(12):1573–1581. 10.1038/cdd.2009.137 19779498
Cornett R, James MO, Henderson GN, Cheung J, Shroads AL, Stacpoole PW. 1999. Inhibition of glutathione S-transferase zeta and tyrosine metabolism by dichloroacetate: A potential unifying mechanism for its altered biotransformation and toxicity. Biochem Biophys Res Commun. 262(3):752–756. 10.1006/bbrc.1999.1287 10471397
Corton JC. 2008. Evaluation of the role of peroxisome proliferator-activated receptor alpha (PPARalpha) in mouse liver tumor induction by trichloroethylene and metabolites. Crit Rev Toxicol. 38(10):857–875. 10.1080/10408440802209796 18821149
Corvi R, Aardema MJ, Gribaldo L, Hayashi M, Hoffmann S, Schechtman L, Vanparys P. 2012. ECVAM prevalidation study on in vitro cell transformation assays: General outline and conclusions of the study. Mutat Res. 744(1):12–19. 10.1016/j.mrgentox.2011.11.009 22138617
Creton S, Aardema MJ, Carmichael PL, Harvey JS, Martin FL, Newbold RF, O’Donovan MR, Pant K, Poth A, Sakai A, et al. 2012. Cell transformation assays for prediction of carcinogenic potential: State of the science and future research needs. Mutagenesis. 27(1):93–101. 10.1093/mutage/ger053 21852270
Curry SH, Chu PI, Baumgartner TG, Stacpoole PW. 1985. Plasma concentrations and metabolic effects of intravenous sodium dichloroacetate. Clin Pharmacol Ther. 37(1):89–93. 10.1038/clpt.1985.17 3965240
Curry SH, Lorenz A, Chu PI, Limacher M, Stacpoole PW. 1991. Disposition and pharmacodynamics of dichloroacetate (DCA) and oxalate following oral DCA doses. Biopharm Drug Dispos. 12(5):375–390. 10.1002/bdd.2510120507 1878534
Dad A, Jeong CH, Pals JA, Wagner ED, Plewa MJ. 2013. Pyruvate remediation of cell stress and genotoxicity induced by haloacetic acid drinking water disinfection by-products. Environ Mol Mutagen. 54(8):629–637. 10.1002/em.21795 23893730
Daniel FB, DeAngelo AB, Stober JA, Olson GR, Page NP. 1992. Hepatocarcinogenicity of chloral hydrate, 2-chloroacetaldehyde, and dichloroacetic acid in the male B6C3F1 mouse. Fundam Appl Toxicol. 19(2):159–168. 10.1016/0272-0590(92)90147-A 1516771
DeAngelo AB, Daniel FB, McMillan L, Wernsing P, Savage RE Jr. 1989. Species and strain sensitivity to the induction of peroxisome proliferation by chloroacetic acids. Toxicol Appl Pharmacol. 101(2):285–298. 10.1016/0041-008X(89)90277-9 2815084
DeAngelo AB, Daniel FB, Most BM, Olson GR. 1996. The carcinogenicity of dichloroacetic acid in the male Fischer 344 rat. Toxicology. 114(3):207–221. 10.1016/S0300-483X(96)03510-X 8980710
DeAngelo AB, Daniel FB, Most BM, Olson GR. 1997. Failure of monochloroacetic acid and trichloroacetic acid administered in the drinking water to produce liver cancer in male F344/N rats. J Toxicol Environ Health. 52(5):425–445. 10.1080/00984109708984074 9388534
DeAngelo AB, Daniel FB, Stober JA, Olson GR. 1991. The carcinogenicity of dichloroacetic acid in the male B6C3F1 mouse. Fundam Appl Toxicol. 16(2):337–347. 10.1016/0272-0590(91)90118-N 2055364
DeAngelo AB, Daniel FB, Wong DM, George MH. 2008. The induction of hepatocellular neoplasia by trichloroacetic acid administered in the drinking water of the male B6C3F1 mouse. J Toxicol Environ Health A. 71(16):1056–1068. 10.1080/15287390802111952 18569617
DeAngelo AB, George MH, House DE. 1999. Hepatocarcinogenicity in the male B6C3F1 mouse following a lifetime exposure to dichloroacetic acid in the drinking water: Dose-response determination and modes of action. J Toxicol Environ Health A. 58(8):485–507. 10.1080/009841099157115 10632141
Deborde M, von Gunten U. 2008. Reactions of chlorine with inorganic and organic compounds during water treatment-Kinetics and mechanisms: A critical review. Water Res. 42(1-2):13–51. 10.1016/j.watres.2007.07.025 17915284
Dees C, Travis C. 1994. Trichloroacetate stimulation of liver DNA synthesis in male and female mice. Toxicol Lett. 70(3):343–355. 10.1016/0378-4274(94)90129-5 8284802
Dickenson ER, Summers RS, Croué JP, Gallard H. 2008. Haloacetic acid and trihalomethane formation from the chlorination and bromination of aliphatic beta-dicarbonyl acid model compounds. Environ Sci Technol. 42(9):3226–3233. 10.1021/es0711866 18522098
Dmitriev AP, Grodzinsky DM. 1975. Effect of radiosensitizing agents on dna single-strand breaks and their repair in Anacystis nidulans. Plant Sci Lett. 4:77–83.10.1016/0304-4211(75)90251-5
Duirk SE, Lindell C, Cornelison CC, Kormos J, Ternes TA, Attene-Ramos M, Osiol J, Wagner ED, Plewa MJ, Richardson SD. 2011. Formation of toxic iodinated disinfection by-products from compounds used in medical imaging. Environ Sci Technol. 45(16):6845–6854. 10.1021/es200983f 21761849
Eastmond DA, Vulimiri SV, French JE, Sonawane B. 2013. The use of genetically modified mice in cancer risk assessment: Challenges and limitations. Crit Rev Toxicol. 43(8):611–631. 10.3109/10408444.2013.822844 23985072
El Arem A, Ghrairi F, Lahouar L, Thouri A, Saafi EB, Ayed A, Zekri M, Ferjani H, Haouas Z, Zakhama A, et al. 2014 a. Hepatoprotective activity of date fruit extracts against dichloroacetic acid-induced liver damage in rats. J Funct Foods. 9:119–130.10.1016/j.jff.2014.04.018
El Arem A, Saafi EB, Ghrairi F, Thouri A, Zekri M, Ayed A, Zakhama A, Achour L. 2014 b. Aqueous date fruit extract protects against lipid peroxidation and improves antioxidant status in the liver of rats subchronically exposed to trichloroacetic acid. J Physiol Biochem. 70(2):451–464. 10.1007/s13105-014-0323-6 24573459
El Arem A, Zekri M, Thouri A, Saafi EB, Ghrairi F, Ayed A, Zakhama A, Achour L. 2014 c. Oxidative damage and alterations in antioxidant enzyme activities in the kidneys of rat exposed to trichloroacetic acid: Protective role of date palm fruit. J Physiol Biochem. 70(2):297–309. 10.1007/s13105-013-0302-3 24338383
Environmental Working Group (EWG).2016. National Drinking Water Database: Haloacetic acids. Washington, D.C.: Environmental Working Group.https://www.ewg.org/tap-water/chemical-contaminants/Total-haloacetic-acids-HAAs/2456/.
Escobar-Hoyos LF, Hoyos-Giraldo LS, Londoño-Velasco E, Reyes-Carvajal I, Saavedra-Trujillo D, Carvajal-Varona S, Sánchez-Gómez A, Wagner ED, Plewa MJ. 2013. Genotoxic and clastogenic effects of monohaloacetic acid drinking water disinfection by-products in primary human lymphocytes. Water Res. 47(10):3282–3290. 10.1016/j.watres.2013.02.052 23602619
European Chemicals Agency (ECHA).2008. Guidance on information requirements and chemical safety assessment. Chapter R.6: QSARS and grouping of chemicals. European Chemicals Agency.
European Union (EU). 2007. European Union Risk Assessment Report: Sodium hypochlorite. Luxembourg: Office for Official Publications of the European Communities.
Fang C, Zhu H. 2001. [Malignant transformation experiment of NIH3T3 cells induced by dibromoacetic acid in drinking water]. Zhongguo Huanjing Kexue. 21(3):245–247.
Fang YY, Kashkarov U, Anders MW, Board PG. 2006. Polymorphisms in the human glutathione transferase zeta promoter. Pharmacogenet Genomics. 16(5):307–313. 10.1097/01.fpc.0000205000.07054.b3 16609361
Federal Register. 1998. National Primary Drinking Water Regulations: Disinfectants and Disinfection Byproducts. Fed Reg. 63(241):69390-69476.
Federal Register. 2016. Revisions to the Unregulated Contaminant Monitoring Rule (UCMR 4) for Public Water Systems and Announcement of Public Meeting. Fed Reg. 81(244):92666-92692.
Fernández-Cañón JM, Baetscher MW, Finegold M, Burlingame T, Gibson KM, Grompe M. 2002. Maleylacetoacetate isomerase (MAAI/GSTZ)-deficient mice reveal a glutathione-dependent nonenzymatic bypass in tyrosine catabolism. Mol Cell Biol. 22(13):4943–4951. 10.1128/MCB.22.13.4943-4951.2002 12052898
Ferreira-Gonzalez A, DeAngelo AB, Nasim S, Garrett CT. 1995. Ras oncogene activation during hepatocarcinogenesis in B6C3F1 male mice by dichloroacetic and trichloroacetic acids. Carcinogenesis. 16(3):495–500. 10.1093/carcin/16.3.495 7697804
Froese KL, Sinclair MI, Hrudey SE. 2002. Trichloroacetic acid as a biomarker of exposure to disinfection by-products in drinking water: A human exposure trial in Adelaide, Australia. Environ Health Perspect. 110(7):679–687. 10.1289/ehp.02110679 12117645
Fuhrman J, Shafer L, Repertinger S, Chan T, Hansen LA. 2005. Mechanisms of SEPA 0009-induced tumorigenesis in v-rasHa transgenic Tg.AC mice. Toxicol Pathol. 33(6):623–630. 10.1080/01926230500278975 16176921
Gao S, Wang Y, Zhang P, Dong Y, Li B. 2008. Subacute oral exposure to dibromoacetic acid induced immunotoxicity and apoptosis in the spleen and thymus of the mice. Toxicol Sci. 105(2):331–341. 10.1093/toxsci/kfn139 18628252
Gao SY, Zhou XR, Gong TT, Jia LM, Li BX. 2016. Dibromoacetic acid induces thymocyte apoptosis by blocking cell cycle progression, increasing intracellular calcium, and the Fas/FasL pathway in vitro. Toxicol Pathol. 44(1):88–97. 10.1177/0192623315612939 26704929
Ge R, Yang S, Kramer PM, Tao L, Pereira MA. 2001. The effect of dichloroacetic acid and trichloroacetic acid on DNA methylation and cell proliferation in B6C3F1 mice. J Biochem Mol Toxicol. 15(2):100–106. 10.1002/jbt.5 11284051
Ged EC, Boyer TH. 2014. Effect of seawater intrusion on formation of bromine-containing trihalomethanes and haloacetic acids during chlorination. Desalination. 345:85–93.10.1016/j.desal.2014.04.021
Giller S, Le Curieux F, Erb F, Marzin D. 1997. Comparative genotoxicity of halogenated acetic acids found in drinking water. Mutagenesis. 12(5):321–328. 10.1093/mutage/12.5.321 9379909
Gonzalez-Leon A, Merdink JL, Bull RJ, Schultz IR. 1999. Effect of pre-treatment with dichloroacetic or trichloroacetic acid in drinking water on the pharmacokinetics of a subsequent challenge dose in B6C3F1 mice. Chem Biol Interact. 123(3):239–253. 10.1016/S0009-2797(99)00140-4 10654841
Gonzalez-Leon A, Schultz IR, Xu G, Bull RJ. 1997. Pharmacokinetics and metabolism of dichloroacetate in the F344 rat after prior administration in drinking water. Toxicol Appl Pharmacol. 146(2):189–195. 10.1006/taap.1997.8232 9344886
Green T, Prout MS. 1985. Species differences in response to trichloroethylene. II. Biotransformation in rats and mice. Toxicol Appl Pharmacol. 79(3):401–411. 10.1016/0041-008X(85)90138-3 3929429
Gulezian D, Jacobson-Kram D, McCullough CB, Olson H, Recio L, Robinson D, Storer R, Tennant R, Ward JM, Neumann DA. 2000. Use of transgenic animals for carcinogenicity testing: Considerations and implications for risk assessment. Toxicol Pathol. 28(3):482–499. 10.1177/019262330002800320 10862569
Gwynn RH, Salaman MH. 1953. Studies on co-carcinogenesis. SH-reactors and other substances tested for co-carcinogenic action in mouse skin. Br J Cancer. 7(4):482–489. 10.1038/bjc.1953.50 13126392
Hammer R, VanBriesen J. 2012. In fracking’s wake: New rules are needed to protect our health and environment from contaminated wastewater. Natural Resources Defense Council. NRDC Document May 2012 D:12-05-A
Harvey JB, Hong HHL, Bhusari S, Ton TV, Wang Y, Foley JF, Peddada SD, Hooth M, DeVito M, Nyska A, et al. 2016. F344/NTac rats chronically exposed to bromodichloroacetic acid develop mammary adenocarcinomas with mixed luminal/basal phenotype and Tgfβ dysregulation. Vet Pathol. 53(1):170–181. 10.1177/0300985815571680 25732176
Hassoun E, Cearfoss J. 2014. Do antioxidant enzymes and glutathione play roles in the induction of hepatic oxidative stress in mice upon subchronic exposure to mixtures of dichloroacetate and trichloroacetate? Toxicol Environ Chem. 96(3):482–490. 10.1080/02772248.2014.947988 25530655
Hassoun E, Cearfoss J, Mamada S, Al-Hassan N, Brown M, Heimberger K, Liu MC. 2014. The effects of mixtures of dichloroacetate and trichloroacetate on induction of oxidative stress in livers of mice after subchronic exposure. J Toxicol Environ Health A. 77(6):313–323. 10.1080/15287394.2013.864576 24593144
Hassoun E, Mettling C. 2015. Dichloroacetate and trichloroacetate toxicity in AML12 cells: Role of oxidative stress. J Biochem Mol Toxicol. 29(11):508–512. 10.1002/jbt.21720 26121004
Hassoun EA, Cearfoss J. 2011. Dichloroacetate- and trichloroacetate-induced modulation of superoxide dismutase, catalase, and glutathione peroxidase activities and glutathione level in the livers of mice after subacute and subchronic exposure. Toxicol Environ Chem. 93(2):332–344. 10.1080/02772248.2010.509602 21170174
Hassoun EA, Cearfoss J, Spildener J. 2010 a. Dichloroacetate- and trichloroacetate-induced oxidative stress in the hepatic tissues of mice after long-term exposure. J Appl Toxicol. 30(5):450–456. 10.1002/jat.1516 20222146
Hassoun EA, Dey S. 2008. Dichloroacetate- and trichloroacetate-induced phagocytic activation and production of oxidative stress in the hepatic tissues of mice after acute exposure. J Biochem Mol Toxicol. 22(1):27–34. 10.1002/jbt.20210 18273911
Hassoun EA, Ray S. 2003. The induction of oxidative stress and cellular death by the drinking water disinfection by-products, dichloroacetate and trichloroacetate in J774.A1 cells. Comp Biochem Physiol C Toxicol Pharmacol. 135(2):119–128. 10.1016/S1532-0456(03)00082-6 12860050
Hassoun EA, Spildener J, Cearfoss J. 2010 b. The induction of tumor necrosis factor-alpha, superoxide anion, myeloperoxidase, and superoxide dismutase in the peritoneal lavage cells of mice after prolonged exposure to dichloroacetate and trichloroacetate. J Biochem Mol Toxicol. 24(2):136–144. 10.1002/jbt.20322 20391627
Hayes FD, Short RD, Gibson JE. 1973. Differential toxicity of monochloroacetate, monofluoroacetate and monoiodoacetate in rats. Toxicol Appl Pharmacol. 26(1):93–102. 10.1016/0041-008X(73)90089-6 4748142
Hayes JD, Strange RC. 2000. Glutathione S-transferase polymorphisms and their biological consequences. Pharmacology. 61(3):154–166. 10.1159/000028396 10971201
Hazardous Substances Data Bank (HSDB).2003. Iodoacetic acid. National Library of Medicine.http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS number or compound name. [accessed: 6/5/17]
Hazardous Substances Data Bank (HSDB).2009. Bromoacetic acid. National Library of Medicine.http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS number or compound name. [accessed: 6/1/17]
Hazardous Substances Data Bank (HSDB).2009a. Bromochloroacetic acid. National Library of Medicine.http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS number or compound name. [accessed: 12/21/15]
Hazardous Substances Data Bank (HSDB).2009b. Bromodichloroacetic acid. National Library of Medicine.http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS number or compound name. [accessed: 12/21/15]
Hazardous Substances Data Bank (HSDB).2009c. Tribromoacetic acid. National Library of Medicine.http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS number or compound name. [accessed: 6/1/17]
Hazardous Substances Data Bank (HSDB).2009d. Dibromochloroacetic acid. National Library of Medicine.http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS number or compound name. [accessed: 12/21/15]
Henderson GN, Curry SH, Derendorf H, Wright EC, Stacpoole PW. 1997. Pharmacokinetics of dichloroacetate in adult patients with lactic acidosis. J Clin Pharmacol. 37(5):416–425. 10.1002/j.1552-4604.1997.tb04319.x 9156374
Hernández-Fonseca K, Cárdenas-Rodríguez N, Pedraza-Chaverri J, Massieu L. 2008. Calcium-dependent production of reactive oxygen species is involved in neuronal damage induced during glycolysis inhibition in cultured hippocampal neurons. J Neurosci Res. 86(8):1768–1780. 10.1002/jnr.21634 18293416
Herren-Freund SL, Pereira MA, Khoury MD, Olson G. 1987. The carcinogenicity of trichloroethylene and its metabolites, trichloroacetic acid and dichloroacetic acid, in mouse liver. Toxicol Appl Pharmacol. 90(2):183–189. 10.1016/0041-008X(87)90325-5 3629594
Hinckley AF, Bachand AM, Nuckols JR, Reif JS. 2005. Identifying public water facilities with low spatial variability of disinfection by-products for epidemiological investigations. Occup Environ Med. 62(7):494–499. 10.1136/oem.2004.017798 15961627
Hladik ML, Focazio MJ, Engle M. 2014. Discharges of produced waters from oil and gas extraction via wastewater treatment plants are sources of disinfection by-products to receiving streams. Sci Total Environ. 466-467:1085–1093. 10.1016/j.scitotenv.2013.08.008 23994821
Hsu CC, Lee HC, Wei YH. 2013. Mitochondrial DNA alterations and mitochondrial dysfunction in the progression of hepatocellular carcinoma. World J Gastroenterol. 19(47):8880–8886. 10.3748/wjg.v19.i47.8880 24379611
Innes JR, Ulland BM. 1968. Carcinogenic study. Vol. 1. Bethesda, MD: National Cancer Institute. NCI-DCCP-CG; p. 1973–1-1. (Evaluation of carcinogenic, teratogenic, and muragenic activities of selected pesticides and industrial chemicals.).
International Agency for Research on Cancer (IARC). 2004 a. Some Drinking-water Disinfectants and Contaminants, including Arsenic. Lyon, France: International Agency for Research on Cancer; Dichloroacetic acid; p. 359–402.
International Agency for Research on Cancer (IARC). 2004 b. Some Drinking-water Disinfectants and Contaminants, including Arsenic. Lyon, France: International Agency for Research on Cancer; Trichloroacetic acid; p. 403–440.
International Agency for Research on Cancer (IARC). 2013 a. Some Chemicals Present in Industrial and Consumer Products, Food and Drinking-water. Lyon, France: International Agency for Research on Cancer; Dibromoacetic acid; p. 513–531.
International Agency for Research on Cancer (IARC). 2013 b. Some Chemicals Present in Industrial and Consumer Products, Food and Drinking-water. Lyon, France: International Agency for Research on Cancer; Bromochloroacetic acid; p. 495–511.
International Agency for Research on Cancer (IARC). 2013 c. Some chemicals present in industrial and consumer products, food and drinking-water. Lyon, France: International Agency for Research on Cancer.
International Agency for Research on Cancer (IARC). 2014. Trichloroethylene, tetrachloroethylene, and some other chlorinated agents. Lyon, France: International Agency for Research on Cancer.
International Agency for Research on Cancer (IARC). 2014 a. Trichloroethylene, Tetrachloroethylene, and Some Other Chlorinated Agents. Lyon, France: International Agency for Research on Cancer; Dichloroacetic acid; p. 353–391.
International Agency for Research on Cancer (IARC). 2014 b. Trichloroethylene, Tetrachloroethylene, and Some Other Chlorinated Agents. Lyon, France: International Agency for Research on Cancer; Trichloroacetic acid; p. 393–437.
International Programme on Chemical Safety (IPCS). 2000. Disinfectants and disinfectant by-products. Geneva, Switzerland: World Health Organization. Environ Health Criteria. •••:216.
Jacobs AC, Hatfield KP. 2013. History of chronic toxicity and animal carcinogenicity studies for pharmaceuticals. Vet Pathol. 50(2):324–333. 10.1177/0300985812450727 22700852
James MO, Yan Z, Cornett R, Jayanti VM, Henderson GN, Davydova N, Katovich MJ, Pollock B, Stacpoole PW. 1998. Pharmacokinetics and metabolism of [14C]dichloroacetate in male Sprague-Dawley rats. Identification of glycine conjugates, including hippurate, as urinary metabolites of dichloroacetate. Drug Metab Dispos. 26(11):1134–1143. 9806957
Jones RR, Weyer PJ, DellaValle CT, Inoue-Choi M, Anderson KE, Cantor KP, Krasner S, Robien K, Freeman LE, Silverman DT, et al. 2016. Nitrate from drinking water and diet and bladder cancer among postmenopausal women in Iowa. Environ Health Perspect. 124(11):1751–1758. 10.1289/EHP191 27258851
Jones RR, Weyer PJ, Dellavalle CT, Robein K, Cantor KP, Krasner S, Beane Freeman LE, Ward MH. 2017. Ingested nitrate, disinfection by-products, and kidney cancer risk in older women. Epidemiology. 28(5):703–711. 10.1097/EDE.0000000000000647 28252454
Kanan A.2010. Occurrence and formation of disinfection by-products in indoor swimming pools water. A thesis presented to Clemson University.
Kaphalia BS, Bhat HK, Khan MF, Ansari GA. 1992. Tissue distribution of monochloroacetic acid and its binding to albumin in rats. Toxicol Ind Health. 8(1-2):53–61. 10.1177/074823379200800105 1542885
Kargalioglu Y, McMillan BJ, Minear RA, Plewa MJ. 2002. Analysis of the cytotoxicity and mutagenicity of drinking water disinfection by-products in Salmonella typhimurium. Teratog Carcinog Mutagen. 22(2):113–128. 10.1002/tcm.10010 11835289
Kensler TW, Wakabayashi N, Biswal S. 2007. Cell survival responses to environmental stresses via the Keap1-Nrf2-ARE pathway. Annu Rev Pharmacol Toxicol. 47:89–116. 10.1146/annurev.pharmtox.46.120604.141046 16968214
Khanna KK, Jackson SP. 2001. DNA double-strand breaks: Signaling, repair and the cancer connection. Nat Genet. 27(3):247–254. 10.1038/85798 11242102
Kim D, Amy GL, Karanfil T. 2015. Disinfection by-product formation during seawater desalination: A review. Water Res. 81:343–355. 10.1016/j.watres.2015.05.040 26099832
Kim H, Haltmeier P, Klotz JB, Weisel CP. 1999. Evaluation of biomarkers of environmental exposures: Urinary haloacetic acids associated with ingestion of chlorinated drinking water. Environ Res. 80(2):187–195. 10.1006/enrs.1998.3896 10092412
Kim H, Weisel CP. 1998. Dermal absorption of dichloro- and trichloroacetic acids from chlorinated water. J Expo Anal Environ Epidemiol. 8(4):555–575.
Kim J, Kang B. 2008. DBPs removal in GAC filter-adsorber. Water Res. 42(1-2):145–152. 10.1016/j.watres.2007.07.040 17706265
Kim S, Collins LB, Boysen G, Swenberg JA, Gold A, Ball LM, Bradford BU, Rusyn I. 2009. Liquid chromatography electrospray ionization tandem mass spectrometry analysis method for simultaneous detection of trichloroacetic acid, dichloroacetic acid, S-(1,2-dichlorovinyl)glutathione and S-(1,2-dichlorovinyl)-L-cysteine. Toxicology. 262(3):230–238. 10.1016/j.tox.2009.06.013 19549554
Kim Y, Ton TV, DeAngelo AB, Morgan K, Devereux TR, Anna C, Collins JB, Paules RS, Crosby LM, Sills RC. 2006. Major carcinogenic pathways identified by gene expression analysis of peritoneal mesotheliomas following chemical treatment in F344 rats. Toxicol Appl Pharmacol. 214(2):144–151. 10.1016/j.taap.2005.12.009 16460773
King WD, Dodds L, Armson BA, Allen AC, Fell DB, Nimrod C. 2004. Exposure assessment in epidemiologic studies of adverse pregnancy outcomes and disinfection byproducts. J Expo Anal Environ Epidemiol. 14(6):466–472. 10.1038/sj.jea.7500345 15026776
Kissling GE, Malarkey DE, Vallant MK, Johnson JD, Hejtmancik MR, Herbert RA, Boorman GA. 2009. Evaluation of dichloroacetic acid for carcinogenicity in genetically modified Tg.AC hemizygous and p53 haploinsufficient mice. Toxicol Sci. 107(1):19–26. 10.1093/toxsci/kfn228 18974089
Klaunig JE, Ruch RJ, Lin ELC. 1989. Effects of trichloroethylene and its metabolites on rodent hepatocyte intercellular communication. Toxicol Appl Pharmacol. 99(3):454–465. 10.1016/0041-008X(89)90153-1 2749732
Komaki Y, Pals J, Wagner ED, Marinas BJ, Plewa MJ. 2009. Mammalian cell DNA damage and repair kinetics of monohaloacetic acid drinking water disinfection by-products. Environ Sci Technol. 43(21):8437–8442. 10.1021/es901852z 19924981
Krasner SW, Kostopoulou M, Toledano MB, Wright J, Patelarou E, Kogevinas M, Villanueva CM, Carrasco-Turigas G, Santa Marina L, Fernández-Somoano A, et al. 2016 a. Occurrence of DBPs in drinking water of european regions for epidemiology studies. J Am Water Works Assoc. 108(10):E501–E512.10.5942/jawwa.2016.108.0152
Krasner SW, Lee TC, Westerhoff P, Fischer N, Hanigan D, Karanfil T, Beita-Sandí W, Taylor-Edmonds L, Andrews RC. 2016 b. Granular activated carbon treatment may result in higher predicted genotoxicity in the presence of bromide. Environ Sci Technol. 50(17):9583–9591. 10.1021/acs.est.6b02508 27467860
Krasner SW, Weinberg HS, Richardson SD, Pastor SJ, Chinn R, Sclimenti MJ, Onstad GD, Thruston AD Jr. 2006. Occurrence of a new generation of disinfection byproducts. Environ Sci Technol. 40(23):7175–7185. 10.1021/es060353j 17180964
Krishna S, Agbenyega T, Angus BJ, Bedu-Addo G, Ofori-Amanfo G, Henderson G, Szwandt IS, O’Brien R, Stacpoole PW. 1995. Pharmacokinetics and pharmacodynamics of dichloroacetate in children with lactic acidosis due to severe malaria. QJM. 88(5):341–349. 7796089
Krishna S, Supanaranond W, Pukrittayakamee S, Karter D, Supputamongkol Y, Davis TM, Holloway PA, White NJ. 1994. Dichloroacetate for lactic acidosis in severe malaria: A pharmacokinetic and pharmacodynamic assessment. Metabolism. 43(8):974–981. 10.1016/0026-0495(94)90177-5 8052155
Krishna S, Supanaranond W, Pukrittayakamee S, Kuile FT, Ruprah M, White NJ. 1996. The disposition and effects of two doses of dichloroacetate in adults with severe falciparum malaria. Br J Clin Pharmacol. 41(1):29–34. 10.1111/j.1365-2125.1996.tb00155.x 8824690
Kulling P, Andersson H, Boström K, Johansson LA, Lindström B, Nyström B. 1992. Fatal systemic poisoning after skin exposure to monochloroacetic acid. J Toxicol Clin Toxicol. 30(4):643–652. 10.3109/15563659209017948 1433433
Kuppusamy SP, Kaiser JP, Wesselkamper SC. 2015. Epigenetic regulation in environmental chemical carcinogenesis and its applicability in human health risk assessment. Int J Toxicol. 34(5):384–392. 10.1177/1091581815599350 26268770
Kusch GD, McCarty LP, Lanham JM. 1990. Monochloroacetic acid exposure: A case report. Pol J Occup Med. 3(4):409–414. 2134323
Lan J, Gou N, Rahman SM, Gao C, He M, Gu AZ. 2016. A quantitative toxicogenomics assay for high-throughput and mechanistic genotoxicity assessment and screening of environmental pollutants. Environ Sci Technol. 50(6):3202–3214. 10.1021/acs.est.5b05097 26855253
Lantagne DS, Blount BC, Cardinali F, Quick R. 2008. Disinfection by-product formation and mitigation strategies in point-of-use chlorination of turbid and non-turbid waters in western Kenya. J Water Health. 6(1):67–82. 10.2166/wh.2007.013 17998608
Lantagne DS, Cardinali F, Blount BC. 2010. Disinfection by-product formation and mitigation strategies in point-of-use chlorination with sodium dichloroisocyanurate in Tanzania. Am J Trop Med Hyg. 83(1):135–143. 10.4269/ajtmh.2010.09-0431 20595492
Larson JL, Bull RJ. 1992. Metabolism and lipoperoxidative activity of trichloroacetate and dichloroacetate in rats and mice. Toxicol Appl Pharmacol. 115(2):268–277. 10.1016/0041-008X(92)90332-M 1641860
Laughter AR, Dunn CS, Swanson CL, Howroyd P, Cattley RC, Corton JC. 2004. Role of the peroxisome proliferator-activated receptor alpha (PPARalpha) in responses to trichloroethylene and metabolites, trichloroacetate and dichloroacetate in mouse liver. Toxicology. 203(1-3):83–98. 10.1016/j.tox.2004.06.014 15363585
Lee KJ, Kim BH, Hong JE, Pyo HS, Park SJ, Lee DW. 2001. A study on the distribution of chlorination by-products (CBPs) in treated water in Korea. Water Res. 35(12):2861–2872. 10.1016/S0043-1354(00)00583-2 11471686
Li W, Gu Y, James MO, Hines RN, Simpson P, Langaee T, Stacpoole PW. 2012. Prenatal and postnatal expression of glutathione transferase zeta 1 in human liver and the roles of haplotype and subject age in determining activity with dichloroacetate. Drug Metab Dispos. 40(2):232–239. 10.1124/dmd.111.041533 22028318
Liang L, Singer PC. 2003. Factors influencing the formation and relative distribution of haloacetic acids and trihalomethanes in drinking water. Environ Sci Technol. 37(13):2920–2928. 10.1021/es026230q 12875395
Lin ELC, Mattox JK, Bernard Daniel F. 1993. Tissue distribution, excretion, and urinary metabolites of dichloroacetic acid in the male Fischer 344 rat. J Toxicol Environ Health. 38(1):19–32. 10.1080/15287399309531697 8421320
Liviac D, Creus A, Marcos R. 2010. Genotoxicity testing of three monohaloacetic acids in TK6 cells using the cytokinesis-block micronucleus assay. Mutagenesis. 25(5):505–509. 10.1093/mutage/geq034 20547559
Lu J, Tan M, Cai Q. 2015. The Warburg effect in tumor progression: Mitochondrial oxidative metabolism as an anti-metastasis mechanism. Cancer Lett. 356 2 Pt A:156–164. 10.1016/j.canlet.2014.04.001 24732809
Luijten M, Olthof ED, Hakkert BC, Rorije E, van der Laan JW, Woutersen RA, van Benthem J. 2016. An integrative test strategy for cancer hazard identification. Crit Rev Toxicol. 46(7):615–639. 10.3109/10408444.2016.1171294 27142259
Lukas G, Vyas KH, Brindle SD, Le Sher AR, Wagner WE Jr. 1980. Biological disposition of sodium dichloroacetate in animals and humans after intravenous administration. J Pharm Sci. 69(4):419–421. 10.1002/jps.2600690415 7373538
Lumpkin MH, Bruckner JV, Campbell JL, Dallas CE, White CA, Fisher JW. 2003. Plasma binding of trichloroacetic acid in mice, rats, and humans under cancer bioassay and environmental exposure conditions. Drug Metab Dispos. 31(10):1203–1207. 10.1124/dmd.31.10.1203 12975328
Maisenbacher HW, Shroads AL, Zhong G, Daigle AD, Abdelmalak MM, Samper IS, Mincey BD, James MO, Stacpoole PW. 2013. Pharmacokinetics of oral dichloroacetate in dogs. J Biochem Mol Toxicol. 27(12):522–525. 10.1002/jbt.21518 24038869
Malliarou E, Collins C, Graham N, Nieuwenhuijsen MJ. 2005. Haloacetic acids in drinking water in the United Kingdom. Water Res. 39(12):2722–2730. 10.1016/j.watres.2005.04.052 15967473
Maloney EK, Waxman DJ. 1999. trans-Activation of PPARalpha and PPARgamma by structurally diverse environmental chemicals. Toxicol Appl Pharmacol. 161(2):209–218. 10.1006/taap.1999.8809 10581215
Mather GG, Exon JH, Koller LD. 1990. Subchronic 90 day toxicity of dichloroacetic and trichloroacetic acid in rats. Toxicology. 64(1):71–80. 10.1016/0300-483X(90)90100-U 2219134
McGuire MJ, McLain JL, Obolensky A. 2002. Information Collection Rule Data Analysis. AWWA Research Foundation and American Water Works Association.
McTigue NE, Cornwell DA, Graf K, Brown R. 2014. Occurrence and consequences of increased bromide in drinking water sources. J Am Water Works Assoc. 106:E492–E508.10.5942/jawwa.2014.106.0141
Melnick RL, Nyska A, Foster PM, Roycroft JH, Kissling GE. 2007. Toxicity and carcinogenicity of the water disinfection byproduct, dibromoacetic acid, in rats and mice. Toxicology. 230(2-3):126–136. 10.1016/j.tox.2006.11.006 17157429
Merdink JL, Bull RJ, Schultz IR. 2000. Trapping and identification of the dichloroacetate radical from the reductive dehalogenation of trichloroacetate by mouse and rat liver microsomes. Free Radic Biol Med. 29(2):125–130. 10.1016/S0891-5849(00)00330-0 10980401
Merdink JL, Bull RJ, Schultz IR. 2001. Toxicokinetics of bromodichloroacetate in B6C3F1 mice. J Appl Toxicol. 21(1):53–57. 10.1002/jat.732 11180280
Merdink JL, Gonzalez-Leon A, Bull RJ, Schultz IR. 1998. The extent of dichloroacetate formation from trichloroethylene, chloral hydrate, trichloroacetate, and trichloroethanol in B6C3F1 mice. Toxicol Sci. 45(1):33–41. 10.1093/toxsci/45.1.33 9848108
Muellner MG, Attene-Ramos MS, Hudson ME, Wagner ED, Plewa MJ. 2010. Human cell toxicogenomic analysis of bromoacetic acid: A regulated drinking water disinfection by-product. Environ Mol Mutagen. 51(3):205–214. 10.1002/em.20530 19753638
Müller G, Spassovski M, Henschler D. 1974. Metabolism of trichloroethylene in man. II. Pharmacokinetics of metabolites. Arch Toxicol. 32(4):283–295. 10.1007/BF00330110 4480028
National Toxicology Program (NTP).1992. Toxicology and carcinogenesis studies of monochloroacetic acid (CAS No. 79-11-8) in F344/N rats and B6C3F1 mice (gavage studies). Research Triangle Park, NC: National Toxicology Program. NTP Technical Report No. 396. NIH Publication No. 92-2851.
National Toxicology Program (NTP).2007a. Toxicology and carcinogenesis studies of dibromoacetic acid (CAS No. 631-64-1) in F344/N rats and B6C3F1 mice (drinking water studies). Research Triangle Park, NC: National Toxicology Program. NTP Technical Report No. 537. NIH Publication No. 07-4475.
National Toxicology Program (NTP).2007b. Toxicology studies of dichloroacetic acid (CAS No. 79-43-6) in genetically modified (FVB Tg.Ac hemizygous) mice (dermal and drinking water studies) and carcinogenicity studies of dichloroacetic acid in genetically modified [B6.129-Trp53^tm1brd^ (N5) haploinsufficient] mice (drinking water studies). Research Triangle Park, NC: National Toxicology Program. NTP Genetically Modified Model Report No. 11. NIH Publication No. 07-4428.
National Toxicology Program (NTP).2009. Toxicology and carcinogenesis studies of bromochloroacetic acid (CAS No. 5589-96-8) in F344/N rats and B6C3F1 mice (drinking water studies). Research Triangle Park, NC: National Toxicology Program. NTP Technical Report No. 549. NIH Publication No. 09-5890.
National Toxicology Program (NTP).2015. Toxicology studies of bromodichloroacetic acid (CAS No. 71133-14-7) in F344/N rats and B6C3F1/N mice and toxicology and carcinogenesis studies of bromodichloroacetic acid in F344/Ntac rats and B6C3F1/N mice (drinking water studies). Research Triangle Park, NC: National Toxicology Program. NTP Technical Report No. 583.
National Toxicology Program (NTP).2017. Report on Carcinogens protocol: Haloacetic acids found as water disinfection by-products. Research Triangle Park, NC: National Toxicology Program.https://ntp.niehs.nih.gov/ntp/roc/protocols/haloacetic_acids.pdf.
Nelson KJ.2015. Formation of haloacetic acids and Nitrosodimethylamine via the chlorination of carbon nanotubes. University of Iowa, Master of Science thesis.https://ir.uiowa.edu/etd/1708. 10.17077/etd.igro9blf
Nelson MA, Sanchez IM, Bull RJ, Sylvester SR. 1990. Increased expression of c-myc and c-Ha-ras in dichloroacetate and trichloroacetate-induced liver tumors in B6C3F1 mice. Toxicology. 64(1):47–57. 10.1016/0300-483X(90)90098-2 2219132
Nieminski EC, Chaudhuri S, Lamoreaux T. 1993. The occurrence of DBPs in Utah drinking waters. J Am Water Works Assoc. 85(9):98–105.10.1002/j.1551-8833.1993.tb06067.x
Nissinen TK, Miettinen IT, Martikainen PJ, Vartiainen T. 2002. Disinfection by-products in Finnish drinking waters. Chemosphere. 48(1):9–20. 10.1016/S0045-6535(02)00034-6 12137063
Ohashi T, Akazawa T, Aoki M, Kuze B, Mizuta K, Ito Y, Inoue N. 2013. Dichloroacetate improves immune dysfunction caused by tumor-secreted lactic acid and increases antitumor immunoreactivity. Int J Cancer. 133(5):1107–1118. 10.1002/ijc.28114 23420584
Ondricek AJ, Kashyap AK, Thamake SI, Vishwanatha JK. 2012. A comparative study of phytoestrogen action in mitigating apoptosis induced by oxidative stress. In Vivo. 26(5):765–775. 22949589
Ono Y, Somiya I, Kawamura M. 1991. The evaluation of genotoxicity using DNA repairing test for chemicals produced in chlorination and ozonation processes. Water Sci Technol. 23(1-3):329–338.10.2166/wst.1991.0431
Organization for Economic Co-operation and Development (OECD).2017. Grouping of chemicals: Chemical categories and read-across. Organization for Economic Co-operation and Development.https://www.oecd.org/chemicalsafety/risk-assessment/groupingofchemicalschemicalcategoriesandread-across.htm. [accessed: 10/22/17]
Pals J, Attene-Ramos MS, Xia M, Wagner ED, Plewa MJ. 2013. Human cell toxicogenomic analysis linking reactive oxygen species to the toxicity of monohaloacetic acid drinking water disinfection byproducts. Environ Sci Technol. 47(21):12514–12523. 10.1021/es403171b 24050308
Pals JA, Ang JK, Wagner ED, Plewa MJ. 2011. Biological mechanism for the toxicity of haloacetic acid drinking water disinfection byproducts. Environ Sci Technol. 45(13):5791–5797. 10.1021/es2008159 21671678
Pals JA, Wagner ED, Plewa MJ. 2016. Energy of the lowest unoccupied molecular orbital, thiol reactivity, and toxicity of three monobrominated water disinfection byproducts. Environ Sci Technol. 50(6):3215–3221. 10.1021/acs.est.5b05581 26854864
Pan Y, Wei X, Hao W. 2015. Trichloroethylene and its oxidative metabolites enhance the activated state and Th1 cytokine gene expression in jurkat cells. Int J Environ Res Public Health. 12(9):10575–10586. 10.3390/ijerph120910575 26343699
Pan Y, Zhang X, Li Y. 2016. Identification, toxicity and control of iodinated disinfection byproducts in cooking with simulated chlor(am)inated tap water and iodized table salt. Water Res. 88:60–68. 10.1016/j.watres.2015.10.002 26474150
Parinet J, Tabaries S, Coulomb B, Vassalo L, Boudenne JL. 2012. Exposure levels to brominated compounds in seawater swimming pools treated with chlorine. Water Res. 46(3):828–836. 10.1016/j.watres.2011.11.060 22153961
Parrish JM, Austin EW, Stevens DK, Kinder DH, Bull RJ. 1996. Haloacetate-induced oxidative damage to DNA in the liver of male B6C3F1 mice. Toxicology. 110(1-3):103–111. 10.1016/0300-483X(96)03342-2 8658551
Parvez S, Rivera-Núñez Z, Meyer A, Wright JM. 2011. Temporal variability in trihalomethane and haloacetic acid concentrations in Massachusetts public drinking water systems. Environ Res. 111(4):499–509. 10.1016/j.envres.2010.12.008 21316653
Patlewicz G, Ball N, Boogaard PJ, Becker RA, Hubesch B. 2015. Building scientific confidence in the development and evaluation of read-across. Regul Toxicol Pharmacol. 72(1):117–133. 10.1016/j.yrtph.2015.03.015 25857293
Paykoc ZV, Powell JF. 1945. The excretion of sodium trichloroacetate. J Pharmacol Exp Ther. 85:289–293. 21010735
Pereira MA. 1996. Carcinogenic activity of dichloroacetic acid and trichloroacetic acid in the liver of female B6C3F1 mice. Fundam Appl Toxicol. 31(2):192–199. 10.1006/faat.1996.0091 8789785
Pereira MA, Kramer PM, Conran PB, Tao L. 2001. Effect of chloroform on dichloroacetic acid and trichloroacetic acid-induced hypomethylation and expression of the c-myc gene and on their promotion of liver and kidney tumors in mice. Carcinogenesis. 22(9):1511–1519. 10.1093/carcin/22.9.1511 11532874
Pereira MA, Li KW, Kramer PM. 1997. Promotion by mixtures of dichloroacetic acid and trichloroacetic acid of N-methyl-N-nitrosourea-initiated cancer in the liver of female B6C3F1 mice. Cancer Lett. 115(1):15–23. 10.1016/S0304-3835(97)04699-5 9097974
Pereira MA, Phelps JB. 1996. Promotion by dichloroacetic acid and trichloroacetic acid of N-methyl-N-nitrosourea-initiated cancer in the liver of female B6C3F1 mice. Cancer Lett. 102(1-2):133–141. 10.1016/0304-3835(96)04156-0 8603361
Pereira MA, Wang W, Kramer PM, Tao L. 2004 b. Prevention by methionine of dichloroacetic acid-induced liver cancer and DNA hypomethylation in mice. Toxicol Sci. 77(2):243–248. 10.1093/toxsci/kfh031 14657517
Pereira MA, Wang W, Kramer PM, Tao LH. 2004 a. DNA hypomethylation induced by non-genotoxic carcinogens in mouse and rat colon. Cancer Lett. 212(2):145–151. 10.1016/j.canlet.2004.03.024 15279894
Pérez-Garrido A, González MP, Escudero AG. 2008. Halogenated derivatives QSAR model using spectral moments to predict haloacetic acids (HAA) mutagenicity. Bioorg Med Chem. 16(10):5720–5732. 10.1016/j.bmc.2008.03.070 18406150
Plewa M, Kargalioglu Y, Vankerk D, Minear R, Wagner E. 2000. Development of quantitative comparative cytotoxicity and genotoxicity assays for environmental hazardous chemicals. Water Sci Technol. 42(7-8):109.10.2166/wst.2000.0558
Plewa MJ, Cemeli E, Anderson D, Wagner E. 2004 a. The genotoxicity of the drinking water disinfection by-product iodoacetic acid is reduced by modulators of oxidative stress. Environ Mol Mutagen. 44(3):220.
Plewa MJ, Kargalioglu Y, Vankerk D, Minear RA, Wagner ED. 2002. Mammalian cell cytotoxicity and genotoxicity analysis of drinking water disinfection by-products. Environ Mol Mutagen. 40(2):134–142. 10.1002/em.10092 12203407
Plewa MJ, Simmons JE, Richardson SD, Wagner ED. 2010. Mammalian cell cytotoxicity and genotoxicity of the haloacetic acids, a major class of drinking water disinfection by-products. Environ Mol Mutagen. 51(8-9):871–878. 10.1002/em.20585 20839218
Plewa MJ, Wagner ED. 2015. Chapter 1, Charting a new path to resolve the adverse health effects of DBPs. In: Karanfil T, Mitch B, Westerhoff P, Xie H, editors. Recent Advances in Disinfection By-Products. Washington, D.C.: American Chemical Society; p. 3–23. 10.1021/bk-2015-1190.ch001
Plewa MJ, Wagner ED, Richardson SD, Thruston AD Jr, Woo YT, McKague AB. 2004 b. Chemical and biological characterization of newly discovered iodoacid drinking water disinfection byproducts. Environ Sci Technol. 38(18):4713–4722. 10.1021/es049971v 15487777
Procházka E, Escher BI, Plewa MJ, Leusch FD. 2015. In vitro cytotoxicity and adaptive stress responses to selected haloacetic acid and halobenzoquinone water disinfection byproducts. Chem Res Toxicol. 28(10):2059–2068. 10.1021/acs.chemrestox.5b00283 26327680
PubChem.2005. PubChem Compound Database: Iodoacetic Acid. Bethesda, MD: National Library of Medicine.https://pubchem.ncbi.nlm.nih.gov/compound/iodoacetic_acid#section=Non-Human-Toxicity-Values. [Accessed: 10/12/17]
PubChem.2016a. PubChem Compound Database: Diiodoacetic acid. Bethesda, MD: National Library of Medicine.https://pubchem.ncbi.nlm.nih.gov/ and search on diiodoacetic acid. [Accessed: 5/16/16]
PubChem.2016b. PubChem Compound Database: Chloroacetic acid. Bethesda, MD: National Library of Medicine.https://pubchem.ncbi.nlm.nih.gov/ and search on chloroacetic acid. [Accessed: 4/11/17]
PubChem.2017. PubChem Compound Database: Chloroacetic acid. Bethesda, MD: National Library of Medicine.https://pubchem.ncbi.nlm.nih.gov/ and search on chloroacetic acid. [Accessed: 4/11/17]
Ratasuk C, Kositanont C, Ratanatamskul C. 2008. Removal of haloacetic acids by ozone and biologically active carbon. Sci Asia. 34:293–298.10.2306/scienceasia1513-1874.2008.34.293
Raymer J, Michael LC.2010. Uptake of water disinfection by-products into food. Research Triangle Park, NC: Research Triangle Institute. MR-0016-1008 10.3768/rtipress.2010.mr.0016.1008
Reckhow DA, Platt TL, MacNeill AL, McClellan JN. 2001. Formation and degradation of dichloroacetonitrile in drinking waters. J Water Supply Res Technol. 50(1):1–13.10.2166/aqua.2001.0001
Reckhow DA, Singer PC. 1985. Mechanisms of organic halide formation during fulvic acid chlorination and implications with respect to preozonation. In: Jolley RL, Bull RJ, Davis WP, Katz S, Roberts MH Jr, Jacobs VA, editors. Water Chlorination: Chemistry, Environmental Impact and Health Effects. Chelsea, MI: Lewis Publishers, Inc.; p. 1229–1257.
Regli S, Chen J, Messner M, Elovitz MS, Letkiewicz FJ, Pegram RA, Pepping TJ, Richardson SD, Wright JM. 2015. Estimating potential increased bladder cancer risk due to increased bromide concentrations in sources of disinfected drinking waters. Environ Sci Technol. 49(22):13094–13102. 10.1021/acs.est.5b03547 26489011
Richard AM, Hunter ES 3rd.1996. Quantitative structure-activity relationships for the developmental toxicity of haloacetic acids in mammalian whole embryo culture. Teratology. 53(6):352-360. 10.1002/(SICI)1096-9926(199606)53:6<352:AID-TERA6>3.0.CO;2-1
Richardson S. 2016. Reviewer form for ORoC information group on haloacetic acids to the National Toxicology Program.
Richardson SD, Fasano F, Ellington JJ, Crumley FG, Buettner KM, Evans JJ, Blount BC, Silva LK, Waite TJ, Luther GW, et al. 2008. Occurrence and mammalian cell toxicity of iodinated disinfection byproducts in drinking water. Environ Sci Technol. 42(22):8330–8338. 10.1021/es801169k 19068814
Richardson SD, Plewa MJ, Wagner ED, Schoeny R, Demarini DM. 2007. Occurrence, genotoxicity, and carcinogenicity of regulated and emerging disinfection by-products in drinking water: A review and roadmap for research. Mutat Res. 636(1-3):178–242. 10.1016/j.mrrev.2007.09.001 17980649
Richardson SD, Postigo C. 2015. Formation of DBPs: State of the science. In: Karanfil T, Krasner SW, Westerhoff P, Xie Y, editors. Recent Advances in Disinfection By-Products. Washington, DC: American Chemical Society; p. 189–214. 10.1021/bk-2015-1190.ch011
Richmond RE, Carter JH, Carter HW, Daniel FB, DeAngelo AB. 1995. Immunohistochemical analysis of dichloroacetic acid (DCA)-induced hepatocarcinogenesis in male Fischer (F344) rats. Cancer Lett. 92(1):67–76. 10.1016/0304-3835(94)03756-9 7538896
Richmond RE, De Angelo AB, Potter CL, Daniel FB. 1991. The role of hyperplastic nodules in dichloroacetic acid-induced hepatocarcinogenesis in B6C3F1 male mice. Carcinogenesis. 12(8):1383–1387. 10.1093/carcin/12.8.1383 1860158
Roberts MG, Singer PC, Obolensky A. 2002. Comparing total HAA and total THM concentrations using ICR data. J Am Water Works Assoc. 94(1):103–114.10.1002/j.1551-8833.2002.tb09386.x
Roccaro P, Vagliasindi FGA, Korshin GV. 2014. Relationships between trihalomethanes, haloacetic acids, and haloacetonitriles formed by the chlorination of raw, treated, and fractionated surface waters. J Water Supply Res Technol. 63(1):21–30.10.2166/aqua.2013.043
Rodriguez MJ, Sérodes J-B, Levallois P, Proulx F. 2007. Chlorinated disinfection by-products in drinking water according to source, treatment, season, and distribution location. J Environ Eng Sci. 6:355–365.10.1139/s06-055
Rogers DR. 1995. Accidental fatal monochloroacetic acid poisoning. Am J Forensic Med Pathol. 16(2):115–116. 10.1097/00000433-199506000-00005 7572862
Rosinger A, Herrick K. 2016. Daily water intake among U.S. men and women, 2009-2012. NCHS Data Brief.(242):1–8. 27139510
Safe Drinking Water Foundation (SDWF).2009. What is chlorination? Safe Drinking Water Foundation. https://www.safewater.org/PDFS/resourcesknowthefacts/WhatisChlorination.pdf.
Saghir SA, Fried K, Rozman KK. 2001. Kinetics of monochloroacetic acid in adult male rats after intravenous injection of a subtoxic and a toxic dose. J Pharmacol Exp Ther. 296(2):612–622. 11160650
Saghir SA, Ghanayem BI, Schultz IR. 2011. Kinetics of trihalogenated acetic acid metabolism and isoform specificity in liver microsomes. Int J Toxicol. 30(5):551–561. 10.1177/1091581811414213 21933969
Saghir SA, Rozman KK. 2003. Kinetics of monochloroacetic acid at subtoxic and toxic doses in rats after single oral and dermal administrations. Toxicol Sci. 76(1):51–64. 10.1093/toxsci/kfg214 12915718
Saghir SA, Schultz IR. 2002. Low-dose pharmacokinetics and oral bioavailability of dichloroacetate in naive and GST-ζ-depleted rats. Environ Health Perspect. 110(8):757–763. 10.1289/ehp.02110757 12153755
Saghir SA, Schultz IR. 2005. Toxicokinetics and oral bioavailability of halogenated acetic acids mixtures in naive and GSTzeta-depleted rats. Toxicol Sci. 84(2):214–224. 10.1093/toxsci/kfi070 15625187
Sanchez IM, Bull RJ. 1990. Early induction of reparative hyperplasia in the liver of B6C3F1 mice treated with dichloroacetate and trichloroacetate. Toxicology. 64(1):33–46. 10.1016/0300-483X(90)90097-Z 2219131
Schroeder M, DeAngelo AB, Mass MJ. 1997. Dichloroacetic acid reduces Ha-ras codon 61 mutations in liver tumors from female B6C3F1 mice. Carcinogenesis. 18(8):1675–1678. 10.1093/carcin/18.8.1675 9276648
Schultz IR, Merdink JL, Gonzalez-Leon A, Bull RJ. 1999. Comparative toxicokinetics of chlorinated and brominated haloacetates in F344 rats. Toxicol Appl Pharmacol. 158(2):103–114. 10.1006/taap.1999.8698 10406925
Schultz IR, Merdink JL, Gonzalez-Leon A, Bull RJ. 2002. Dichloroacetate toxicokinetics and disruption of tyrosine catabolism in B6C3F1 mice: Dose-response relationships and age as a modifying factor. Toxicology. 173(3):229–247. 10.1016/S0300-483X(02)00034-3 11960676
Schultz IR, Shangraw RE. 2006. Effect of short-term drinking water exposure to dichloroacetate on its pharmacokinetics and oral bioavailability in human volunteers: A stable isotope study. Toxicol Sci. 92(1):42–50. 10.1093/toxsci/kfj193 16611621
Schultz IR, Sylvester SR. 2001. Stereospecific toxicokinetics of bromochloro- and chlorofluoroacetate: Effect of GST-ζ depletion. Toxicol Appl Pharmacol. 175(2):104–113. 10.1006/taap.2001.9250 11543642
Schultz TW, Amcoff P, Berggren E, Gautier F, Klaric M, Knight DJ, Mahony C, Schwarz M, White A, Cronin MT. 2015. A strategy for structuring and reporting a read-across prediction of toxicity. Regul Toxicol Pharmacol. 72(3):586–601. 10.1016/j.yrtph.2015.05.016 26003513
Schultz TW, Carlson RE, Cronin MTD, Hermens JLM, Johnson R, O’Brien PJ, Roberts DW, Siraki A, Wallace KB, Veith GD. 2006. A conceptual framework for predicting the toxicity of reactive chemicals: Modeling soft electrophilicity. SAR QSAR Environ Res. 17(4):413–428. 10.1080/10629360600884371 16920662
Seidel CJ, Samson CC, Bartrand T, Ergul A, Summers RS. 2017. Disinfection byproduct occurrence at large water systems after stage 2 DBPR. J Am Water Works Assoc. 109(7):17–30. 10.5942/jawwa.2017.109.0082
Shangraw RE, Fisher DM. 1996. Pharmacokinetics of dichloroacetate in patients undergoing liver transplantation. Anesthesiology. 84(4):851–858. 10.1097/00000542-199604000-00012 8638839
Shangraw RE, Fisher DM. 1999. Pharmacokinetics and pharmacodynamics of dichloroacetate in patients with cirrhosis. Clin Pharmacol Ther. 66(4):380–390. 10.1053/cp.1999.v66.a101340 10546922
Shroads AL, Coats BS, McDonough CW, Langaee T, Stacpoole PW. 2015. Haplotype variations in glutathione transferase zeta 1 influence the kinetics and dynamics of chronic dichloroacetate in children. J Clin Pharmacol. 55(1):50–55. 10.1002/jcph.371 25079374
Shroads AL, Langaee T, Coats BS, Kurtz TL, Bullock J, Weithorn D, Gong Y, Wagner D, Ostrov DA, Johnson JA, et al. 2010. Human polymorphisms in the glutathione transferase zeta 1 maleylacetoacetate isomerase gene predict the kinetics and toxicity of dichloroacetate. Drug Metab Rev. 42:204–204.
Si EC, Pfeifer RW, Yim GK. 1987. Iodoacetic acid and related sulfhydryl reagents fail to inhibit cell-cell communication: Mechanisms of immunotoxicity in vitro. Toxicology. 44(1):73–89. 10.1016/0300-483X(87)90047-3 3105120
Singer PC, Weinberg HS, Brophy K, Liang L, Roberts M, Grisstede I, Krasner S, Baribeau H, Arora H, Najm I. 2002. Relative dominance of haloacetic acids and trihalomethanes in treated drinking water. AWWA Research Foundation and the American Water Works Association.
Smith EM, Plewa MJ, Lindell CL, Richardson SD, Mitch WA. 2010 b. Comparison of byproduct formation in waters treated with chlorine and iodine: Relevance to point-of-use treatment. Environ Sci Technol. 44(22):8446–8452. 10.1021/es102746u 20964286
Smith MJ, Germolec DR, Luebke RW, Sheth CM, Auttachoat W, Guo TL, White KL Jr. 2010 a. Immunotoxicity of dibromoacetic acid administered via drinking water to female B(6)C(3)F(1) mice. J Immunotoxicol. 7(4):333–343. 10.3109/1547691X.2010.519744 20958156
Smith MT, Guyton KZ, Gibbons CF, Fritz JM, Portier CJ, Rusyn I, DeMarini DM, Caldwell JC, Kavlock RJ, Lambert P, et al. 2016. Key characteristics of carcinogens as a basis for organizing data on mechanisms of carcinogenesis. Environ Health Perspect. 124(6):713–721. 10.1289/ehp.1509912 26600562
Snyder RD, Pullman J, Carter JH, Carter HW, DeAngelo AB. 1995. In vivo administration of dichloroacetic acid suppresses spontaneous apoptosis in murine hepatocytes. Cancer Res. 55(17):3702–3705. 7641179
Spalding JW, French JE, Stasiewicz S, Furedi-Machacek M, Conner F, Tice RR, Tennant RW. 2000. Responses of transgenic mouse lines p53(+/-) and Tg.AC to agents tested in conventional carcinogenicity bioassays. Toxicol Sci. 53(2):213–223. 10.1093/toxsci/53.2.213 10696769
Stacpoole PW. 2011. The dichloroacetate dilemma: Environmental hazard versus therapeutic goldmine-both or neither? Environ Health Perspect. 119(2):155–158. 10.1289/ehp.1002554 20920954
Stacpoole PW, Henderson GN, Yan ZM, Cornett R, James MO. 1998. Pharmacokinetics, metabolism, and toxicology of dichloroacetate. Drug Metab Rev. 30(3):499–539. 10.3109/03602539808996323 9710704
Stacpoole PW, Kurtz TL, Han Z, Langaee T. 2008. Role of dichloroacetate in the treatment of genetic mitochondrial diseases. Adv Drug Deliv Rev. 60(13-14):1478–1487. 10.1016/j.addr.2008.02.014 18647626
Stalter D, O’Malley E, von Gunten U, Escher BI. 2016 a. Fingerprinting the reactive toxicity pathways of 50 drinking water disinfection by-products. Water Res. 91:19–30. 10.1016/j.watres.2015.12.047 26773486
Stalter D, O’Malley E, Von Gunten U, Escher BI. 2016 b. Point-of-use water filters can effectively remove disinfection by-products and toxicity from chlorinated and chloraminated tap water. Environ Sci Water Res Technol. 2:875–883.10.1039/C6EW00068A
Stauber AJ, Bull RJ. 1997. Differences in phenotype and cell replicative behavior of hepatic tumors induced by dichloroacetate (DCA) and trichloroacetate (TCA). Toxicol Appl Pharmacol. 144(2):235–246. 10.1006/taap.1997.8159 9194407
Stauber AJ, Bull RJ, Thrall BD. 1998. Dichloroacetate and trichloroacetate promote clonal expansion of anchorage-independent hepatocytes in vivo and in vitro. Toxicol Appl Pharmacol. 150(2):287–294. 10.1006/taap.1998.8417 9653059
Stevens DK, Eyre RJ, Bull RJ. 1992. Adduction of hemoglobin and albumin invivo by metabolites of trichloroethylene, trichloroacetate, and dichloroacetate in rats and mice. Fundam Appl Toxicol. 19(3):336–342. 10.1016/0272-0590(92)90171-D 1459365
Styles JA, Wyatt I, Coutts C. 1991. Trichloroacetic acid: Studies on uptake and effects on hepatic DNA and liver growth in mouse. Carcinogenesis. 12(9):1715–1719. 10.1093/carcin/12.9.1715 1893532
Szczuka A, Parker KM, Harvey C, Hayes E, Vengosh A, Mitch WA. 2017. Regulated and unregulated halogenated disinfection byproduct formation from chlorination of saline groundwater. Water Res. 122:633–644. 10.1016/j.watres.2017.06.028 28646800
Tanaka N, Bohnenberger S, Kunkelmann T, Munaro B, Ponti J, Poth A, Sabbioni E, Sakai A, Salovaara S, Sasaki K, et al. 2012. Prevalidation study of the BALB/c 3T3 cell transformation assay for assessment of carcinogenic potential of chemicals. Mutat Res. 744(1):20–29. 10.1016/j.mrgentox.2011.12.008 22198331
Tanguay RM, Jorquera R, Poudrier J, St-Louis M. 1996. Tyrosine and its catabolites: From disease to cancer. Acta Biochim Pol. 43(1):209–216. 10.18388/abp.1996_4530 8790725
Tao L, Li Y, Kramer PM, Wang W, Pereira MA. 2004 b. Hypomethylation of DNA and the insulin-like growth factor-II gene in dichloroacetic and trichloroacetic acid-promoted mouse liver tumors. Toxicology. 196(1-2):127–136. 10.1016/j.tox.2003.11.011 15036762
Tao L, Wang W, Li L, Kramer PK, Pereira MA. 2005. DNA hypomethylation induced by drinking water disinfection by-products in mouse and rat kidney. Toxicol Sci. 87(2):344–352. 10.1093/toxsci/kfi257 16014735
Tao L, Wang W, Li L, Kramer PM, Pereira MA. 2004 a. Effect of dibromoacetic acid on DNA methylation, glycogen accumulation, and peroxisome proliferation in mouse and rat liver. Toxicol Sci. 82(1):62–69. 10.1093/toxsci/kfh266 15342954
Tao L, Yang S, Xie M, Kramer PM, Pereira MA. 2000 a. Hypomethylation and overexpression of c-jun and c-myc protooncogenes and increased DNA methyltransferase activity in dichloroacetic and trichloroacetic acid-promoted mouse liver tumors. Cancer Lett. 158(2):185–193. 10.1016/S0304-3835(00)00518-8 10960769
Tao L, Yang S, Xie M, Kramer PM, Pereira MA. 2000 b. Effect of trichloroethylene and its metabolites, dichloroacetic acid and trichloroacetic acid, on the methylation and expression of c-jun and c-myc protooncogenes in mouse liver: Prevention by methionine. Toxicol Sci. 54(2):399–407. 10.1093/toxsci/54.2.399 10774822
Tao LH, Kramer PM, Ge RG, Pereira MA. 1998. Effect of dichloroacetic acid and trichloroacetic acid on DNA methylation in liver and tumors of female B6C3F1 mice. Toxicol Sci. 43(2):139–144. 10.1093/toxsci/43.2.139 9710955
Teixidó E, Piqué E, Gonzalez-Linares J, Llobet JM, Gómez-Catalán J. 2015. Developmental effects and genotoxicity of 10 water disinfection by-products in zebrafish. J Water Health. 13(1):54–66. 10.2166/wh.2014.006 25719465
Templin MV, Stevens DK, Stenner RD, Bonate PL, Turnan D, Bull RJ. 1995. Factors affecting species differences in the kinetics of metabolites of trichloroethylene. J Toxicol Environ Health. 44(4):435–447. 10.1080/15287399509531972 7723076
Tennant R, Haseman J, Stoll RE.2001. Transgenic assays and the identification of carcinogens. Environ Mol Mutagen. 37(1):86-88. 10.1002/1098-2280(2001)37:1<86:AID-EM1010>3.0.CO;2-G
Tennant RW, Spalding J. 1996. Predictions for the outcome of rodent carcinogenicity bioassays: Identification of trans-species carcinogens and noncarcinogens. Environ Health Perspect. 104 Suppl 5:1095–1100. 8933059
Teo TL, Coleman HM, Khan SJ. 2015. Chemical contaminants in swimming pools: Occurrence, implications and control. Environ Int. 76:16–31. 10.1016/j.envint.2014.11.012 25497109
Thai SF, Allen JW, DeAngelo AB, George MH, Fuscoe JC. 2001. Detection of early gene expression changes by differential display in the livers of mice exposed to dichloroacetic acid. Carcinogenesis. 22(8):1317–1322. 10.1093/carcin/22.8.1317 11470764
Thai SF, Allen JW, DeAngelo AB, George MH, Fuscoe JC. 2003. Altered gene expression in mouse livers after dichloroacetic acid exposure. Mutat Res. 543(2):167–180. 10.1016/S1383-5742(03)00014-0 12644186
Theodoratos A, Tu WJ, Cappello J, Blackburn AC, Matthaei K, Board PG. 2009. Phenylalanine-induced leucopenia in genetic and dichloroacetic acid generated deficiency of glutathione transferase Zeta. Biochem Pharmacol. 77(8):1358–1363. 10.1016/j.bcp.2009.01.017 19426674
Tong Z, Board PG, Anders MW. 1998. Glutathione transferase zeta-catalyzed biotransformation of dichloroacetic acid and other α-haloacids. Chem Res Toxicol. 11(11):1332–1338. 10.1021/tx980144f 9815194
Toxic Release Inventory (TRI).2017. TRI Explorer Chemical Report. TRI on-site and off-site reported disposed of or otherwise released (in pounds), for all 19 facilities, for facilities in all industries, for chloroacetic acid chemical, U.S., 2015. U.S. Environmental Protection Agency.https://www.epa.gov/triexplorer. [accessed: 4/2017]
Tully DB, Luft JC, Rockett JC, Ren H, Schmid JE, Wood CR, Dix DJ.2005. Reproductive and genomic effects in testes from mice exposed to the water disinfectant byproduct bromochloroacetic acid. Reprod Toxicol. 19(3 Spec Iss):353-366. 10.1016/j.reprotox.2004.06.009
Tzeng HF, Blackburn AC, Board PG, Anders MW. 2000. Polymorphism- and species-dependent inactivation of glutathione transferase zeta by dichloroacetate. Chem Res Toxicol. 13(4):231–236. 10.1021/tx990175q 10775321
U.S. Environmental Protection Agency (USEPA).2000. The history of drinking water treatment. U.S. Environmental Protection Agency. EPA 816/F-00/006
U.S. Environmental Protection Agency (USEPA).2003. Toxicological review of dichloroacetic acid. Washington, D.C.: U.S. Environmental Protection Agency. EPA 635/R-03/007
U.S. Environmental Protection Agency (USEPA).2005. Economic analysis for the final stage 2 disinfectants and disinfection byproducts rule. U.S. Environmental Protection Agency. EPA 815/R-05/010
U.S. Environmental Protection Agency (USEPA).2006. Economic analysis for the final ground water rule. U.S. Environmental Protection Agency. EPA 815/R-06/014
U.S. Environmental Protection Agency (USEPA).2010. Comprehensive disinfectants and disinfection byproducts rules (stage 1 and stage 2): Quick reference guide. U.S. Environmental Protection Agency. EPA 816/F-10/080
U.S. Environmental Protection Agency (USEPA).2011a. Toxicological review of trichloroacetic acid. Washington, D.C.: U.S. Environmental Protection Agency. EPA 635/R-09/003F
U.S. Environmental Protection Agency (USEPA).2011b. Toxicological review of trichloroethylene (CAS No. 79-01-6). In support of summary information on the Integrated Risk Information System (IRIS). Washington, D.C.: U.S. Environmental Protection Agency. EPA 635/R-09/011F
U.S. Environmental Protection Agency (USEPA).2015a. Basic information about your drinking water. U.S. Environmental Protection Agency.https://www.epa.gov/your-drinking-water/basic-information-about-your-drinking-water.
U.S. Environmental Protection Agency (USEPA).2015b. About private water wells. U.S. Environmental Protection Agency.https://www.epa.gov/privatewells/about-private-water-wells.
U.S. Environmental Protection Agency (USEPA).2016a. Conventional treatment. U.S. Environmental Protection Agency.https://iaspub.epa.gov/tdb/pages/treatment/treatmentOverview.do?treatmentProcessId=1934681921. [accessed: 10/17/16]
U.S. Environmental Protection Agency (USEPA).2016b. Six-year review 3 compliance monitoring data (2006-2011). U.S. Environmental Protection Agency.https://www.epa.gov/dwsixyearreview/six-year-review-3-compliance-monitoring-data-2006-2011.
Vander Heiden MG, Cantley LC, Thompson CB. 2009. Understanding the Warburg effect: The metabolic requirements of cell proliferation. Science. 324(5930):1029–1033. 10.1126/science.1160809 19460998
Varshney M, Chandra A, Chauhan LKS, Goel SK. 2013. Micronucleus induction by oxidative metabolites of trichloroethylene in cultured human peripheral blood lymphocytes: A comparative genotoxicity study. Environ Sci Pollut Res Int. 20(12):8709–8716. 10.1007/s11356-013-1806-7 23719688
Varshney M, Chandra A, Chauhan LKS, Goel SK. 2014. In vitro cytogenetic assessment of trichloroacetic acid in human peripheral blood lymphocytes. Environ Sci Pollut Res Int. 21(2):843–850. 10.1007/s11356-013-1949-6 23812791
Villanueva CM, Fernández F, Malats N, Grimalt JO, Kogevinas M. 2003 a. Meta-analysis of studies on individual consumption of chlorinated drinking water and bladder cancer. J Epidemiol Community Health. 57(3):166–173. 10.1136/jech.57.3.166 12594192
Villanueva CM, Gracia-Lavedan E, Bosetti C, Righi E, Molina AJ, Martín V, Boldo E, Aragonés N, Perez-Gomez B, Pollan M, et al. 2017. Colorectal cancer and long-term exposure to trihalomethanes in drinking water: A multicenter case-control study in Spain and Italy. Environ Health Perspect. 125(1):56–65. 10.1289/EHP155 27383820
Villanueva CM, Kogevinas M, Grimalt JO. 2003 b. Haloacetic acids and trihalomethanes in finished drinking waters from heterogeneous sources. Water Res. 37(4):953–958. 10.1016/S0043-1354(02)00411-6 12531279
Von Tungeln LS, Yi P, Bucci TJ, Samokyszyn VM, Chou MW, Kadlubar FF, Fu PP. 2002. Tumorigenicity of chloral hydrate, trichloroacetic acid, trichloroethanol, malondialdehyde, 4-hydroxy-2-nonenal, crotonaldehyde, and acrolein in the B6C3F(1) neonatal mouse. Cancer Lett. 185(1):13–19. 10.1016/S0304-3835(02)00231-8 12142074
Walgren JE, Kurtz DT, McMillan JM. 2000 a. The effect of the trichloroethylene metabolites trichloroacetate and dichloroacetate on peroxisome proliferation and DNA synthesis in cultured human hepatocytes. Cell Biol Toxicol. 16(4):257–273. 10.1023/A:1007638227821 11101007
Walgren JE, Kurtz DT, McMillan JM. 2000 b. Expression of PPARα in human hepatocytes and activation by trichloroacetate and dichloroacetate. Res Commun Mol Pathol Pharmacol. 108(1-2):116–132. 11758968
Walgren JL, Jollow DJ, McMillan JM. 2004. Induction of peroxisome proliferation in cultured hepatocytes by a series of halogenated acetates. Toxicology. 197(3):189–197. 10.1016/j.tox.2004.01.007 15033542
Walgren JL, Kurtz DT, McMillan JM. 2005. Lack of direct mitogenic activity of dichloroacetate and trichloroacetate in cultured rat hepatocytes. Toxicology. 211(3):220–230. 10.1016/j.tox.2005.03.009 15925025
Wang S, Zheng W, Liu X, Xue P, Jiang S, Lu D, Zhang Q, He G, Pi J, Andersen ME, et al. 2014. Iodoacetic acid activates Nrf2-mediated antioxidant response in vitro and in vivo. Environ Sci Technol. 48(22):13478–13488. 10.1021/es502855x 25332096
Wei J, Ye B, Wang W, Yang L, Tao J, Hang Z. 2010. Spatial and temporal evaluations of disinfection by-products in drinking water distribution systems in Beijing, China. Sci Total Environ. 408(20):4600–4606. 10.1016/j.scitotenv.2010.06.053 20663540
Wei X, Wang S, Zheng W, Wang X, Liu X, Jiang S, Pi J, Zheng Y, He G, Qu W. 2013. Drinking water disinfection byproduct iodoacetic acid induces tumorigenic transformation of NIH3T3 cells. Environ Sci Technol. 47(11):5913–5920. 10.1021/es304786b 23641915
Weinberg HS, Krasner SW, Richardson SD, Thruston AD Jr.2002. The occurrence of disinfection by-products (DBPs) of health concern in drinking water: Results of a nationwide DBP occurrence study. Athens, GA: U.S. Environmental Protection Agency. EPA 600/R-02/068
Werner D, Valdivia-Garcia M, Weir P, Haffey M. 2016. Trihalomethanes formation in point of use surface water disinfection with chlorine or chlorine dioxide tablets. Water Environ J. 30:271–277.10.1111/wej.12209
Wood CE, Hester SD, Chorley BN, Carswell G, George MH, Ward W, Vallanat B, Ren HZ, Fisher A, Lake AD, et al. 2015. Latent carcinogenicity of early-life exposure to dichloroacetic acid in mice. Carcinogenesis. 36(7):782–791. 10.1093/carcin/bgv057 25913432
Wright JM, Murphy PA, Nieuwenhuijsen MJ, Savitz DA. 2006. The impact of water consumption, point-of-use filtration and exposure categorization on exposure misclassification of ingested drinking water contaminants. Sci Total Environ. 366(1):65–73. 10.1016/j.scitotenv.2005.08.010 16126253
Xu G, Stevens DK, Bull RJ. 1995. Metabolism of bromodichloroacetate in B6C3F1 mice. Drug Metab Dispos. 23(12):1412–1416. 8689953
Xu X, Mariano TM, Laskin JD, Weisel CP. 2002. Percutaneous absorption of trihalomethanes, haloacetic acids, and haloketones. Toxicol Appl Pharmacol. 184(1):19–26. 10.1006/taap.2002.9494 12392965
Yu KO, Barton HA, Mahle DA, Frazier JM. 2000. In vivo kinetics of trichloroacetate in male Fischer 344 rats. Toxicol Sci. 54(2):302–311. 10.1093/toxsci/54.2.302 10774812
Zhai H, Zhang X. 2011. Formation and decomposition of new and unknown polar brominated disinfection byproducts during chlorination. Environ Sci Technol. 45(6):2194–2201. 10.1021/es1034427 21323365
Zhang JY, Zhang F, Hong CQ, Giuliano AE, Cui XJ, Zhou GJ, Zhang GJ, Cui YK. 2015 a. Critical protein GAPDH and its regulatory mechanisms in cancer cells. Cancer Biol Med. 12(1):10–22. 10.7497/j.issn.2095-3941.2014.0019 25859407
Zhang L, Xu L, Zeng Q, Zhang SH, Xie H, Liu AL, Lu WQ. 2012. Comparison of DNA damage in human-derived hepatoma line (HepG2) exposed to the fifteen drinking water disinfection byproducts using the single cell gel electrophoresis assay. Mutat Res. 741(1-2):89–94. 10.1016/j.mrgentox.2011.11.004 22108252
Zhang SH, Miao DY, Liu AL, Zhang L, Wei W, Xie H, Lu WQ. 2010. Assessment of the cytotoxicity and genotoxicity of haloacetic acids using microplate-based cytotoxicity test and CHO/HGPRT gene mutation assay. Mutat Res. 703(2):174–179. 10.1016/j.mrgentox.2010.08.014 20801231
Zhang SH, Miao DY, Tan L, Liu AL, Lu WQ. 2016. Comparative cytotoxic and genotoxic potential of 13 drinking water disinfection by-products using a microplate-based cytotoxicity assay and a developed SOS/umu assay. Mutagenesis. 31(1):35–41. 10.1093/mutage/gev053 26188195
Zhang X, Bull RJ, Fisher J, Cotruvo JA, Cummings BS. 2011. The synergistic effect of sodium chlorite and bromochloroacetic acid on BrO3(-)-induced renal cell death. Toxicology. 289(2-3):151–159. 10.1016/j.tox.2011.08.008 21864635
Zhang X, Echigo S, Minear RA, Plewa MJ. 2000. Characterization and comparison of disinfection by-products of four major disinfectants. In: Barrett SE, Krasner SW, Amy GL, editors. Natural Organic Matter and Disinfection By-Products. Washington, DC: American Chemical Society; p. 299–314. 10.1021/bk-2000-0761.ch019
Zhang YQ, Wu QP, Zhang JM, Yang XH. 2015 b. Removal of bromide and bromate from drinking water using granular activated carbon. J Water Health. 13(1):73–78. 10.2166/wh.2014.084 25719467