# Introduction

Water disinfection is among the most important and beneficial public health advances of the 20th century and has substantially reduced the United States incidences of cholera, typhoid, and amoebic dysentery caused by waterborne pathogens (Richardson et al. 2007). According to the U.S. Environmental Protection Agency (EPA), over 48,000 U.S. public water systems provide disinfected water to more than 250 million people, while 10% to 15% of the U.S. population uses private groundwater wells that are typically not disinfected (USEPA 2005; 2015a; 2015b). In addition, swimming pools and spas use on-site chlorination or bromination of water for disinfection. A consequence of the water disinfection process is the formation of a large number of unintended compounds from chemicals and organic material in the water; these unintended chemicals are of potential public health concern (IPCS 2000). Reports have put the number at over 500 chemicals, and identification of more by-products is ongoing. Haloacetic acids (HAAs) and trihalomethanes (THMs) are the largest groups of water disinfection by-products by weight and make up about 50% to 75% of total halogenated disinfection by-products measured and about 25% to 50% of total organic halides measured (Krasner et al. 2016a; Krasner et al. 2006). Two of four EPA-regulated trihalomethanes, chloroform and bromodichloromethane, are listed in the RoC as reasonably anticipated to be a human carcinogen. Over 30 different forms of haloacetic acids are chemically possible, including iodinated and fluorinated forms. Some of these halogen-substituted acetic acids have been identified in drinking water and five are regulated by USEPA (2010).

The Office of the Report on Carcinogens (ORoC) has evaluated mono-, di-, and trihaloacetic acids identified in drinking water for possible listing in the RoC. The haloacetic acids evaluated consist of nine chlorine and bromine-containing mono-, di-, or trihaloacetic acids either regulated by EPA or being considered for regulation and four iodine-containing acetic acids for a total of 13 haloacetic acids (see Properties section for a list of the HAAs evaluated). As part of the evaluation, ORoC assessed whether some or all of these chemicals can be considered members of a class of carcinogens or if they should be considered separately. It is known that the type and proportion of haloacetic acids formed differ with different disinfection processes and water sources. In addition, some haloacetic acids in drinking water that are not monitored or regulated may have health consequences. It is important to review the haloacetic acid chemical group for carcinogenicity and identify chemicals that may be cancer hazards as this information can help to inform public health decisions on water regulations and on water disinfection processes.

As per the process for preparation of the Report on Carcinogens (RoC), the Office of the RoC released a draft concept document for “Haloacetic Acids (HAAs) Found as Water Disinfection By-products,” which outlined the rationale and proposed the approach for their review, for public comment. ORoC also presented the draft to the NTP Board of Scientific Counselors (BSC) at the April 11, 2016 meeting, which provided opportunity for written and oral public comments. Subsequent to the meeting, the concept was finalized and HAAs were approved by the NTP Director as a candidate substance for review. The concept document is available on the RoC website ([underlined: https://ntp.niehs.nih.gov/go/790113]).

At an Information Group Meeting on HAAs at NIEHS on September 9, 2016, input from scientific experts on water disinfection by-products and cancer mechanisms was requested early in the review process. The approach to evaluation of individual HAAs and data needs were discussed for evaluation of physicochemical, mechanistic, and cancer endpoints. A “read-across” approach (see Section 7 for discussion of this approach), based on available data for the HAAs (classified by the number of halogen substitutions [e.g., mono-, di-, or tri-] or type of halogen substitution [e.g., chlorine, bromine, and iodine]), to determine if haloacetic acids could be evaluated as a chemical class, or subclass(es), was considered. Technical advisors for the review of HAAs Found as Water Disinfection By-products are identified on the “About This Report” page of this monograph.

Public comments on scientific issues were requested at several times prior to the development of the RoC monograph, including the request for information on the nomination, and the request for comment on the draft concept document, which outlined the rationale and approach for conducting the scientific review. In addition, NTP posted its protocol for preparing the draft RoC monograph on Haloacetic Acids Found as Water Disinfection By-products for public input on the ORoC website at https://ntp.niehs.nih.gov/go/790113 prior to the release of the draft monograph.