# Appendix D Oxidative Stress and Genotoxic Potency Data for Haloacetic Acids

Table D-1 In Vitro and In Vivo Haloacetic Acid-induced Oxidative Stress

Test System (Potency Measurement, Units) | Monohaloacetic Acids | | | Dihaloacetic Acids | | | | | Trihaloacetic Acids
Test System (Potency Measurement, Units) | CA | BA | IA | DCA | DBA | BCA | CIA | BIA | TCA | TBA | BDCA | CDBA | Reference
AREc32: human breast cancer cell line (MCF7) (1/mM, IR = 1.5) | 3.7 | 192 | 278 | 0.17 | 8.3 | 7.1 | 45.5 | 38.5 | – | 2.3 | 0.5 | 0.2 | Stalter et al. (2016a)
ARE-bla: human hepatocellular carcinoma cell line (HepG2) (1/mM, IR = 1.5) | 4.0 | 90.9 | 196 | 0.06 | 4.0 | 2.2 | 10 | 18.9 | – | 1.5 | 0.25 | 0.46 | Stalter et al. (2016a)
ARE-bla: human hepatocellular carcinoma cell line (HepG2) (1/mM, IR = 1.5) | 14 | 141 | 256 | – | – | – | – | – | – | – | – | – | Procházka et al. (2015)
ARE-bla: human hepatocellular carcinoma cell line (HepG2) (1/mM, IR = 1.5) | 116 | 510 | 1,010 | – | – | – | – | – | – | – | – | – | Pals et al. (2013)
Lipid peroxidation; male mice, single 300 mg/kg oral dose TBARS (nmol/g liver, wet wt) | – | – | – | 129 | 250^a^ | 290^a^ | – | – | 67 | – | 240^a^ | – | Austin et al. (1996); Larson and Bull (1992)
Oxidative DNA damage; male mice, single 300 mg/kg oral dose (8-OHdG/10^5^ dG liver) | – | – | – | 1.4^a^ | 2.9^a^ | 2.9^a^ | – | – | 1.2^a^ | – | 1.7^a^ | – | Austin et al. (1996)
Oxidative DNA damage; male mice, 21 day water– 0.5 and 2 g/L (8-OHdG/10^5^ dG liver) | – – | – – | – – | – – | 1.4^a^ 1.8^a^ | 1.2^a^ 1.6^a^ | – – | – – | – – | – – | – – | – – | Parrish et al. (1996)

CA = chloro-, BA = bromo-, IA = iodo-, DCA = dichloro-, DBA = dibromo-, BCA = bromochloro-, CIA = chloroiodo-, BIA = bromoiodo-, TCA = trichloro-, TBA = tribromo-, BDCA = bromodichloro-, CDBA = chlorodibromoacetic acid, mM = millimolar, IR = induction ratio, TBARS = thiobarbituric acid-reactive substances, 8-OHdG = 8-hydroxydeoxyguanosine, – = negative, blank cell = not tested.

^a^ Values estimated from figures using WebPlot Digitizer @ https://arohatgi.info/WebPlotDigitizer/app/.

Table D-2 Summary of Genetic Toxicology Results of Haloacetic Acids in CEBs

Haloacetic Acid | Study Type | Results | URL
Chloro- | Ames | – | https://tools.niehs.nih.gov/cebs3/ntpViews/?studyNumber=002-02485-0003-0000-4
Chloro- | Ames | – | https://tools.niehs.nih.gov/cebs3/ntpViews/?studyNumber=002-02485-0004-0000-5
Chloro- | Mammalian cell cytogenetics (CA) | – | https://tools.niehs.nih.gov/cebs3/ntpViews/?studyNumber=002-02485-0002-0000-3
Chloro- | Mammalian cell cytogenetics (SCE) | + | https://tools.niehs.nih.gov/cebs3/ntpViews/?studyNumber=002-02485-0001-0000-2
Chloro- | Mammalian cell mutagenicity | + | https://tools.niehs.nih.gov/cebs3/ntpViews/?studyNumber=002-02485-0010-0000-2
Chloro- | Drosophila germ cell mutagenicity | E | https://tools.niehs.nih.gov/cebs3/ntpViews/?studyNumber=002-02485-0009-0000-0
Bromo- | Ames | + | https://tools.niehs.nih.gov/cebs3/ntpViews/?studyNumber=002-01737-0001-0000-1
Bromo- | Ames | + | https://tools.niehs.nih.gov/cebs3/ntpViews/?studyNumber=002-01737-0002-0000-2
Iodo- | Ames | E | https://tools.niehs.nih.gov/cebs3/ntpViews/?studyNumber=002-02289-0001-0000-4
Iodo- | Ames | (+) | https://tools.niehs.nih.gov/cebs3/ntpViews/?studyNumber=002-02289-0002-0000-5
Iodo- | Drosophila germ cell mutagenicity | – | https://tools.niehs.nih.gov/cebs3/ntpViews/?studyNumber=002-02289-0003-0000-6
Dichloro- | Ames | + | https://tools.niehs.nih.gov/cebs3/ntpViews/?studyNumber=002-02007-0008-0000-9
Dichloro- | Ames | + | https://tools.niehs.nih.gov/cebs3/ntpViews/?studyNumber=002-02007-0009-0000-0
Dichloro- | Male mice (micronucleus) Female mice (micronucleus) | – – | https://tools.niehs.nih.gov/cebs3/ntpViews/?studyNumber=002-02007-0004-0000-5
Dichloro- | Male mice (micronucleus) Female mice (micronucleus) | – – | https://tools.niehs.nih.gov/cebs3/ntpViews/?studyNumber=002-02007-0006-0000-7
Dichloro- | Male mice (micronucleus) Female mice (micronucleus) | – – | https://tools.niehs.nih.gov/cebs3/ntpViews/?studyNumber=002-02007-0007-0000-8
Dichloro- | Male mice (micronucleus) Female mice (micronucleus) | – + | https://tools.niehs.nih.gov/cebs3/ntpViews/?studyNumber=002-02007-0005-0000-6
Dibromo- | Ames | + | https://tools.niehs.nih.gov/cebs3/ntpViews/?studyNumber=002-01996-0006-0000-3
Dibromo- | Male mice (micronucleus) Female mice (micronucleus) | + – | https://tools.niehs.nih.gov/cebs3/ntpViews/?studyNumber=002-01996-0005-0000-2
Bromochloro- | Ames | + | https://tools.niehs.nih.gov/cebs3/ntpViews/?studyNumber=002-01740-0005-0000-9
Bromochloro- | Ames | + | https://tools.niehs.nih.gov/cebs3/ntpViews/?studyNumber=002-01740-0006-0000-0
Bromochloro- | Male mice (micronucleus) Female mice (micronucleus) | – – | https://tools.niehs.nih.gov/cebs3/ntpViews/?studyNumber=002-01740-0004-0000-8
Trichloro- | Ames | – | https://tools.niehs.nih.gov/cebs3/ntpViews/?studyNumber=002-02942-0001-0000-0
Tribromo- | Ames | + | https://tools.niehs.nih.gov/cebs3/ntpViews/?studyNumber=002-02933-0002-0000-1
Bromodichloro- | Ames | + | https://tools.niehs.nih.gov/cebs3/ntpViews/?studyNumber=002-01742-0018-0000-5
Bromodichloro- | Ames | (+) | https://tools.niehs.nih.gov/cebs3/ntpViews/?studyNumber=002-01742-0004-0000-0
Bromodichloro- | Male mice (micronucleus) Female mice (micronucleus) | – – | https://tools.niehs.nih.gov/cebs3/ntpViews/?studyNumber=002-01742-0003-0000-9

– = negative, (+) = weak positive, + = positive, E = equivocal.

Table D-3 Mutagenic/Genotoxic Potency Estimates of Haloacetic Acids in Bacteria

Test System (Potency Measurement, Units) | Monohaloacetic Acids | | | Dihaloacetic Acids | | | | | | Trihaloacetic Acids | | | | Reference
Test System (Potency Measurement, Units) | CA | BA | IA | DCA | DBA | BCA | CIA | BIA | TCA | | TBA | BDCA | CDBA
SOS-umuC: TA1535/pSK1002 − S9 (1/M, IR = 1.5) + S9 (1/M, IR = 1.5) | –^a^ –^a^ | –^a^ –^a^ | –^a^ –^a^ | – – | 2,564 1,493 | 2,941 1,064 | 5,263 2,083 | 9,091 11,490 | – – | | 142,860 13,890 | 9,091 455 | 9,091 625 | Stalter et al. (2016a)
SOS-umuC: TA1535/pSK1002 − S9 (1/M, IR = 2) − S9 (1/M, IR = 1.5) | (+) 60^b^ | 1,107 2,400^b^ | 8,696 15,400^b^ | 83 180^b^ | 89 760^b^ | – – | – – | – – | (+) 60^b^ | | – – | – – | – – | Zhang et al. (2016)
SOS-umuC: TA1535/pSK1002 − S9 (β-galactosidase activity)^c^ + S9 (β-galactosidase activity)^c^ | – – | – – | – – | neg 1.5 | – – | – – | – – | – – | 0.72 1.18 | | – – | – – | – – | Ono et al. (1991)
Ames preincubation: TA100 − S9 (revertants/μmol) | 27 | 5,465 | 14,129 | – | 148 | – | – | – | – | | – | – | – | Plewa et al. (2000); Plewa et al. (2004b)
Ames preincubation: TA100 − S9 (revertants/μmol)^d^ + S9 (revertants/μmol)^d^ | 44 63 | 6,588 2,642 | – – | 36 13 | 183 165 | – – | – – | – – | – – | | – – | – – | – – | Kargalioglu et al. (2002)
Ames preincubation: TA98 − S9 (revertants/μmol)^d^ + S9 (revertants/μmol)^d^ | 6 – | 351 179 | – – | 2 – | 16 12 | – – | – – | – – | – – | | – – | – – | – – | Kargalioglu et al. (2002)
Ames preincubation: RSJ100 − S9 (revertants/μmol)^d^ + S9 (revertants/μmol)^d^ | – – | – – | – – | 17 – | – – | – – | – – | – – | – – | | – – | – – | – – | Kargalioglu et al. (2002)
SOS chromotest: E. coli PQ37 − S9 (1/(mg/mL), IR = 1.5) + S9 (1/(mg/mL), IR = 1.5) | – – | – – | – – | 2 – | 5 10 | – – | – – | – – | – – | | 1.3 10 | – – | – – | Giller et al. (1997)
Ames fluctuation: TA100 − S9 (1/[mg/mL]) + S9 (1/[mg/mL]) | – – | – 50 | – – | 10 0.67 | 100 33 | – – | – – | – – | 0.57 0.33 | | 0.5 0.2 | – – | – – | Giller et al. (1997)

CA= chloro-, BA = bromo-, IA = iodo-, DCA = dichloro-, DBA = dibromo-, BCA = bromochloro-, CIA = chloroiodo-, BIA = bromoiodo-, TCA = trichloro-, TBA = tribromo-, BDCA = bromodichloro-, CDBA = chlorodibromoacetic acid, M = molar, IR = induction ratio, –S9 = without metabolic activation, +S9 = with metabolic activation, – = negative, (+) = weak positive but no potency value reported, blank cell = not tested.

^a^ Likely a false negative due to cytotoxicity.

^b^ Potency values at an induction ratio of 1.5 were estimated from figures using WebPlot Digitizer @ https://arohatgi.info/WebPlotDigitizer/app/.

^c^ Calculated as [(A-B)/B] where A = the β-galactosidase activity of the test agent and B is the baseline activity (<0.5, negative; >0.5-1.0, weak positive; >1.0-2.0, positive).

^d^ Values adjusted for cytotoxicity.

Table D-4 Mutagenic/Genotoxic Potency Estimates of Haloacetic Acids in Mammalian Cells

Test System (Potency Measurement, Units) | Monohaloacetic Acids | | | Dihaloacetic Acids | | | | | Trihaloacetic Acids | | | | Reference
Test System (Potency Measurement, Units) | CA | BA | IA | DCA | DBA | BCA | CIA or (DIA) | BIA | TCA | TBA | BDCA | CDBA | Reference
p53-bla: human colon carcinoma cell line HCT-116 (1/M, IR = 1.5) | 5,882 | 105,260 | 212,770 | – | 3,846 | 4,348 | 9,091 | 9,091 | – | – | – | – | Stalter et al. (2016a)
SCGE: CHO AS52 cells LGC (1/M) GP (1/M) | 3,333 2,439 | 76,920 58,820 | 200,000 114,900 | – – | 1,333 556 | 333 333 | (1,000) (500) | 400 313 | – – | 333 400 | – – | 71 71 | Plewa et al. (2002); Plewa et al. (2010); Plewa et al. (2004b); Richardson et al. (2008)
SCGE: CHO AS52 cells (tail moment units/μmol) | – | 68,900 | – | – | 887 | – | – | – | – | 254 | – | – | Plewa et al. (2000)
HGPRT mutations: CHO-K1 cells (mutant frequency/mM) | 8.7 | 14.6 | 835.9 | 2.8 | 66.2 | – | – | – | – | – | – | – | Zhang et al. (2010)
SCGE assay: HepG2 cells MEC (1/μM) | – | 10 | 100 | 0.1 | 1 | – | – | – | 0.01 | – | – | – | Zhang et al. (2012)
p53-bla: human colon carcinoma cell line HCT-116 (1/M, IR = 1.5) | 10,000 | 98,039 | 156,250 | – | – | – | – | – | – | – | – | – | Procházka et al. (2015)
SCGE: human lymphocytes GP (1/mM) | 1.2 | 83 | 96 | – | – | – | – | – | – | – | – | – | Escobar-Hoyos et al. (2013)
Mitotic index: human lymphocytes EC_50_ (1/mM) | 1.4 | 12.7 | 20.3 | – | – | – | – | – | – | – | – | – | Escobar-Hoyos et al. (2013)
SCGE: human small intestine epithelial cells EC_50_ (1/mM) | 0.29 | 17.7 | 45.7 | – | – | – | – | – | – | – | – | – | Attene-Ramos et al. (2010)

CA= chloro-, BA = bromo-, IA = iodo-, DCA = dichloro-, DBA = dibromo-, BCA = bromochloro-, CIA = chloroiodo-, DIA = diiodo-, BIA = bromoiodo-, TCA = trichloro-, TBA = tribromo-, BDCA = bromodichloro-, CDBA = chlorodibromoacetic acid, M = molar, IR = induction ratio, SCGE = single cell gel electrophoresis or comet assay, – = negative, LGC = lowest genotoxic concentration, GP = genotoxic potency (calculated using regression analysis as the midpoint of the curve within the concentration range that expressed above 70% cell viability), MEC = minimum effective concentration, EC50 = effective concentration that reduced the mitotic index by 50% or induced average SCGE damage of 50% tail DNA, blank cell = not tested.

Table D-5 Epigenetic Effects of Haloacetic Acids in Mouse and Rat Tissues

Species (sex) | Tissue | HAA | Conc (g/L) | Hypomethylation | | Comments | Reference
Species (sex) | Tissue | HAA | Conc (g/L) | DNA (% Reduction)^a^ | Genes | Comments | Reference
Mice (M,F) | Kidney | DCA TCA | 3.2 4.0 | 40 65 | c-myc | Mice treated for 7 days. Unlike the liver, effects in kidney only in males. c-myc hypomethylation prevented by treatment with methionine. | Tao et al. (2005)
Mice (M) Rats (M) | Kidney | DBA | 1–2 | 40–60 45–56 | c-myc | High dose caused reduction at 7 days and 28 days; at low dose, significant reduction only after 28 days. | Tao et al. (2005)
Mice (F) Rats (M) | Liver | DBA | 1–2 | 45–70 33–52 | c-myc, IGF-II | Both doses caused significant reduction after 7 and 28 days. mRNA expression of c-myc and IGF-II genes significantly increased in mice and c-myc expression increased in rats. | Tao et al. (2004a)
Mice (F) | Liver Liver tumors | DCA TCA | 2.6^b^ 3.3^b^ | 27–85 27–85 | IGF-II | Hypomethylation status in DCA- and TCA-promoted liver tumors that were initiated by MNU and in normal liver. Both compounds caused the same reduction in liver and liver tumor DNA (estimated from a figure) but there was significantly greater reduction in liver tumors compared to normal liver tissue. 79.3% of 28 CpG sites in the promoter region of the IGF-II gene were methylated in control mouse liver compared to 46.4% and 58% in normal liver and 8.7% and 10.7% in liver tumors of DCA- and TCA-treated mice, respectively. IGF-II expression was increased 4.5- to 5.1-fold in tumors compared to normal liver. | Tao et al. (2004b)
Mice (F) | Liver | DCA TCA | 500 mg/kg 500 mg/kg | NR | c-jun, c-myc | Single gavage dose administered daily for 5 days. Treatment with methionine prevented hypomethylation. | Tao et al. (2000a)
Mice (F) | Liver Liver tumors | DCA TCA | 2.6^b^ 3.3^b^ | NR | c-jun, c-myc | mRNA expression and protein levels of c-myc and c-jun were increased in DCA- and TCA-promoted liver tumors but not normal tissue. DNA methyltransferase (MTase) activity increased in liver tumors promoted by DCA and TCA (greater effect for DCA) but decreased in normal liver. Increased MTase activity is associated with silencing tumor suppressor genes. | Tao et al. (2000b)
Mice (F) | Liver Liver tumors | DCA TCA | 3.2^b^ 4.0^b^ | 36^c^ 40–51^c^ | NR | Hypomethylation status was measured in DCA- and TCA-promoted liver tumors that were initiated by MNU and in normal liver. Hypomethylation in normal liver was observed after 11 days but not after 44 weeks. Methylation status in adenomas also returned to normal with termination of DCA exposure 1 week prior to sacrifice but not with TCA. | Tao et al. (1998)
Mice (F) | Liver Liver tumors | DCA | 3.2 | 55 | NR | Mice sacrificed after 8 or 44 weeks of exposure. Methionine treatment prevented hypomethylation, reduced DCA-induced tumor multiplicity, and slowed the progression of foci to tumors. (Hypomethylation estimated from a figure in the paper with results after 8-weeks exposure.) | Pereira et al. (2004a)
Mice (F) | Liver Kidney | DCA TCA | 500 mg/kg 500 mg/kg | NR | c-myc | Single gavage dose administered daily for 5 days. Both DCA and TCA induced hypomethylation and expression of c-myc in liver. Co-administration of chloroform prevented DCA- but not TCA-induced hypomethylation. In a second experiment, chronic administration of TCA in the drinking water promoted kidney tumors. DCA also promoted kidney tumors when co-administered with chloroform. | Pereira et al. (2001)
Mice (F) | Liver Kidney Bladder | DCA TCA | 500 mg/kg 500 mg/kg | NR | c-myc | Hypomethylation of the promoter region of c-myc in liver, kidney, and urinary bladder occurred after 72 and 96 hours (but not at earlier time points) after a single gavage dose of either DCA or TCA. Enhanced cell proliferation in the liver also reported after 72 and 96 hours. | Ge et al. (2001)

HAA = haloacetic acid, DCA = dichloroacetic acid, DBA = dibromoacetic acid, TCA = trichloroacetic acid, MNU = N-methyl-N-nitrosourea, IGF-II = insulin-like growth factor-II, NR = not reported.

^a^ % Reduction in 5-methylcytosine compared to control DNA.

^b^ Converted from 20 mmol/L or 25 mmol/L, MW DCA = 128.9, TCA = 163.4, administered in drinking water for 44 to 46 weeks beginning at 6 weeks of age.

^c^ Reduction in liver tumors compared to normal liver tissue from the same animal. TCA promoted both adenomas and carcinomas, DCA only adenomas.

Table D-6 Gene Expression Studies of Di- and Trihaloacetic Acids in Yeast and Rodent Tissue

Haloacetic Acid | Test System | Results | Reference
Dichloro- | Mouse normal liver (4 wk treatment) and liver tumors induced by dichloroacetic acid after 93 weeks | Normal liver: 15 genes differentially expressed (14 were suppressed) in the functional categories of cell growth, tissue remodeling, apoptosis, cancer progression, fatty acid metabolism, and xenobiotic metabolism. Hepatocellular carcinomas: 11 of the same 15 genes showed a similar expression pattern as in normal liver from exposed mice. | Thai et al. (2003)
Dichloro- | Mouse normal liver (4 wk treatment) and liver tumors induced by dichloroacetic acid after 93 weeks | Normal liver: Six differentially expressed genes (5 were suppressed; one gene was induced) involved in fatty acid metabolism, tissue remodeling and tumor invasion. No altered genes identified that are involved in genotoxicity pathways. Hepatocellular carcinomas: Four genes showed similar expression pattern as in normal liver from exposed mice. | Thai et al. (2001)
Dichloro- | Rat normal liver (i.p. injection) | One gene with 50% homology to a mouse fibroblast growth factor mRNA identified and might be involved in hepatocellular proliferation and DNA synthesis. | Choi and Park (1996)
Dichloro- Trichloro- | Mouse liver tumors (chronic exposure) | Hyperplastic nodules and hepatocellular carcinomas: Increased expression of c-myc and c-H-ras compared to surrounding tissue or controls in both preneoplastic nodules and carcinomas. Myc expression was similar in DCA-induced nodules and carcinomas. However, myc expression in TCA-induced tumors was significantly higher than in DCA-induced nodules and tumors and appeared to be related to the early progression of TCA-induced tumors to a malignant state. c-H-ras expression was higher in carcinomas from both treatments than in hyperplastic nodules or normal liver, thus, was closely associated with malignancy. | Nelson et al. (1990)
Trichloro- | Green-fluorescent protein (GFP)-tagged yeast reporter strains | Activated DNA repair pathways suggested strong base damage, mismatches and double-strand breaks. Damage was consistent with oxidative DNA damage. | Lan et al. (2016)
Bromodichloro- | Mouse: normal liver tissue and tumors (chronic exposure) | Nontumor liver tissue from treated mice: Altered oncogenic, metabolic, and hepatic function-related pathways. The top differentially expressed genes were involved in cell growth and proliferation, neoplasia, and transcriptional regulation. Hepatocellular carcinomas: Dysregulated metabolic and cancer-related pathways including cell movement, growth, development, and proliferation; cancer signaling, fatty acid metabolism, cell cycle regulation, apoptosis signaling, upregulation of oncogenes, and downregulation of tumor suppressor genes. Hepatoblastomas: Markedly different from adjacent hepatocellular carcinomas and normal liver with upregulation of oncogenic signaling pathways (especially Wnt/Ctnnb1-pathway related genes), reduced hepatic metabolic function, upregulation of stem/pluripotent progenitor cell genes and stem cell-related target genes, and upregulation of genomic imprinting genes. | NTP (2015)
Bromodichloro- | Rat: normal mammary tissue and tumors (chronic exposure) | Mammary adenocarcinomas: Eight genes significantly upregulated. Five associated with Tgfß pathway signaling, including its effects on matrix remodeling, mammary gland cancer progression, angiogenesis, tumor invasion, and metastasis. | NTP (2015)
Bromochloro- | Rat: peritoneal mesothelioma (chronic exposure) | Mesotheliomas: 169 cancer-related genes differentially expressed and were categorized into binding activity, cell growth and proliferation, cell cycle progression, apoptosis, invasion, and metastasis. Important carcinogenic pathways involved in rat peritoneal mesothelioma development included insulin-like growth factor-1 (IGF-1), p38 MAPK, Wnt/ß-catenin, and integrin signaling and are similar to mesotheliomas in humans. | Kim et al. (2006)
Bromochloro- | Mouse sperm (daily treatment for 14 days) | Testes-expressed genes: 40 genes with altered expression involved in cell communication and adhesion, cell cycle and cell proliferation, metabolism, signal transduction, stress response, spermatogenesis, and male fertility. | Tully et al. (2005)

Figure D-1

Palmitoyl-CoA Oxidation in Cultured Rat Hepatocytes Exposed to Haloacetic Acids

Source: Walgren et al. (2004) (used by permission from Elsevier Ireland Ltd., License No. 4061470820696).

A = monohaloacetic acids: monoiodo- (MIA), monobromo- (MBA), and monochloroacetic acid (MCA); B = dihaloacetic acids: dibromo- (DBA) and dichloroacetic acid (DCA); C = trihaloacetic acids: trichloro- (TCA) and tribromoacetic acid (TBA).