# Appendix C Animal Studies

## C.1 Monochloroacetic Acid: Study Quality for Animal Studies

Table C-1 NTP 1992 (M Mouse): Monochloroacetic Acid: Gavage

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups.
Controls | +++ Concurrent vehicle controls were used.
Historical data | Yes
Animal model (sensitivity) | +++ Both sexes of non-transgenic animals were used.
Statistical power (sensitivity) | +++ Large numbers of animals (50) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | ++^a^ There was no significant difference in survival and body weight was not significantly decreased. There was a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | +++ A near life-span duration (106 weeks) was used.
Dose-response (sensitivity) | ++^a^ Three exposure levels were used that spanned a range of 20-fold.
Outcome
Pathology | +++ All major organs and gross lesions were histologically evaluated and findings were verified by an independent pathologist.
Consistency between groups | +++ All groups were treated the same.
Study duration (sensitivity) | +++ A near life-span duration (106 weeks) was used.
Confounding
Confounding | ++[underlined: +]^b^ Drinking water contained 44.7 ug/l of dihaloacetic acids and 3.8 ug/l of dibromoacetic acid.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Tumor combinations were appropriate.

Overall utility: +++. Large numbers of animals per group were used in both sexes and were continuously monitored for disease. Three dose levels spanning a range of 200-fold were used. Lesions and all major organs were histologically evaluated and statistics were clearly reported.

^a^ ERRATUM: Errors were identified in the Report on Carcinogens Monograph on Haloacetic Acids Found as Water Disinfection By-products. The number of + signs was incorrect in the original table. These errors have been corrected; one + sign was removed.

^b^ ERRATUM: Errors were identified in the Report on Carcinogens Monograph on Haloacetic Acids Found as Water Disinfection By-products. The number of + signs was incorrect in the original table. These errors have been corrected; one + sign was added and underlined.

Table C-2 NTP 1992 (F Mouse): Monochloroacetic Acid: Gavage

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups.
Controls | +++ Concurrent vehicle controls were used.
Historical data | Yes
Animal model (sensitivity) | +++ Both sexes of non-transgenic animals were used.
Statistical power (sensitivity) | +++ Large numbers of animals (50) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | +++ There was no significant difference in survival or body weight. There was a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | +++ A near life-span duration (106 weeks) was used.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 20-fold.
Outcome
Pathology | +++ All major organs and gross lesions were histologically evaluated and findings were verified by an independent pathologist.
Consistency between groups | +++ All groups were treated the same.
Study duration (sensitivity) | +++ A near life-span duration (106 weeks) was used.
Confounding
Confounding | ++ Drinking water contained 44.7 ug/l of dihaloacetic acids and 3.8 ug/l of dibromoacetic acid.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Tumor combinations were appropriate.

Overall utility: +++. Large numbers of animals per group were used in both sexes and were continuously monitored for disease. Three dose levels spanning a range of 200-fold were used. Lesions and all major organs were histologically evaluated and statistics were clearly reported.

Table C-3 NTP 1992 (M Rat): Monochloroacetic Acid: Gavage

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups.
Controls | +++ Concurrent vehicle controls were used.
Historical data | Yes
Animal model (sensitivity) | ++ Both sexes of non-transgenic animals were used and the strain is in common use. Rats were more sensitive to monochloroacetic acid non-neoplastic effects, causing death and cardiomyopathy during the short term studies, compared to mice and so their dose levels were much lower.
Statistical power (sensitivity) | +++ The numbers of animals (50 at 104 weeks and 10 at 6 and 15 months) varied considerably for each group depending on the time of sacrifice.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | ++ There was a significant decrease in survival but not in body weight. There was no significant increase in neoplasm incidence. Rats were more sensitive to non-neoplastic effects, causing death and cardiomyopathy during the short term studies, compared to mice and so their dose levels were much lower.
Exposure duration (sensitivity) | +++ A near life-span duration (104 weeks) was used.
Dose-response (sensitivity) | ++ Two exposure levels were used that spanned a range of 2-fold, making the detection of a dose response limited.
Outcome
Pathology | +++ All major organs and gross lesions were histologically evaluated and findings were verified by an independent pathologist.
Consistency between groups | +++ All groups were treated the same.
Study duration (sensitivity) | +++ A near life-span duration (104 weeks) was used.
Confounding
Confounding | +++ The test agent was well characterized, animals were treated the same between groups, and were continually monitored for infectious diseases.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Tumor combinations were appropriate.

Overall utility: ++. The study was well conducted to rule out confounding and with a strong power to detect tumor induction. However, only two exposed dose levels were tested, which limit the detection of dose response relationships. Rats were more sensitive to non-neoplastic effects, causing death and cardiomyopathy during the short term studies, compared to mice and so their dose levels were much lower.

Table C-4 NTP 1992 (F Rat): Monochloroacetic Acid: Gavage

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups.
Controls | +++ Concurrent vehicle controls were used.
Historical data | Yes
Animal model (sensitivity) | ++ Both sexes of non-transgenic animals were used and the strain is in common use. Rats were more sensitive to monochloroacetic acid non-neoplastic effects, causing death and cardiomyopathy during the short term studies, compared to mice and so their dose levels were much lower.
Statistical power (sensitivity) | +++ The numbers of animals (50 at 104 weeks and 10 at 6 and 15 months) varied considerably for each group depending on the time of sacrifice.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | ++ There was a significant decrease in survival but not in body weight. There was no significant increase in neoplasm incidence, but there was a significant increase in preneoplasm incidence. Rats were more sensitive to non-neoplastic effects, causing death and cardiomyopathy during the short term studies, compared to mice and so their dose levels were much lower.
Exposure duration (sensitivity) | +++ A near life-span duration (104 weeks) was used.
Dose-response (sensitivity) | ++ Two exposure levels were used that spanned a range of 2-fold, making the detection of a dose response limited.
Outcome
Pathology | +++ All major organs and gross lesions were histologically evaluated and findings were verified by an independent pathologist.
Consistency between groups | +++ All groups were treated the same.
Study duration (sensitivity) | +++ A near life-span duration (104 weeks) was used.
Confounding
Confounding | +++ The test agent was well characterized, animals were treated the same between groups, and were continually monitored for infectious diseases.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Tumor combinations were appropriate.

Overall utility: ++. The study was well conducted to rule out confounding and with a strong power to detect tumor induction. However, only two exposed dose levels were tested, which limit the detection of dose response relationships. Rats were more sensitive to non-neoplastic effects, causing death and cardiomyopathy during the short term studies, compared to mice and so their dose levels were much lower.

Table C-5 DeAngelo et al. 1997 (M Rat): Monochloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | Not reported.
Controls | +++ Concurrent vehicle controls of sodium chloride at equal molar concentrations as the trichloroacetic acid high dose group were used.
Historical data | Yes
Animal model (sensitivity) | ++ Only males of non-transgenic animals were used.
Statistical power (sensitivity) | +++ Moderate numbers of animals (29−32) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | +++ There was no significant difference in survival, but there was a significant decrease in body weight that required dose reduction. There was no significant difference in neoplasm incidence.
Exposure duration (sensitivity) | +++ A near life-span duration (104 weeks) was used.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 100-fold.
Outcome
Pathology | +++ Full necropsies with histological evaluations were performed.
Consistency between groups | +++ Groups were not reported to have been treated differently.
Study duration (sensitivity) | +++ A near life-span duration (104 weeks) was used.
Confounding
Confounding | +++ The rats were confirmed pathogen free and the chemical purity and stability were confirmed.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Lesions were reported, which included liver hyperplasia, adenomas, and carcinomas. The authors felt the hyperplasia were preneoplastic.

Overall utility: +++. A well conducted study on almost all aspects, but it only involved male rats.

## C.2 Monoiodoacetic Acid: Study Quality for Animal Studies

Table C-6 Gwynn and Salaman 1953 (NR Mouse): Iodoacetic Acid: Dermal

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | Not reported.
Controls | +++ A concurrent negative control of acetic acid was used.
Historical data | No
Animal model (sensitivity) | + The sex of the mice were not reported. The strain of mouse is unfamiliar.
Statistical power (sensitivity) | + Small and insufficient numbers of animals (12) were used for each group.
Exposure
Chemical characterization | Chemical purity and stability were not reported.
Dosing regimen | +++ There was no significant difference in survival and body weight was not reported. There was a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | +++ A short duration was used (27 weeks), but initiation/promotion studies are normally short.
Dose-response (sensitivity) | + One exposure level was used. Preliminary tests showed this to be the maximumly tolerated dose without causing crusting or ulceration. dose was the MTD, not to cause crusting or ulceration. [1.4% (average) was calculated by NTP from a reported M/20−M/10 solution, i.e., 1/20 to 1/10 of a molar solution. Based on a MW of 185.95, it comes to 0.92975−1.8595%, averaging to 1.4%.] Vehicle control (acetone): 21 days after 0.15% DMBA, acetone was administered (2/wk × 12 wk; 1/wk × 15 wk). Acetic acid negative control (0.9% acetic acid): 39 days after 0.1% DMBA, 0.9% acetic acid was administered (1/wk × 20 wk). Reported at M/1−-M/5 solution, i.e., 1/10 to 1/5 of a molar solution. Based on a MW of 60.05, it comes to 0.6−1.2%, averaging to 0.9%.
Outcome
Pathology | + Not reported and necropsies were not likely to have occurred beyond histological examination of the skin tumors.
Consistency between groups | Not reported.
Study duration (sensitivity) | +++ A short duration was used (30 weeks), but initiation/promotion studies are usually short.
Confounding
Confounding | + Disease surveillance, animal husbandry, or chemical characterization were not reported.
Reporting and analysis
Reporting data and statistics | Not reported.
Combining lesions | +++ Only benign papillomas were reported.

Overall utility: +. The chemicals were not characterized and purity was not reported. The sex of the animals were not reported and only a single dose level was tested on a very low number of animals per group. Histology of the neoplasms were carried out, but the skin tumors were classified as benign papillomas based on their appearance “macroscopically.” Statistical significance was not calculated.

## C.3 Dichloroacetic Acid: Study Quality for Animal Studies

Table C-7 DeAngelo et al. 1996 (M Rat [Study 1]): Dichloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | Not reported.
Controls | +++ Concurrent vehicle controls of sodium chloride at equal molar concentrations as the high dose were used.
Historical data | Yes
Animal model (sensitivity) | ++ Only males of non-transgenic animals were used.
Statistical power (sensitivity) | ++ The exact number of animals was not clearly reported. It appears to have been between 21 to 33 for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | +++ There were no significant differences in survival, but the high dose group was sacrificed early because of peripheral neuropathy and body weight was not significantly different. There was a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | +++ A near life-span duration (100 weeks) was used. The high dose group was stopped at 60 weeks due to peripheral neuropathy and was not included in the study results.
Dose-response (sensitivity) | ++ Two exposure levels were effectively used that spanned a range of 10-fold. The original high dose was 100-fold higher than the low exposure level, but caused toxicity, requiring dose reduction and were not reported.
Outcome
Pathology | ++ Only the liver was histologically examined.
Consistency between groups | ++ The high dose group had their dose reduced three times due to irreversible peripheral neuropathy and they were all scarified at 60 weeks, while other dose groups were scarified at 100 weeks. They also have 5 rats undergo full necropsies, with histological evaluations of all major organs. However, the high dose group results were not reported.
Study duration (sensitivity) | +++ A near life-span duration (100 weeks) was used. The high dose group was stopped at 60 weeks due to peripheral neuropathy and was not included in the study results.
Confounding
Confounding | ++ Animals started out viral free, but continual disease surveillance was not reported. The high dose group was treated differently but results from that group were not reported.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Lesions were reported, which included liver hyperplasia, adenomas, and carcinomas. The authors felt the hyperplasia were preneoplastic.

Overall utility: ++. Animals were certified pathogen free, though were not reported to be continuously monitored for disease. Only two exposed dose levels were effectively reported and only males were tested. The duration was near life-span and historical controls were considered during data analysis. However, only liver lesion incidences were reported.

Table C-8 DeAngelo et al. 1996 (M Rat [Study 2]): Dichloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | Not reported.
Controls | +++ Concurrent controls were exposed to deionized water (vehicle). NaCl was omitted from the water of control animals because no significant effects such as differences in tumor incidence or altered water consumption was noted in the previous bioassay at 100 weeks exposure.
Historical data | Yes
Animal model (sensitivity) | ++ Only males of non-transgenic animals were used.
Statistical power (sensitivity) | ++ The exact number of animals was not clearly reported. It appears to have been between 27 to 28 for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | +++ At sacrifice, the mean body weight of the animals (1.6 g/l) was significantly reduced to 73% of the control value.
Exposure duration (sensitivity) | +++ A near life-span duration (103 weeks exposure period) was used. The high dose group (2.5 g/l) DCA was lowered to 1.5 g/l at eight weeks exposure and to 1.0 g/l at 26 weeks exposure. A mean daily exposure concentration was reported as 1.6 g/l.
Dose-response (sensitivity) | + One exposure level was used, which cause toxicity, requiring dose reduction.
Outcome
Pathology | ++ No indication that a full necropsy was done.
Consistency between groups | ++ 103 wk bioassay grossly evaluated liver, kidneys, spleen, testes, thyroid, stomach, rectum, duodenum, ileum, jejunum, colon, and urinary bladder and microscopically evaluated grossly detected lesions.
Study duration (sensitivity) | +++ A near life-span duration (103 weeks exposure period) was used.
Confounding
Confounding | ++ Animals started out viral free, but continual disease surveillance was not reported. The 100 week and the 103 week DeAngelo 1996 studies were done in two different laboratories but were reported in the same publication; it is unclear if the same animal care procedures were performed at both locations.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Liver lesions were reported, which included liver hyperplasia, adenomas, and carcinomas.

Overall utility: ++. Animals were certified pathogen free, though were not reported to be continuously monitored for disease. Only one exposed dose level was tested and only males were tested. The duration was near life-span and historical controls were considered during data analysis. However, only liver lesion incidences were reported.

Table C-9 Richmond et al. 1995 (M Rat): Dichloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups.
Controls | +++ Concurrent vehicle controls of 2 g/l of sodium chloride were used.
Historical data | No
Animal model (sensitivity) | ++ Only males of non-transgenic animals were used.
Statistical power (sensitivity) | ++ The number of animals was sufficient (23−29) for each group.
Exposure
Chemical characterization | Chemical purity and stability were not reported.
Dosing regimen | +++ There was no clear significant difference in survival and body weight was not reported. There was a non-significant increase in neoplasm incidence.
Exposure duration (sensitivity) | +++ Near life-span duration (104 weeks) were used.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 50-fold.
Outcome
Pathology | ++ Only the liver was histologically examined.
Consistency between groups | ++ All groups were treated the same except for the last time point for sacrifice was 60 weeks for the 2.4 g/l group and 104 weeks for all other groups. This was because of toxicity, causing tumors and hind limb paralysis.
Study duration (sensitivity) | +++ Near life-span and less than near life-span durations (104 weeks) were used.
Confounding
Confounding | + Neither disease surveillance, nor chemical purity or characterization was reported. Neither survival nor body weight was clearly reported.
Reporting and analysis
Reporting data and statistics | ++ Statistical significance was reported for neoplasm incidence, though no analysis of body weight changes or differences in survival were reported and body weights were not reported at all and survival was not clearly reported but was estimated by NTP to not have been greatly different.
Combining lesions | +++ Total proliferative lesions were reported which included liver hyperplastic nodules, hepatocellular adenomas, and hepatocellular carcinomas.

Overall utility: ++. The chemical and animal husbandry conditions were not characterized and only a low to moderate number of males rats were tested. However, they were tested at three dose levels spanning a 50-fold range and the exposure duration was near life-span for all but the high dose group. Survival and body weights were not clearly reported and only the liver was histologically evaluated.

Table C-10 DeAngelo et al. 1991 (M Mouse [Study 1]): Dichloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups.
Controls | +++ Concurrent vehicle controls of 2 g/l of sodium chloride at equal molar concentrations as the high exposure dose level were used.
Historical data | No
Animal model (sensitivity) | ++ Only males of non-transgenic animals were used.
Statistical power (sensitivity) | ++ Sufficient numbers of animals (27−30) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | +++ There was no significant difference in survival and there was a significant decrease in body weight. There was a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | +++ A less than life-span durations (60 weeks for the high exposure group and 75 weeks for the other exposure group) were used.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 100-fold.
Outcome
Pathology | ++ Only a select number of organs were examined and only lesions or tissues with lesions were histologically evaluated.
Consistency between groups | ++ Different numbers of animals in each treatment group were tested at either 60 weeks or 75 weeks of exposure.
Study duration (sensitivity) | +++ A less than life-span durations (60 weeks for the high exposure group and 75 weeks for the other exposure group) were used.
Confounding
Confounding | ++ The chemical was well characterized, but disease surveillance was not reported and different numbers of animals were sacrificed at different times. Further, only a select few organs were involved in the necropsy. The high dose group drank 60% less water than controls near the last third of the study and so the mean daily dose was decreased from 573 mg/kg/day to 387. The medium and low dose had not difference in water intake compared to controls.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Only hepatocellular adenomas and carcinomas were combined.

Overall utility: +++. Three dose levels, which spanned a 100-fold range were tested in only males for up to 75 weeks. Only a few select organs were necropsied.

Table C-11 DeAngelo et al. 1991 (M Mouse [Study 2]): Dichloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups.
Controls | +++ Concurrent vehicle controls of 1.5 g/l of acetic acid at equal molar concentrations as the high exposure dose level were used.
Historical data | No
Animal model (sensitivity) | ++ Only males of non-transgenic animals were used.
Statistical power (sensitivity) | + Small and insufficient numbers of animals (10−12) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | +++ There was no significant difference in survival and there was a significant decrease in body weight. There was a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | +++ A less than life-span durations (60 weeks for the high exposure group and 75 weeks for the other exposure group) were used.
Dose-response (sensitivity) | + One exposure level was used.
Outcome
Pathology | ++ Only a select number of organs were examined and only lesions or tissues with gross lesions were histologically evaluated.
Consistency between groups | +++ Exposed and controls were treated the same.
Study duration (sensitivity) | +++ A less than life-span durations (60 weeks for the high exposure group and 75 weeks for the other exposure group) were used.
Confounding
Confounding | ++ The chemical was well characterized, but disease surveillance was not reported. Further, only a select few organs were involved in the necropsy. The water intake was significantly lower than controls (69% of that in controls), though the DCA concentration was 7% higher than expected.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Only hepatocellular adenomas and carcinomas were combined.

Overall utility: ++. One dose level was tested in a small number of males for 60 weeks. Only a few select organs were necropsied.

Table C-12 DeAngelo et al. 1999 (M Mouse): Dichloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups.
Controls | +++ Two sets of concurrent vehicle controls were used, one for the 500, 1,000, 2,000, and 3,500 mg/L groups and one started a month later for the 50 mg/L group.
Historical data | No
Animal model (sensitivity) | ++ Only males of non-transgenic animals were used.
Statistical power (sensitivity) | ++ The numbers of animals (16−53) varied considerably for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | +++ There was a significant decrease in survival and body weight. There was a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | +++ A near life-span duration (90−100 weeks) was used.
Dose-response (sensitivity) | +++ Four exposure levels were used that spanned a range of 7-fold.
Outcome
Pathology | ++ Only gross lesions were histologically examined and normal tissue from all major organs was only histologically examined in 5 mice of the high dose group.
Consistency between groups | ++ Only 5 mice from the high dose group had undergone histological examinations of all major organs, while the other groups only had histological examinations of gross lesions.
Study duration (sensitivity) | +++ A near life-span duration (90−100 weeks) was used.
Confounding
Confounding | ++ The mice were initially viral, bacteria, and parasite free, but continual disease surveillance was not reported. All major organs from only 5 mice from the high dose group were histologically evaluated, only gross lesions were histologically evaluated in the other groups.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | Tumor types were not combined.

Overall utility: ++. Only male mice, initially confirmed pathogen free, were used with differing numbers per group (as low was 16 in the high dose group). Continual disease surveillance was not reported. Multiple dose levels ranging 100-fold, were tested for a near life-span duration. However, only 5 high dose group mice received histological evaluations of all major organs, with histological evaluations of only gross lesions in the other groups.

Table C-13 Herren-Freund et al. 1987 (M Mouse): Dichloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | Not reported.
Controls | +++ Concurrent vehicle controls of 2 g/l of sodium chloride to match that found in exposed groups and a positive control of phenobarbital at 500 mg/l (positive controls are not reported here) were used.
Historical data | No
Animal model (sensitivity) | ++ Only males of non-transgenic animals were used.
Statistical power (sensitivity) | ++ Moderate numbers of animals (22−26) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | +++ Survival was not reported and body weight was significantly decreased. There was a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | +++ A less than life-span duration (61 weeks) was used.
Dose-response (sensitivity) | + One exposure level was used, so dose response relationships could not be measured.
Outcome
Pathology | ++ Only the liver was histologically examined.
Consistency between groups | +++ All groups were treated the same.
Study duration (sensitivity) | +++ A less than life-span duration (61 weeks) was used.
Confounding
Confounding | +++ Disease surveillance was not reported, but chemical purity and stability were tested.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Tumor types were not combined.

Overall utility: ++. The durations were less than near life-span. Only males were tested at a single dose level and only livers were histologically evaluated.

Table C-14 Herren-Freund et al. 1987 (M Mouse): Dichloroacetic Acid: Drinking Water (Initiation-promotion)

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | Not reported.
Controls | +++ Concurrent vehicle controls of 2 g/l of sodium chloride to match that found in exposed groups and a positive control of phenobarbital at 500 mg/l (positive controls are not reported here) were used.
Historical data | No
Animal model (sensitivity) | ++ Only males of non-transgenic animals were used.
Statistical power (sensitivity) | ++ Moderate numbers of animals (22−26) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | +++ Survival was not reported and body weight was significantly decreased. There was a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | +++ A less than life-span duration (61 weeks) was used.
Dose-response (sensitivity) | + Two exposure levels were used which spanned a range of 2.5-fold.
Outcome
Pathology | ++ Only the liver was histologically examined.
Consistency between groups | +++ All groups were treated the same.
Study duration (sensitivity) | +++ A less than life-span duration (61 weeks) was used.
Confounding
Confounding | +++ Disease surveillance was not reported, but chemical purity and stability were tested.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Tumor types were not combined.

Overall utility: ++. The duration was less than near life-span. Only males were tested at two narrow dose levels and only livers were histologically evaluated.

Table C-15 Wood et al. 2015 (M Mouse): Dichloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | Not reported.
Controls | +++ Concurrent vehicle controls were used.
Historical data | No
Animal model (sensitivity) | +++ Both sexes of non-transgenic animals were used and the strain is in common use.
Statistical power (sensitivity) | ++ Moderate numbers of animals (27) were used for each group, though the original number of animals at the start of the study were not reported.
Exposure
Chemical characterization | ++ Purity was not reported. Stability had been shown previously in stock drinking water over 8−12 days, while bottles were changed twice a week.
Dosing regimen | +++ There was no significant difference in survival, but there was a significant decrease in body weight. There was a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | ++ Exposure duration was short (10 weeks), though the observation duration was near life-span (94 weeks).
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 3.5-fold. These were based on previous chronic studies in the same strain of male mice which were estimated to be 20,000−30,000 times greater than those in normal tap water.
Outcome
Pathology | + Only livers were examined. Even gross examination of other organs were not reported.
Consistency between groups | +++ Groups were not reported to have been treated differently.
Study duration (sensitivity) | +++ A near life-span duration (94 weeks) was used.
Confounding
Confounding | ++ Continual disease surveillance was not reported.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Hepatocellular adenomas, hepatocellular carcinomas, and hepatocellular blastomas were combined as neoplasms which is appropriate.

Overall utility: ++. Chemical stability was reported and target concentrations were verified, but purity was not reported. Disease surveillance was not reported. Three dose levels, previously shown to be carcinogenic were used. The exposure duration was short, but the observation duration was near life-span. Only livers were examined during necropsy.

Table C-16 Wood et al. 2015 (F Mouse): Dichloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | Not reported.
Controls | +++ Concurrent vehicle controls were used.
Historical data | No
Animal model (sensitivity) | +++ Both sexes of non-transgenic animals were used and the strain is in common use.
Statistical power (sensitivity) | ++ Moderate numbers of animals (27) were used for each group, though the original number of animals at the start of the study were not reported.
Exposure
Chemical characterization | ++ Purity was not reported. Stability had been shown previously in stock drinking water over 8−12 days, while bottles were changed twice a week.
Dosing regimen | +++ There was no significant difference in survival, but there was a significant decrease in body weight. There was a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | ++ Exposure duration was short (10 weeks), though the observation duration was near life-span (94 weeks).
Dose-response (sensitivity) | ++ Two exposure levels were used that spanned a range of 2-fold. These were based on previous chronic studies in the same strain of male mice which were estimated to be 20,000−30,000 times greater than those in normal tap water.
Outcome
Pathology | + Only livers were examined. Even gross examination of other organs were not reported.
Consistency between groups | +++ Groups were not reported to have been treated differently.
Study duration (sensitivity) | +++ A near life-span duration (94 weeks) was used.
Confounding
Confounding | ++ Continual disease surveillance was not reported.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Hepatocellular adenomas, hepatocellular carcinomas, and hepatocellular blastomas were combined as neoplasms which is appropriate.

Overall utility: ++. Chemical stability was reported and target concentrations were verified, but purity was not reported. Disease surveillance was not reported. Two dose levels, previously shown to be carcinogenic were used. The exposure duration was short, but the observation duration was near life-span. Only livers were examined during necropsy.

Table C-17 Pereira 1996 (F Mouse [Study 1]): Dichloroacetic Acid (DCA): Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ It was not reported if animals were randomly assigned to exposure groups, but they were necropsied blinded and the mice were randomly assigned an ID number, which suggests they were randomly assigned to treatment groups, but it is not known for sure.
Controls | +++ Concurrent vehicle controls of sodium chloride at equal molar concentrations as in the high dose group were used.
Historical data | No
Animal model (sensitivity) | ++ Only females of non-transgenic animals were used.
Statistical power (sensitivity) | ++ The number of animals (15−90) varied considerably for each group.
Exposure
Chemical characterization | Chemical purity and stability were not reported.
Dosing regimen | +++ Survival was not reported, but there was a significant decreased in body weight and a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | +++ A near life-span duration (576 days) was used.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 10-fold.
Outcome
Pathology | ++ Only the liver was histologically examined.
Consistency between groups | +++ Groups were not reported to have been treated differently.
Study duration (sensitivity) | +++ A near life-span duration (576 days) was used.
Confounding
Confounding | ++ Continual disease surveillance and survival were not reported. The high exposure group had a significant decrease in water consumption.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Lesions were reported, which included liver foci, adenomas, and carcinomas. The authors felt the foci were preneoplastic.

Overall utility: ++. The chemicals were not characterized, not even purity was reported. Disease surveillance was not continually monitored. A variable number of only females was tested, with only their livers examined histologically. The study duration was near life-span.

Table C-18 Pereira 1996 (F Mouse [Study 2]): Dichloroacetic Acid (DCA): Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ It was not reported if animals were randomly assigned to exposure groups, but they were necropsied blinded and the mice were randomly assigned an ID number, which suggests they were randomly assigned to treatment groups, but it is not known for sure.
Controls | +++ Concurrent vehicle controls of sodium chloride at equal molar concentrations as in the high dose group were used.
Historical data | No
Animal model (sensitivity) | ++ Only females of non-transgenic animals were used.
Statistical power (sensitivity) | ++ The number of animals (15−90) varied considerably for each group.
Exposure
Chemical characterization | Chemical purity and stability were not reported.
Dosing regimen | +++ Survival was not reported, but there was a significant decreased in body weight and a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | ++ A less than life-span duration (360 days) was used.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 10-fold.
Outcome
Pathology | ++ Only the liver was histologically examined.
Consistency between groups | +++ Groups were not reported to have been treated differently.
Study duration (sensitivity) | +++ A less than life-span duration (360 days) was used.
Confounding
Confounding | ++ Continual disease surveillance and survival were not reported. The high exposure group had a significant decrease in water consumption.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Lesions were reported, which included liver foci, adenomas, and carcinomas. The authors felt the foci were preneoplastic.

Overall utility: ++. The chemicals were not characterized, not even purity was reported. Disease surveillance was not continually monitored. A variable number of only females was tested, with only their livers examined histologically. Study duration was less than life-span.

Table C-19 Pereira et al. 1997 (F Mouse): Dichloroacetic Acid (DCA): Drinking Water (I/P)

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups with initial body weights the same for each group.
Controls | +++ Concurrent controls were appropriate for an initiation/promotion study in which all groups received the initiator (NMU), and the negative control group was given only the initiator and promotor vehicle.
Historical data | No
Animal model (sensitivity) | ++ Only females of non-transgenic animals were used.
Statistical power (sensitivity) | ++ Small, but sufficient numbers of animals (>20) were used for each group.
Exposure
Chemical characterization | + Chemical purity and stability were not reported.
Dosing regimen | +++ There was no significant difference in survival or body weight and there was a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | +++ Animals were exposed for 44 weeks, starting 4 weeks after a single injection of the initiator at 15 d of age. This is short for carcinogenicity studies, but initiation/promotion studies are normally shorter and tumors were significantly induced.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 3-fold.
Outcome
Pathology | ++ Only the liver was histologically examined.
Consistency between groups | +++ Groups were not reported to have been treated differently.
Study duration (sensitivity) | +++ A less than near life-span duration (48 weeks) was used, but initiation/promotion studies are normally short.
Confounding
Confounding | ++ Continual disease surveillance and survival were not reported.
Reporting and analysis
Reporting data and statistics | ++ Significance levels were reported, but the statistical test was not reported.
Combining lesions | +++ Lesions were reported, which included liver foci, adenomas, and carcinomas. The authors felt the foci were preneoplastic.

Overall utility: +. The chemicals were not characterized, not even purity was reported. Disease surveillance was not reported. A low number of only females were tested, with only their livers examined histologically. The statistical methods were not reported.

Table C-20 Bull et al. 1990 (M Mouse): Dichloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups.
Controls | +++ Concurrent vehicle controls were used.
Historical data | No
Animal model (sensitivity) | ++ Only males of non-transgenic animals were used.
Statistical power (sensitivity) | + Small numbers of animals (11−24) were used for each group.
Exposure
Chemical characterization | ++ Chemical purity and stability were not verified.
Dosing regimen | +++ There were no deaths and body weight was not reported. There was a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | +++ A less than life-span duration (52 weeks) was used.
Dose-response (sensitivity) | ++ Two exposure levels were used that spanned a range of 2-fold.
Outcome
Pathology | + Only livers from some animals were histologically evaluated. Results only reported overall lesions, which include hyperplasia. Liver lesions that were histologically evaluated were randomly selected and blindly evaluated.
Consistency between groups | + All untreated control lesions were histologically evaluated, but only some of the exposed groups were evaluated.
Study duration (sensitivity) | +++ A less than life-span duration (52 weeks) was used.
Confounding
Confounding | + Disease surveillance was not reported. Only samples of liver lesions were histologically evaluated and inappropriately reported.
Reporting and analysis
Reporting data and statistics | + Statistical evaluations were rarely reported and incidences that could be significant by Fisher's Exact test (calculated by NTP) were not reported as significant, so NTP calculations were included.
Combining lesions | ++ Only total lesions were adequately reported to allow for quantitation of the results. These included liver hyperplasia, hepatocellular adenoma, and hepatocellular carcinoma, which entail a continuum of the same disease process, however there were 4/73 lesion types that were also included but were neither hyperplastic nor neoplastic.

Overall utility: +. The chemical was not characterized, disease surveillance was not reported. A low number of mice per group were exposed for a less than near life-span duration and only males had results reported. Only livers were histologically examined. Not all lesions were histologically evaluated, but instead samples of lesions were evaluated. Results were reported so that incidences of specific neoplasms could not be determined but could be estimated.

Table C-21 Daniel et al. 1992 (M Mouse): Dichloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups.
Controls | +++ Concurrent vehicle controls were used.
Historical data | Yes
Animal model (sensitivity) | ++ Only males of non-transgenic animals were used.
Statistical power (sensitivity) | ++ Moderate numbers of animals (20−24) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | +++ There was no significant difference in survival or body weight. There was a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | +++ A near life-span duration (104 weeks) was used.
Dose-response (sensitivity) | + One exposure level was used, which was low compared to other similar studies from the same lab.
Outcome
Pathology | + Histological evaluations were only done on liver, kidney, testes, spleen, and gross lesions.
Consistency between groups | ++ Only 5 mice from the high dose group had undergone histological examinations of all major organs, while the other groups only had histological examinations of gross lesions.
Study duration (sensitivity) | +++ A near life-span duration (104 weeks) was used.
Confounding
Confounding | ++ Continual disease surveillance was not reported. Only some mice received a full histological evaluation.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Lesions were reported, which included liver hyperplasia, adenomas, and carcinomas. The authors felt the hyperplasia were preneoplastic.

Overall utility: ++. Continual disease surveillance was not reported. Only males were tested and only at one dose level. Histological evaluations from all major organs only occurred in five mice per group, with histological evaluations in the other mice only occurring on tissues with gross lesions.

Table C-22 NTP 2007b (M & F Mouse [Study 1]): Dichloroacetic Acid: Dermal

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups.
Controls | +++ Concurrent vehicle controls of 99.9% acetone were used.
Historical data | No
Animal model (sensitivity) | + Both sexes of transgenic animals, that are sensitive to carcinogens with a propensity to develop squamous papillomas or carcinomas of the skin or forestomach, were used. However, the transgenic strain is sensitive to skin injury and will develop papillomas, suggesting it may overestimate a chemical's carcinogenic potential.
Statistical power (sensitivity) | + Small and insufficient numbers of animals (10) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | ++ There was no significant difference in survival, but there was a significant decrease in body weight. There was no significant increase in neoplasm incidence, but there was in preneoplasm incidence.
Exposure duration (sensitivity) | +++ While the duration was short (39 weeks) compared to carcinogenicity studies, it was performed in transgenic mice prone to developing cancer.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 16-fold.
Outcome
Pathology | +++ All major organs and gross lesions were histologically evaluated and findings were verified by an independent pathologist.
Consistency between groups | +++ All groups were treated the same except that positive controls underwent a complete necropsy. However, positive controls will not be reported here.
Study duration (sensitivity) | +++ While the duration was short (39 weeks) compared to carcinogenicity studies, it was performed in transgenic mice prone to developing cancer.
Confounding
Confounding | +++ The test agent was well characterized, animals were treated the same between groups, and were continually monitored for infectious diseases.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Tumor types were not combined.

Overall utility: +. The study was well conducted except for a low number of transgenic animals per group, which may overestimate carcinogenic potential. The ability to translate hazards in this model to non-transgenic mice is limited.

Table C-23 NTP 2007b (M Mouse [Study 2]): Dichloroacetic Acid: Dermal

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups.
Controls | +++ Concurrent vehicle controls of 99.9% acetone were used.
Historical data | No
Animal model (sensitivity) | + Both sexes of transgenic animals, that are sensitive to carcinogens with a propensity to develop squamous papillomas or carcinomas of the skin or forestomach, were used. However, the transgenic strain is sensitive to skin injury and will develop papillomas, suggesting it may overestimate a chemical's carcinogenic potential.
Statistical power (sensitivity) | ++ Small and insufficient numbers of animals (15) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | ++ There was no significant difference in survival or body weight. There was no significant increase in neoplasm incidence, but there was a significant increase in preneoplasm incidence.
Exposure duration (sensitivity) | ++ While the duration was short (26 weeks) compared to carcinogenicity studies, it was performed in transgenic mice prone to developing cancer.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 16-fold.
Outcome
Pathology | +++ All major organs and gross lesions were histologically evaluated and findings were verified by an independent pathologist.
Consistency between groups | +++ All groups were treated the same except that positive controls underwent a complete necropsy. However, positive controls will not be reported here.
Study duration (sensitivity) | +++ While the duration was short (26 weeks) compared to carcinogenicity studies, it was performed in transgenic mice prone to developing cancer.
Confounding
Confounding | +++ The test agent was well characterized, animals were treated the same between groups, and were continually monitored for infectious diseases.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Tumor types were not combined.

Overall utility: +. The study was well conducted except for a low number of transgenic animals per group, which may overestimate carcinogenic potential. The ability to translate hazards in this model to non-transgenic mice is limited.

Table C-24 NTP 2007b (M Mouse [Study 1]): Dichloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups.
Controls | +++ Concurrent vehicle controls of 99.9% acetone were used.
Historical data | No
Animal model (sensitivity) | + Both sexes of transgenic animals, that are sensitive to carcinogens with a propensity to develop squamous papillomas or carcinomas of the skin or forestomach, were used. However, the transgenic strain is sensitive to skin injury and will develop papillomas, suggesting it may overestimate a chemical's carcinogenic potential.
Statistical power (sensitivity) | + Small and insufficient numbers of animals (10) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | +++ There was no significant difference in survival and no significant decrease in body weight. There was a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | +++ While the duration was short (26 weeks) compared to carcinogenicity studies, it was performed in transgenic mice prone to developing cancer.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 16-fold.
Outcome
Pathology | +++ All major organs and gross lesions were histologically evaluated and findings were verified by an independent pathologist.
Consistency between groups | +++ All groups were treated the same except that positive controls underwent a complete necropsy. However, positive controls will not be considered here.
Study duration (sensitivity) | +++ While the duration was short (26 weeks) compared to carcinogenicity studies, it was performed in transgenic mice prone to developing cancer.
Confounding
Confounding | +++ The test agent was well characterized, animals were treated the same between groups, and were continually monitored for infectious diseases.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Tumor types were not combined.

Overall utility: +. The study was well conducted except for a low number of transgenic animals per group, which may overestimate carcinogenic potential. The ability to translate hazards in this model to non-transgenic mice is limited.

Table C-25 NTP 2007b (F Mouse [Study 1]): Dichloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups.
Controls | +++ Concurrent vehicle controls of 99.9% acetone were used.
Historical data | No
Animal model (sensitivity) | + Both sexes of transgenic animals, that are sensitive to carcinogens with a propensity to develop squamous papillomas or carcinomas of the skin or forestomach, were used. However, the transgenic strain is sensitive to skin injury and will develop papillomas, suggesting it may overestimate a chemical's carcinogenic potential.
Statistical power (sensitivity) | + Small and insufficient numbers of animals (10) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | ++ There was no significant difference in survival, but there was a significant decrease in body weight. There was no significant increase in neoplasm incidence, but there was a significant increase in preneoplasm incidence.
Exposure duration (sensitivity) | +++ While the duration was short (26 weeks) compared to carcinogenicity studies, it was performed in transgenic mice prone to developing cancer.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 16-fold.
Outcome
Pathology | +++ All major organs and gross lesions were histologically evaluated and findings were verified by an independent pathologist.
Consistency between groups | +++ All groups were treated the same except that positive controls underwent a complete necropsy. However, positive controls will not be considered here.
Study duration (sensitivity) | +++ While the duration was short (26 weeks) compared to carcinogenicity studies, it was performed in transgenic mice prone to developing cancer.
Confounding
Confounding | +++ The test agent was well characterized, animals were treated the same between groups, and were continually monitored for infectious diseases.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Tumor types were not combined.

Overall utility: +. The study was well conducted except for a low number of transgenic animals per group, which may overestimate carcinogenic potential. The ability to translate hazards in this model to non-transgenic mice is limited.

Table C-26 NTP 2007b (M Mouse [Study 2]): Dichloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups.
Controls | +++ Concurrent vehicle controls of 99.9% acetone were used.
Historical data | No
Animal model (sensitivity) | + Both sexes of transgenic animals, that are sensitive to carcinogens with a propensity to develop squamous papillomas or carcinomas of the skin or forestomach, were used. However, the transgenic strain is sensitive to skin injury and will develop papillomas, suggesting it may overestimate a chemical's carcinogenic potential.
Statistical power (sensitivity) | ++ Small and insufficient numbers of animals (15) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | + There was no significant difference in survival and no significant decrease in body weight. There was no significant increase in neoplasm incidence.
Exposure duration (sensitivity) | ++ While the duration was short (26 weeks) compared to carcinogenicity studies, it was performed in transgenic mice prone to developing cancer.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 16-fold.
Outcome
Pathology | +++ All major organs and gross lesions were histologically evaluated and findings were verified by an independent pathologist.
Consistency between groups | +++ All groups were treated the same except that positive controls underwent a complete necropsy. However, positive controls will not be reported here.
Study duration (sensitivity) | +++ While the duration was short (26 weeks) compared to carcinogenicity studies, it was performed in transgenic mice prone to developing cancer.
Confounding
Confounding | +++ The test agent was well characterized, animals were treated the same between groups, and were continually monitored for infectious diseases.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Tumor types were not combined.

Overall utility: +. The study was well conducted except for a low number of transgenic animals per group, which may overestimate carcinogenic potential. The ability to translate hazards in this model to non-transgenic mice is limited.

Table C-27 NTP 2007b (F Mouse [Study 2]): Dichloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups.
Controls | +++ Concurrent vehicle controls of 99.9% acetone were used.
Historical data | No
Animal model (sensitivity) | + Both sexes of transgenic animals, that are sensitive to carcinogens with a propensity to develop squamous papillomas or carcinomas of the skin or forestomach, were used. However, the transgenic strain is sensitive to skin injury and will develop papillomas, suggesting it may overestimate a chemical's carcinogenic potential.
Statistical power (sensitivity) | ++ Small and insufficient numbers of animals (15) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | ++ There was a significant decrease in survival and body weight. There was no significant increase in neoplasm incidence.
Exposure duration (sensitivity) | ++ While the duration was short (26 weeks) compared to carcinogenicity studies, it was performed in transgenic mice prone to developing cancer.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 16-fold.
Outcome
Pathology | +++ All major organs and gross lesions were histologically evaluated and findings were verified by an independent pathologist.
Consistency between groups | +++ All groups were treated the same except that positive controls underwent a complete necropsy. However, positive controls will not be considered here.
Study duration (sensitivity) | +++ While the duration was short (26 weeks) compared to carcinogenicity studies, it was performed in transgenic mice prone to developing cancer.
Confounding
Confounding | +++ The test agent was well characterized, animals were treated the same between groups, and were continually monitored for infectious diseases.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Tumor types were not combined.

Overall utility: +. The study was well conducted except for a low number of transgenic animals per group, which may overestimate carcinogenic potential. The ability to translate hazards in this model to non-transgenic mice is limited.

Table C-28 NTP 2007b (M Mouse [Study 3]): Dichloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups.
Controls | +++ Concurrent vehicle controls of 99.9% acetone were used.
Historical data | No
Animal model (sensitivity) | + Both sexes of transgenic animals, that are sensitive to carcinogens with a propensity to develop lymphomas or sarcomas, were used. However, the transgenic strain may overestimate a chemical's carcinogenic potential.
Statistical power (sensitivity) | + Small and insufficient numbers of animals (10) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | ++ There was no significant difference in survival, but there was a significant decrease in body weight. There was no significant difference in neoplasm incidence.
Exposure duration (sensitivity) | +++ While the duration was short (26 weeks) compared to carcinogenicity studies, it was performed in transgenic mice prone to developing cancer.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 16-fold.
Outcome
Pathology | +++ All major organs and gross lesions were histologically evaluated and findings were verified by an independent pathologist.
Consistency between groups | +++ All groups were treated the same except that positive controls underwent a complete necropsy. However, positive controls will not be considered here.
Study duration (sensitivity) | +++ While the duration was short (26 weeks) compared to carcinogenicity studies, it was performed in transgenic mice prone to developing cancer.
Confounding
Confounding | +++ The test agent was well characterized, animals were treated the same between groups, and were continually monitored for infectious diseases.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Tumor types were not combined.

Overall utility: +. The study was well conducted except for a low number of transgenic animals per group, which may overestimate carcinogenic potential. The ability to translate hazards in this model to non-transgenic mice is limited.

Table C-29 NTP 2007b (F Mouse [Study 3]): Dichloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups.
Controls | +++ Concurrent vehicle controls of 99.9% acetone were used.
Historical data | No
Animal model (sensitivity) | + Both sexes of transgenic animals, that are sensitive to carcinogens with a propensity to develop lymphomas or sarcomas, were used. However, the transgenic strain may overestimate a chemical's carcinogenic potential.
Statistical power (sensitivity) | + Small and insufficient numbers of animals (10) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | ++ There was no significant difference in survival, but there was a significant decrease in body weight. There was no significant difference in neoplasm incidence.
Exposure duration (sensitivity) | +++ While the duration was short (26 weeks) compared to carcinogenicity studies, it was performed in transgenic mice prone to developing cancer.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 16-fold.
Outcome
Pathology | +++ All major organs and gross lesions were histologically evaluated and findings were verified by an independent pathologist.
Consistency between groups | +++ All groups were treated the same except that positive controls underwent a complete necropsy. However, positive controls will not be considered here.
Study duration (sensitivity) | +++ While the duration was short (26 weeks) compared to carcinogenicity studies, it was performed in transgenic mice prone to developing cancer.
Confounding
Confounding | +++ The test agent was well characterized, animals were treated the same between groups, and were continually monitored for infectious diseases.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Tumor types were not combined.

Overall utility: +. The study was well conducted except for a low number of transgenic animals per group, which may overestimate carcinogenic potential. The ability to translate hazards in this model to non-transgenic mice is limited.

Table C-30 NTP 2007b (M Mouse [Study 4]): Dichloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups.
Controls | +++ Concurrent vehicle controls of 99.9% acetone were used.
Historical data | No
Animal model (sensitivity) | + Both sexes of transgenic animals, that are sensitive to carcinogens with a propensity to develop lymphomas or sarcomas, were used. However, the transgenic strain may overestimate a chemical's carcinogenic potential.
Statistical power (sensitivity) | ++ Small and insufficient numbers of animals (15) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | ++ There was no significant difference in survival, but there was a significant decrease in body weight. There was no significant difference in neoplasm incidence.
Exposure duration (sensitivity) | ++ While the duration was short (26 weeks) compared to carcinogenicity studies, it was performed in transgenic mice prone to developing cancer.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 16-fold.
Outcome
Pathology | +++ All major organs and gross lesions were histologically evaluated and findings were verified by an independent pathologist.
Consistency between groups | +++ All groups were treated the same except that positive controls underwent a complete necropsy. However, positive controls will not be considered here.
Study duration (sensitivity) | +++ While the duration was short (26 weeks) compared to carcinogenicity studies, it was performed in transgenic mice prone to developing cancer.
Confounding
Confounding | +++ The test agent was well characterized, animals were treated the same between groups, and were continually monitored for infectious diseases.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Tumor types were not combined.

Overall utility: +. The study was well conducted except for a low number of transgenic animals per group, which may overestimate carcinogenic potential. The ability to translate hazards in this model to non-transgenic mice is limited.

Table C-31 NTP 2007b (F Mouse [Study 4]): Dichloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups.
Controls | +++ Concurrent vehicle controls of 99.9% acetone were used.
Historical data | No
Animal model (sensitivity) | + Both sexes of transgenic animals, that are sensitive to carcinogens with a propensity to develop lymphomas or sarcomas, were used. However, the transgenic strain may overestimate a chemical's carcinogenic potential.
Statistical power (sensitivity) | ++ Small and insufficient numbers of animals (15) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | ++ There was no significant difference in survival, but there was a significant decrease in body weight. There was no significant difference in neoplasm incidence.
Exposure duration (sensitivity) | ++ While the duration was short (26 weeks) compared to carcinogenicity studies, it was performed in transgenic mice prone to developing cancer.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 16-fold.
Outcome
Pathology | +++ All major organs and gross lesions were histologically evaluated and findings were verified by an independent pathologist.
Consistency between groups | +++ All groups were treated the same except that positive controls underwent a complete necropsy. However, positive controls will not be considered here.
Study duration (sensitivity) | +++ While the duration was short (26 weeks) compared to carcinogenicity studies, it was performed in transgenic mice prone to developing cancer.
Confounding
Confounding | +++ The test agent was well characterized, animals were treated the same between groups, and were continually monitored for infectious diseases.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Tumor types were not combined.

Overall utility: +. The study was well conducted except for a low number of transgenic animals per group, which may overestimate carcinogenic potential. The ability to translate hazards in this model to non-transgenic mice is limited.

## C.4 Dibromoacetic Acid: Study Quality for Animal Studies

Table C-32 NTP 2007a (M Mouse): Dibromoacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups.
Controls | +++ Concurrent vehicle controls were used.
Historical data | Yes
Animal model (sensitivity) | +++ Both sexes of non-transgenic animals were used.
Statistical power (sensitivity) | +++ Large numbers of animals (50) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | +++ There was no significant difference in survival and body weight was not significantly decreased. There was a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | +++ A near life-span duration (106 weeks) was used.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 20-fold.
Outcome
Pathology | +++ All major organs and gross lesions were histologically evaluated and findings were verified by an independent pathologist.
Consistency between groups | +++ All groups were treated the same.
Study duration (sensitivity) | +++ A near life-span duration (106 weeks) was used.
Confounding
Confounding | ++ Drinking water contained 44.7 ug/l of dihaloacetic acids and 3.8 ug/l of dibromoacetic acid.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Tumor combinations were appropriate.

Overall utility: +++. Large numbers of animals per group were used in both sexes and were continuously monitored for disease. Three dose levels spanning a range of 200-fold were used. Lesions and all major organs were histologically evaluated and statistics were clearly reported.

Table C-33 NTP 2007a (F Mouse): Dibromoacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups.
Controls | +++ Concurrent vehicle controls were used.
Historical data | Yes
Animal model (sensitivity) | +++ Both sexes of non-transgenic animals were used.
Statistical power (sensitivity) | +++ Large numbers of animals (50) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | +++ There was no significant difference in survival or body weight. There was a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | +++ A near life-span duration (106 weeks) was used.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 20-fold.
Outcome
Pathology | +++ All major organs and gross lesions were histologically evaluated and findings were verified by an independent pathologist.
Consistency between groups | +++ All groups were treated the same.
Study duration (sensitivity) | +++ A near life-span duration (106 weeks) was used.
Confounding
Confounding | ++ Drinking water contained 44.7 ug/l of dihaloacetic acids and 3.8 ug/l of dibromoacetic acid.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Tumor combinations were appropriate.

Overall utility: +++. Large numbers of animals per group were used in both sexes and were continuously monitored for disease. Three dose levels spanning a range of 200-fold were used. Lesions and all major organs were histologically evaluated and statistics were clearly reported.

Table C-34 NTP 2007a (M Rat): Dibromoacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups.
Controls | +++ Concurrent vehicle controls were used.
Historical data | Yes
Animal model (sensitivity) | +++ Both sexes of non-transgenic animals were used.
Statistical power (sensitivity) | +++ Large numbers of animals (50) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | ++ There was no significant difference in survival, but there was a significant decrease in body weight. There was no significant increase in neoplasm incidence but was a significant increase in preneoplasm incidence.
Exposure duration (sensitivity) | +++ A near life-span duration (106 weeks) was used.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 20-fold.
Outcome
Pathology | +++ All major organs and gross lesions were histologically evaluated and findings were verified by an independent pathologist.
Consistency between groups | +++ All groups were treated the same.
Study duration (sensitivity) | +++ A near life-span duration (106 weeks) was used.
Confounding
Confounding | ++ Drinking water contained 44.7 ug/l of dihaloacetic acids and 3.8 ug/l of dibromoacetic acid.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Tumor combinations were appropriate.

Overall utility: +++. Large numbers of animals per group were used in both sexes and were continuously monitored for disease. Three dose levels spanning a range of 200-fold were used. Lesions and all major organs were histologically evaluated and statistics were clearly reported.

Table C-35 NTP 2007a (F Rat): Dibromoacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups.
Controls | +++ Concurrent vehicle controls were used.
Historical data | Yes
Animal model (sensitivity) | +++ Both sexes of non-transgenic animals were used.
Statistical power (sensitivity) | +++ Large numbers of animals (50) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | +++ There was no significant difference in survival, but there was a significant decrease in body weight. There was no significant increase in neoplasm incidence but was a significant increase in preneoplasm incidence.
Exposure duration (sensitivity) | +++ A near life-span duration (106 weeks) was used.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 20-fold.
Outcome
Pathology | +++ All major organs and gross lesions were histologically evaluated and findings were verified by an independent pathologist.
Consistency between groups | +++ All groups were treated the same.
Study duration (sensitivity) | +++ A near life-span duration (106 weeks) was used.
Confounding
Confounding | ++ Drinking water contained 44.7 ug/l of dihaloacetic acids and 3.8 ug/l of dibromoacetic acid.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Tumor combinations were appropriate.

Overall utility: +++. Large numbers of animals per group were used in both sexes and were continuously monitored for disease. Three dose levels spanning a range of 200-fold were used. Lesions and all major organs were histologically evaluated and statistics were clearly reported.

## C.5 Bromochloroacetic Acid: Study Quality for Animal Studies

Table C-36 NTP 2009 (M Rat): Bromochloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups with initial body weights the same for each group.
Controls | +++ Concurrent vehicle controls were used.
Historical data | Yes
Animal model (sensitivity) | +++ Both sexes of non-transgenic animals were used and the strain is in common use.
Statistical power (sensitivity) | +++ Large numbers of animals (50) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | +++ There was no significant difference in survival, but there was a significant decrease in body weight and a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | +++ A near life-span duration (105 weeks) was used.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 4-fold.
Outcome
Pathology | +++ All major organs and gross lesions were histologically evaluated and findings were verified by an independent pathologist.
Consistency between groups | +++ All groups were treated the same.
Study duration (sensitivity) | +++ A near life-span duration (105 weeks) was used.
Confounding
Confounding | +++ The test agent was well characterized, animals were treated the same between groups, and were continually monitored for infectious diseases.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Tumor combinations were appropriate.

Overall utility: +++. A very high-quality study, with no major concerns.

Table C-37 NTP 2009 (F Rat): Bromochloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups with initial body weights the same for each group.
Controls | +++ Concurrent vehicle controls were used.
Historical data | Yes
Animal model (sensitivity) | +++ Both sexes of non-transgenic animals were used and the strain is in common use.
Statistical power (sensitivity) | +++ Large numbers of animals (50) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | +++ There was no significant difference in survival, but there was a significant decrease in body weight and a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | +++ A near life-span duration (105 weeks) was used.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 4-fold.
Outcome
Pathology | +++ All major organs and gross lesions were histologically evaluated and findings were verified by an independent pathologist.
Consistency between groups | +++ All groups were treated the same.
Study duration (sensitivity) | +++ A near life-span duration (105 weeks) was used.
Confounding
Confounding | +++ The test agent was well characterized, animals were treated the same between groups, and were continually monitored for infectious diseases.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Tumor combinations were appropriate.

Overall utility: +++. A very high-quality study, with no major concerns.

Table C-38 NTP 2009 (M Mouse): Bromochloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups with initial body weights the same for each group.
Controls | +++ Concurrent vehicle controls were used.
Historical data | Yes
Animal model (sensitivity) | +++ Both sexes of non-transgenic animals were used and the strain is in common use.
Statistical power (sensitivity) | +++ Large numbers of animals (50) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | +++ There was no significant difference in survival, but there was a significant decrease in body weight and a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | +++ A near life-span duration (105 weeks) was used.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 4-fold.
Outcome
Pathology | +++ All major organs and gross lesions were histologically evaluated and findings were verified by an independent pathologist.
Consistency between groups | +++ All groups were treated the same.
Study duration (sensitivity) | +++ A near life-span duration (105 weeks) was used.
Confounding
Confounding | +++ The test agent was well characterized, animals were treated the same between groups, and were continually monitored for infectious diseases.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Tumor combinations were appropriate.

Overall utility: +++. A very high-quality study, with no major concerns.

Table C-39 NTP 2009 (F Mouse): Bromochloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups with initial body weights the same for each group.
Controls | +++ Concurrent vehicle controls were used.
Historical data | Yes
Animal model (sensitivity) | +++ Both sexes of non-transgenic animals were used and the strain is in common use.
Statistical power (sensitivity) | +++ Large numbers of animals (50) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | +++ There was no significant difference in survival or body weight and there was a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | +++ A near life-span duration (105 weeks) was used.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 4-fold.
Outcome
Pathology | +++ All major organs and gross lesions were histologically evaluated and findings were verified by an independent pathologist.
Consistency between groups | +++ All groups were treated the same.
Study duration (sensitivity) | +++ A near life-span duration (105 weeks) was used.
Confounding
Confounding | +++ The test agent was well characterized, animals were treated the same between groups, and were continually monitored for infectious diseases.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Tumor combinations were appropriate.

Overall utility: +++. A very high-quality study, with no major concerns.

## C.6 Trichloroacetic Acid: Study Quality for Animal Studies

Table C-40 DeAngelo et al. 1997 (M Rat): Trichloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | Not reported.
Controls | +++ Concurrent vehicle controls of sodium chloride at equal molar concentrations as the trichloroacetic acid high dose group were used.
Historical data | No
Animal model (sensitivity) | ++ Only males of non-transgenic animals were used.
Statistical power (sensitivity) | +++ Moderate numbers of animals (29−32) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | ++[underlined: +]^a^ There was no significant difference in survival, but there was a significant increase in body weight. There was no significant difference in neoplasm incidence.
Exposure duration (sensitivity) | +++ A near life-span duration (104 weeks) was used.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 100-fold.
Outcome
Pathology | +++ Full necropsies with histological evaluations were performed.
Consistency between groups | +++ Groups were not reported to have been treated differently.
Study duration (sensitivity) | +++ A near life-span duration (104 weeks) was used.
Confounding
Confounding | +++ The rats were confirmed pathogen free and the chemical purity and stability were confirmed.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Lesions were reported, which included liver hyperplasia, adenomas, and carcinomas. The authors felt the hyperplasia were preneoplastic.

Overall utility: +++. A well conducted study on almost all aspects, but it only involved male rats.

^a^ ERRATUM: Errors were identified in the Report on Carcinogens Monograph on Haloacetic Acids Found as Water Disinfection By-products. The number of + signs in this cell was incorrect in the original table. This error has been corrected; one + sign was added and underlined.

Table C-41 DeAngelo 2008 (M Mouse [Study 1]): Trichloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups.
Controls | +++ Concurrent vehicle controls of 2 g/l of sodium chloride were used.
Historical data | No
Animal model (sensitivity) | +++ Only males of non-transgenic animals were used and the strain is in common use.
Statistical power (sensitivity) | +++ Moderate numbers of animals (30) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | +++ There was no significant difference in survival or body weight and there was a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | ++ A less than life-span duration (60 weeks) was used.
Dose-response (sensitivity) | +++ Three exposed dose levels were used, which increased by 10-fold each time, covering a wide dose range.
Outcome
Pathology | +++ A complete necropsy with histological examine was performed, including verification by an independent pathologist.
Consistency between groups | ++ All tissues were evaluated from 5 mice of the high dose and negative control groups, while other mice had most organs and all organs with gross lesions histologically evaluated.
Study duration (sensitivity) | ++ A less than life-span duration (60 weeks) was used.
Confounding
Confounding | +++ Infectious disease detection was used and the vehicle control was appropriate.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Only hepatocellular adenomas and carcinomas were combined.

Overall utility: +++. Three dose levels were used that spanned a 100-fold range. Most organs were histologically evaluated and evaluations were confirmed by an independent pathologist.

Table C-42 DeAngelo 2008 (M Mouse [Study 2]): Trichloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups.
Controls | +++ Concurrent vehicle controls of 1.5 g/l of neutralized acetic acid in drinking water was used.
Historical data | No
Animal model (sensitivity) | +++ Only males of non-transgenic animals were used and the strain is in common use.
Statistical power (sensitivity) | +++ A large number of animals (42−51) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | +++ There was no significant difference in survival or body weight and there was a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | +++ A near life-span duration (104 weeks) was used.
Dose-response (sensitivity) | + Only one exposure level was used.
Outcome
Pathology | +++ A complete necropsy with histological examine was performed, including verification by an independent pathologist.
Consistency between groups | +++ All treatment groups appear to have been treated similarly.
Study duration (sensitivity) | +++ A near life-span duration (104 weeks) was used.
Confounding
Confounding | +++ Infectious disease detection was used and husbandry was reported. Vehicle control was appropriate, though not ideal.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Only hepatocellular adenomas and carcinomas were combined.

Overall utility: ++. Only one dose level was tested but was given for a near life-span of a large number of animals. Most organs were histologically evaluated and evaluations were confirmed by an independent pathologist.

Table C-43 DeAngelo 2008 (M Mouse [Study 3]): Trichloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Mice were randomly assigned to exposure groups.
Controls | +++ Concurrent vehicle controls of neutralized drinking water was used.
Historical data | No
Animal model (sensitivity) | +++ Only males of non-transgenic animals were used and the strain is in common use.
Statistical power (sensitivity) | +++ Large numbers of animals (51−53) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | ++ There was no significant difference in survival or body weight and there was a significant increase in neoplasm incidence, but the highest level was low compared to the other studies by this author.
Exposure duration (sensitivity) | +++ A near life-span duration (104 weeks) was used.
Dose-response (sensitivity) | ++ Two expose levels were used that spanned a range of 10-fold.
Outcome
Pathology | +++ A complete necropsy with histological examine was performed, including verification by an independent pathologist.
Consistency between groups | +++ All exposure groups appear to have been treated similarly.
Study duration (sensitivity) | +++ A near life-span duration (104 weeks) was used.
Confounding
Confounding | +++ Infectious disease detection was used and the vehicle control was appropriate.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Only hepatocellular adenomas and carcinomas were combined.

Overall utility: ++. Only two dose levels were tested but they were low compared to other studies and were given for near a life-span of time to a large number of animals. Most organs were histologically evaluated and evaluations were confirmed by an independent pathologist.

Table C-44 Herren-Freund et al. 1987 (M Mouse): Trichloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | Not reported.
Controls | +++ Concurrent vehicle controls of 2 g/l of sodium chloride to match that found in exposed groups and a positive control of phenobarbital at 500 mg/l (positive controls are not reported here) were used.
Historical data | No
Animal model (sensitivity) | ++ Only males of non-transgenic animals were used.
Statistical power (sensitivity) | ++ Moderate numbers of animals (22−26) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | +++ Survival was not reported and body weight was significantly decreased. There was a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | +++ A less than life-span duration (61 weeks) was used.
Dose-response (sensitivity) | + One exposure level was used, so dose response relationships could not be measured.
Outcome
Pathology | ++ Only the liver was histologically examined.
Consistency between groups | +++ All groups were treated the same.
Study duration (sensitivity) | +++ A less than life-span duration (61 weeks) was used.
Confounding
Confounding | +++ Disease surveillance was not reported, but chemical purity and stability were tested.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Tumor types were not combined.

Overall utility: ++. The durations were less than near life-span. Only males were tested at a single dose level and only livers were histologically evaluated.

Table C-45 Herren-Freund et al. 1987 (M Mouse): Trichloroacetic Acid: Drinking Water (I/P)

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | Not reported.
Controls | +++ Concurrent vehicle controls of 2 g/l of sodium chloride to match that found in exposed groups and a positive control of phenobarbital at 500 mg/l (positive controls are not reported here) were used.
Historical data | No
Animal model (sensitivity) | ++ Only males of non-transgenic animals were used.
Statistical power (sensitivity) | ++ Moderate numbers of animals (22−26) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | +++ Survival was not reported and body weight was significantly decreased. There was a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | +++ A less than life-span duration (61 weeks) was used.
Dose-response (sensitivity) | + Two exposure levels were used which spanned a range of 2.5-fold.
Outcome
Pathology | ++ Only the liver was histologically examined.
Consistency between groups | +++ All groups were treated the same.
Study duration (sensitivity) | +++ A less than life-span duration (61 weeks) was used.
Confounding
Confounding | +++ Disease surveillance was not reported, but chemical purity and stability were tested.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Tumor types were not combined.

Overall utility: ++. The duration was less than near life-span. Only males were tested at two narrow dose levels and only livers were histologically evaluated.

Table C-46 Pereira 1996 (F Mouse [Study 1]): Trichloroacetic Acid (TCA): Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ It was not reported if animals were randomly assigned to exposure groups, but they were necropsied blinded and the mice were randomly assigned an ID number, which suggests they were randomly assigned to treatment groups, but it is not known for sure.
Controls | +++ Concurrent vehicle controls of sodium chloride at equal molar concentrations as in the high dose group were used.
Historical data | No
Animal model (sensitivity) | ++ Only females of non-transgenic animals were used.
Statistical power (sensitivity) | ++ The number of animals (15−90) varied considerably for each group.
Exposure
Chemical characterization | Chemical purity and stability were not reported.
Dosing regimen | +++ Survival was not reported, but there was a significant decreased in body weight and a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | +++ A near life-span duration (576 days) was used.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 10-fold.
Outcome
Pathology | ++ Only the liver was histologically examined.
Consistency between groups | +++ Groups were not reported to have been treated differently.
Study duration (sensitivity) | +++ A near life-span duration (576 days) was used.
Confounding
Confounding | ++ Continual disease surveillance and survival were not reported. The high exposure group had a significant decrease in water consumption.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Lesions were reported, which included liver foci, adenomas, and carcinomas. The authors felt the foci were preneoplastic.

Overall utility: ++. The chemicals were not characterized, not even purity was reported. Disease surveillance was not continually monitored. A variable number of only females were tested, with only their livers examined histologically.

Table C-47 Pereira 1996 (F Mouse [Study 2]): Trichloroacetic Acid (TCA): Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ It was not reported if animals were randomly assigned to exposure groups, but they were necropsied blinded and the mice were randomly assigned an ID number, which suggests they were randomly assigned to treatment groups, but it is not known for sure.
Controls | +++ Concurrent vehicle controls of sodium chloride at equal molar concentrations as in the high dose group were used.
Historical data | No
Animal model (sensitivity) | ++ Only females of non-transgenic animals were used.
Statistical power (sensitivity) | ++ The number of animals (15−90) varied considerably for each group.
Exposure
Chemical characterization | Chemical purity and stability were not reported.
Dosing regimen | +++ Survival was not reported, but there was a significant decreased in body weight and a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | ++ A less than life-span duration (360 days) was used.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 10-fold.
Outcome
Pathology | ++ Only the liver was histologically examined.
Consistency between groups | +++ Groups were not reported to have been treated differently.
Study duration (sensitivity) | +++ A less than life-span duration (360 days) was used.
Confounding
Confounding | ++ Continual disease surveillance and survival were not reported. The high exposure group had a significant decrease in water consumption.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Lesions were reported, which included liver foci, adenomas, and carcinomas. The authors felt the foci were preneoplastic.

Overall utility: ++. The chemicals were not characterized, not even purity was reported. Disease surveillance was not continually monitored. A variable number of only females were tested, with only their livers examined histologically.

Table C-48 Pereira et al. 1997 (F Mouse): TCA: Drinking Water (I/P)

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups with initial body weights the same for each group.
Controls | +++ Concurrent controls were appropriate for an initiation/promotion study in which all groups received the initiator (NMU) and the negative control group was given only the initiator and promotor vehicle.
Historical data | No
Animal model (sensitivity) | ++ Only females of non-transgenic animals were used.
Statistical power (sensitivity) | ++ Small, but sufficient numbers of animals (>20) were used for each group.
Exposure
Chemical characterization | Chemical purity and stability were not reported.
Dosing regimen | +++ There was no significant decrease in survival or body weight and there was a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | +++ Animals were exposed for 44 weeks, starting 4 weeks after a single injection of the initiator. This is short for carcinogenicity studies, but initiation/promotion studies are normally shorter and tumors were significantly induced.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 3-fold.
Outcome
Pathology | ++ Only the liver was histologically examined.
Consistency between groups | +++ Groups were not reported to have been treated differently.
Study duration (sensitivity) | +++ A less than near life-span duration (48 weeks) was used, but initiation/promotion studies are normally short.
Confounding
Confounding | ++ Continual disease surveillance and survival were not reported.
Reporting and analysis
Reporting data and statistics | ++ Significance levels were reported, but the statistical test was not reported.
Combining lesions | +++ Lesions were reported, which included liver foci, adenomas, and carcinomas. The authors felt the foci were preneoplastic.

Overall utility: +. The chemicals were not characterized, not even purity was reported. Disease surveillance was not reported. A low number of only females were tested, with only their livers examined histologically. The statistical methods were not reported.

Table C-49 Bull et al. 1990 (M Mouse): Trichloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups.
Controls | +++ Concurrent vehicle controls were used.
Historical data | No
Animal model (sensitivity) | ++ Only males of non-transgenic animals were used.
Statistical power (sensitivity) | + Small numbers of animals (11−24) were used for each group.
Exposure
Chemical characterization | ++ Chemical purity and stability were not verified.
Dosing regimen | +++ There were no deaths and body weight was not reported. There was a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | +++ A less than life-span duration (52 weeks) was used.
Dose-response (sensitivity) | ++ Two exposure levels were used that spanned a range of 2-fold.
Outcome
Pathology | + Only livers from some animals were histologically evaluated. Results only reported overall lesions, which include hyperplasia. Liver lesions that were histologically evaluated were randomly selected and blindly evaluated.
Consistency between groups | + All untreated control lesions were histologically evaluated, but only some of the exposed groups were.
Study duration (sensitivity) | +++ A less than life-span duration (52 weeks) was used.
Confounding
Confounding | + Disease surveillance was not reported. Only samples of liver lesions were histologically evaluated and inappropriately reported.
Reporting and analysis
Reporting data and statistics | + Statistical evaluations were rarely reported and incidences that could be significant by Fisher's Exact test (calculated by NTP) were not reported as significant, so no NTP calculations were included.
Combining lesions | ++ Only total lesions were adequately reported to allow for quantitation of the results. These included liver hyperplasic nodules, hepatocellular adenoma, and hepatocellular carcinoma, which entail and continuum of the same disease process, however there were 4/73 lesions types that were also included but were not hyperplastic or neoplastic.

Overall utility: +. The chemical was not characterized, disease surveillance was not reported. A low number of mice per group were exposed for a less than near life-span duration and only males had results reported. Only livers were histologically examined. Not all lesions were histologically evaluated, but instead samples of lesions were evaluated. Results were reported so that incidences of specific neoplasms could not be determined but could be estimated.

Table C-50 Von Tungeln et al. 2002 (M+F Mouse [Study 1]): Trichloroacetic Acid: IP Injection

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | + Randomization was not reported. However, survival during the first 28 days of age ranged from 100% to 71% (data not reported). After 28 days of age, surviving mice were allocated to each treatment group, after which survival was 92% or higher.
Controls | +++ Concurrent vehicle controls of DMSO and 4-aminobiphenyl positive controls were used.
Historical data | No
Animal model (sensitivity) | +++ Both sexes of non-transgenic animals were used. Modifying factor is age of animals at study start.
Statistical power (sensitivity) | ++ Moderate numbers of animals (22−24) were used for each group.
Exposure
Chemical characterization | Chemical purity and stability were not reported.
Dosing regimen | + There was no significant difference in survival and body weight was not reported. There was no significant difference in neoplasm incidence.
Exposure duration (sensitivity) | + Two doses were administered at the beginning of the study, no additional exposure occurred throughout the study.
Dose-response (sensitivity) | ++ Two exposure levels were used that spanned a range of 2-fold.
Outcome
Pathology | ++ Necropsies and histological evaluations were stated to have occurred, but only incidences of liver tumors were reported.
Consistency between groups | ++ Before the mice reached 28 days of age, mortality was as high as 29% and then a set number of the survivors were used for the remainder of the study. No information was reported about the early mortality.
Study duration (sensitivity) | +++ Duration was near life-span (20 months).
Confounding
Confounding | ++ Mice were reported to be specific pathogen free, but mortality was high before the age of 28 days and this early mortality was not reported.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Only hepatocellular adenomas and carcinomas were combined.

Overall utility: ++. The study used both positive and negative controls but did not characterize the chemicals and used a small, number of male mice per group. Only two doses were administered at two narrow dose levels, though the duration of observation was almost near life-span. Early mortality was not reported.

Table C-51 Von Tungeln et al. 2002 (M+F Mouse [Study 2]): Trichloroacetic Acid: IP Injection

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | + Randomization was not reported. However, survival during the first 28 days of age ranged from 100% to 71% (data not reported). After 28 days of age, surviving mice were allocated to each treatment group, after which survival was 92% or higher.
Controls | +++ Concurrent vehicle controls of DMSO and 4-aminobiphenyl positive controls were used.
Historical data | No
Animal model (sensitivity) | +++ Both sexes of non-transgenic animals were used. Modifying factor is age of animals at study start.
Statistical power (sensitivity) | ++ Moderate numbers of animals (22−24) were used for each group.
Exposure
Chemical characterization | Chemical purity and stability were not reported.
Dosing regimen | + There was no significant difference in survival and body weight was not reported. There was no significant difference in neoplasm incidence after exposure of neonatal mouse to TCA.
Exposure duration (sensitivity) | + Two doses were administered at the beginning of the study, no additional exposure occurred throughout the study.
Dose-response (sensitivity) | ++ Two exposure levels were used that spanned a range of 2-fold.
Outcome
Pathology | ++ Necropsies and histological evaluations were stated to have occurred, but only incidences of liver tumors were reported.
Consistency between groups | ++ Before the mice reached 28 days of age, mortality was as high as 29% and then a set number of the survivors were used for the remainder of the study. No information was reported about the early mortality.
Study duration (sensitivity) | ++ Duration was less than life-span (12 months).
Confounding
Confounding | ++ Mice were reported to be specific pathogen free, but mortality was high before the age of 28 days and this early mortality was not reported.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Only hepatocellular adenomas and carcinomas were combined.

Overall utility: ++. The study used both positive and negative controls but did not characterize the chemicals and used a small, number of male mice per group. Only two doses were administered at two narrow dose levels, though the duration of observation was almost near life-span. Early mortality was not reported.

## C.7 Bromodichloroacetic Acid: Study Quality for Animal Studies

Table C-52 NTP 2015 (M Rat): Bromodichloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups but were not blinded.
Controls | +++ Concurrent vehicle controls were used.
Historical data | Yes
Animal model (sensitivity) | +++ Both sexes of non-transgenic animals were used.
Statistical power (sensitivity) | +++ Large numbers of animals (50) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | +++ There was no significant decrease in survival, but there was a decrease in body weight and a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | +++ A near life-span duration (105 weeks) was used.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 4-fold.
Outcome
Pathology | +++ All major organs and gross lesions were histologically evaluated and findings were verified by an independent pathologist.
Consistency between groups | +++ All groups were treated the same.
Study duration (sensitivity) | +++ A near life-span duration (105 weeks) was used.
Confounding
Confounding | +++ The test agent was well characterized, animals were treated the same between groups, and were continually monitored for infectious diseases.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Tumor combinations were appropriate.

Overall utility: +++. Well reported and designed study, with a large number of animals of both sexes exposed for near life-span at three exposure levels.

Table C-53 NTP 2015 (F Rat): Bromodichloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups but were not blinded.
Controls | +++ controls adequate number
Historical data | Yes
Animal model (sensitivity) | +++ Both sexes of non-transgenic animals were used.
Statistical power (sensitivity) | +++ Large numbers of animals (49−51) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | +++ There was a significant decrease in survival and body weight and a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | +++ A near life-span duration (104 weeks) was used.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 4-fold.
Outcome
Pathology | +++ All major organs and gross lesions were histologically evaluated and findings were verified by an independent pathologist.
Consistency between groups | +++ All groups were treated the same.
Study duration (sensitivity) | +++ A near life-span duration (104 weeks) was used.
Confounding
Confounding | +++ The test agent was well characterized, animals were treated the same between groups, and were continually monitored for infectious diseases.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Tumor combinations were appropriate.

Overall utility: +++. Well reported and designed study, with a large number of animals of both sexes exposed for near life-span at three exposure levels.

Table C-54 NTP 2015 (M Mouse): Bromodichloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups but were not blinded.
Controls | +++ Concurrent vehicle controls were used.
Historical data | Yes
Animal model (sensitivity) | +++ Both sexes of non-transgenic animals were used.
Statistical power (sensitivity) | +++ Large numbers of animals (50−51) were used for each group.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | +++ There was a significant decrease in survival and body weight, with a significant increase in neoplasm incidence.
Exposure duration (sensitivity) | +++ A near life-span duration (105 weeks) was used.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 4-fold.
Outcome
Pathology | +++ All major organs and gross lesions were histologically evaluated and findings were verified by an independent pathologist.
Consistency between groups | +++ All groups were treated the same.
Study duration (sensitivity) | +++ A near life-span duration (105 weeks) was used.
Confounding
Confounding | +++ The test agent was well characterized, animals were treated the same between groups, and were continually monitored for infectious diseases.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Tumor combinations were appropriate.

Overall utility: +++. Well reported and designed study, with a large number of animals of both sexes exposed for near life-span at three exposure levels.

Table C-55 NTP 2015 (F Mouse): Bromodichloroacetic Acid: Drinking Water

Study Utility Domain and Question | Rating and Rationale
Study design
Randomization | +++ Animals were randomly assigned to exposure groups but were not blinded.
Controls | +++ Concurrent vehicle controls were used.
Historical data | Yes
Animal model (sensitivity) | +++ Both sexes of non-transgenic animals were used.
Statistical power (sensitivity) | +++ There was no significant decrease in survival, but there was a decrease in body weight and a significant increase in neoplasm incidence.
Exposure
Chemical characterization | +++ Chemical purity and stability were well characterized.
Dosing regimen | +++ Three exposure levels were used that spanned a range of 4-fold.
Exposure duration (sensitivity) | +++ A near life-span duration (105 weeks) was used.
Dose-response (sensitivity) | +++ Three exposure levels were used that spanned a range of 4-fold.
Outcome
Pathology | +++ All major organs and gross lesions were histologically evaluated and findings were verified by an independent pathologist.
Consistency between groups | +++ All groups were treated the same.
Study duration (sensitivity) | +++ A near life-span duration (105 weeks) was used.
Confounding
Confounding | +++ The test agent was well characterized, animals were treated the same between groups, and were continually monitored for infectious diseases.
Reporting and analysis
Reporting data and statistics | +++ Appropriate statistical analyses were reported.
Combining lesions | +++ Tumor combinations were appropriate.

Overall utility: +++. Well reported and designed study, with a large number of animals of both sexes exposed for near life-span at three exposure levels.

## C.8 Animal Studies for Haloacetic Acids: Results by Tumor

Studies in this section are grouped by number of halogen substitutions on the alpha carbon of acetic acid (mono- to di- to trihaloacetic acids) followed by increasing electrophilicity of the HAA (i.e., chloro- to bromo- to iodoacetic acid; dichloro- to dibromoacetic acid; trichloro- to tribromo- to bromodichloroacetic acid). This format follows the text in the monograph. Animals for a given study are grouped by male then female rats first, followed by male then female mice; monochloroacetic acid is the only gavage study and is listed first, followed by drinking water studies.

Table C-56 Liver Tumors

Reference and Study Design | Exposure | Dose Levels | Tumor Incidence (n/N) (%) | Comments
NTP (1992) Animal: Rat F344/N M 6–7 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 15 30 mg/kg bw 5 doses/week × 104 weeks | Liver – Adenoma | | Survival: After 104 weeks, the survival of the 30 mg/kg group was lower than controls and there was a significant trend: 27/53*(trend = 0.011) – 21/53, 16/53*(=0.015). Body weight: Body weights were similar to controls during the 6 and 15 month interim evaluations as well as the 2 year study. Other comments: No neoplasms were found at the 6 month evaluation and no treatment related neoplasms were found at the 15 month interim evaluation or at the end of the study. Strengths and limitations: The study was well conducted to rule out confounding and with a strong power to detect tumor induction. However, only two exposed dose levels were tested, which limit the detection of dose response relationships. Rats were more sensitive to non-neoplastic effects, causing death and cardiomyopathy during the short term studies, compared to mice and so their dose levels were much lower.
NTP (1992) Animal: Rat F344/N M 6–7 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 15 30 mg/kg bw 5 doses/week × 104 weeks | 0 | 1/53 (2%)
NTP (1992) Animal: Rat F344/N M 6–7 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 15 30 mg/kg bw 5 doses/week × 104 weeks | 15 | 0/53
NTP (1992) Animal: Rat F344/N M 6–7 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 15 30 mg/kg bw 5 doses/week × 104 weeks | 30 | 1/53 (2%)
NTP (1992) Animal: Rat F344/N M 6–7 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 15 30 mg/kg bw 5 doses/week × 104 weeks | Liver – Carcinoma
NTP (1992) Animal: Rat F344/N M 6–7 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 15 30 mg/kg bw 5 doses/week × 104 weeks | 0 | 0/53
NTP (1992) Animal: Rat F344/N M 6–7 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 15 30 mg/kg bw 5 doses/week × 104 weeks | 15 | 1/53 (2%)
NTP (1992) Animal: Rat F344/N M 6–7 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 15 30 mg/kg bw 5 doses/week × 104 weeks | 30 | 0/53
NTP (1992) Animal: Rat F344/N F 6–7 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 15 30 mg/kg bw 5 doses/week × 104 weeks | Liver – Adenoma | | Survival: After 104 weeks, the survival of the 30 mg/kg group was lower than controls and there was a significant trend: 37/53*(Trend = 0.043) – 19/53***(=0.001), 26/53*(=0.046). Body weight: Body weights were similar to controls during the 6 and 15 month interim evaluations as well as the 2 year study. Other comments: No neoplasms were found at the 6 month evaluation and no treatment related neoplasms were found at the 15 month interim evaluation or at the end of the study. Strengths and limitations: The study was well conducted to rule out confounding and with a strong power to detect tumor induction. However, only two exposed dose levels were tested, which limit the detection of dose response relationships. Rats were more sensitive to non-neoplastic effects, causing death and cardiomyopathy during the short term studies, compared to mice and so their dose levels were much lower.
NTP (1992) Animal: Rat F344/N F 6–7 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 15 30 mg/kg bw 5 doses/week × 104 weeks | 0 | 1/53 (2%)
NTP (1992) Animal: Rat F344/N F 6–7 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 15 30 mg/kg bw 5 doses/week × 104 weeks | 15 | 0/53
NTP (1992) Animal: Rat F344/N F 6–7 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 15 30 mg/kg bw 5 doses/week × 104 weeks | 30 | 0/53
NTP (1992) Animal: Mouse B6C3F1 M 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg in deionized water 5 doses/week × 104 weeks | Liver – Adenoma^a^ | | Survival: The 100 mg/kg group was lower than controls and there was a significant trend: 46/60***(trend <0.001) – 39/60, 21/60***(<0.001). Body weight: Body weights were similar to controls. Strengths and limitations: The study was well conducted to rule out confounding and with a strong power to detect tumor induction. However, only two exposed dose levels were tested, which limit the detection of dose response relationships.
NTP (1992) Animal: Mouse B6C3F1 M 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg in deionized water 5 doses/week × 104 weeks | 0 | 6/60 (12.7%)
NTP (1992) Animal: Mouse B6C3F1 M 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg in deionized water 5 doses/week × 104 weeks | 50 | 6/59 (14.8%)
NTP (1992) Animal: Mouse B6C3F1 M 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg in deionized water 5 doses/week × 104 weeks | 100 | 1/59 (4.2%)
NTP (1992) Animal: Mouse B6C3F1 M 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg in deionized water 5 doses/week × 104 weeks | Trend p value: =0.0.059N
NTP (1992) Animal: Mouse B6C3F1 M 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg in deionized water 5 doses/week × 104 weeks | Liver – Carcinoma^a^
NTP (1992) Animal: Mouse B6C3F1 M 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg in deionized water 5 doses/week × 104 weeks | 0 | 6/60 (11.7%)
NTP (1992) Animal: Mouse B6C3F1 M 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg in deionized water 5 doses/week × 104 weeks | 50 | 2/59 (4.7%)
NTP (1992) Animal: Mouse B6C3F1 M 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg in deionized water 5 doses/week × 104 weeks | 100 | 5/59 (19.9%)
NTP (1992) Animal: Mouse B6C3F1 M 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg in deionized water 5 doses/week × 104 weeks | Trend p value: =0.440N
NTP (1992) Animal: Mouse B6C3F1 M 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg in deionized water 5 doses/week × 104 weeks | Liver – Adenoma or carcinoma^a^
NTP (1992) Animal: Mouse B6C3F1 M 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg in deionized water 5 doses/week × 104 weeks | 0 | 12/60 (23.6%)
NTP (1992) Animal: Mouse B6C3F1 M 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg in deionized water 5 doses/week × 104 weeks | 50 | 8/59 (19.1%)
NTP (1992) Animal: Mouse B6C3F1 M 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg in deionized water 5 doses/week × 104 weeks | 100 | 6/59 (23.3%)
NTP (1992) Animal: Mouse B6C3F1 M 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg in deionized water 5 doses/week × 104 weeks | Trend p value: =0.082N
NTP (1992) Animal: Mouse B6C3F1 F 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg in deionized water 5 doses/week × 104 weeks | Liver – Adenoma | | Survival: Survival of the exposed groups were similar to controls: 42/60 – 40/60, 44/60. Body weight: Body weights of the low dose group were similar to controls, but after a year the high dose group had significantly lower body weight. Strengths and limitations: The study was well conducted to rule out confounding and with a strong power to detect tumor induction. However, only two exposed dose levels were tested, which limit the detection of dose response relationships.
NTP (1992) Animal: Mouse B6C3F1 F 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg in deionized water 5 doses/week × 104 weeks | 0 | 1/60 (2%)
NTP (1992) Animal: Mouse B6C3F1 F 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg in deionized water 5 doses/week × 104 weeks | 50 | 1/60 (2%)
NTP (1992) Animal: Mouse B6C3F1 F 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg in deionized water 5 doses/week × 104 weeks | 100 | 2/60 (3%)
NTP (1992) Animal: Mouse B6C3F1 F 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg in deionized water 5 doses/week × 104 weeks | Liver – Carcinoma
NTP (1992) Animal: Mouse B6C3F1 F 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg in deionized water 5 doses/week × 104 weeks | 0 | 0/60
NTP (1992) Animal: Mouse B6C3F1 F 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg in deionized water 5 doses/week × 104 weeks | 50 | 1/59 (2%)
NTP (1992) Animal: Mouse B6C3F1 F 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg in deionized water 5 doses/week × 104 weeks | 100 | 0/60
DeAngelo et al. (1997) Animal: Rat F344/N M 28–30 days Study duration: 104 weeks | Agent: Monochloroacetic acid >99% Treatment: Drinking water 0+ 50 500 2,000++ mg/L in drinking water ad libitum × 104 weeks + 31–32 mM NaCl (~isomolar to 5,000 mg/L TCA) ++ 2,000 mg/L × 8 wk, then 1,500 mg/L to 24 weeks, then 1,000 mg/L; averaging 1,100 mg/L throughout the study | Liver – Adenoma | | Survival: No significant difference in survival: 23/29–24/32, 23/32, 25/29. Body weight: The 2.0 g/l MCA was decreased to 1.5 g/l after 8 weeks and to 1 g/l after 24 weeks because of significant differences in body weight gain. The 0.5 g/l group had 13% lower body weight than untreated controls. Significantly increased preneoplastic lesions: Hyperplastic nodules were reported but were not significantly increased. They are likely considered part of the continuum toward neoplasia as it was reported combined with adenomas and carcinomas as proliferative lesions and other publications by this author under similar studies reported that a similar lesion (large foci of cellular alteration) was only distinguishable from adenomas because the nodules caused compression at less than 80% of its surface (DeAngelo et al. 2008). Other comments: Amount of water consumed was similar among groups (76.9 ml/kg/d–70.5, ml/kg/d, 55.6 ml/kg/d, 55.5 ml/kg/d). Strengths and limitations: A well conducted study on almost all aspects, but only involved male rats.
DeAngelo et al. (1997) Animal: Rat F344/N M 28–30 days Study duration: 104 weeks | | 0 | 1/23 (4%)
DeAngelo et al. (1997) Animal: Rat F344/N M 28–30 days Study duration: 104 weeks | | 50 | 2/25 (8%)
DeAngelo et al. (1997) Animal: Rat F344/N M 28–30 days Study duration: 104 weeks | | 500 | 0/23
DeAngelo et al. (1997) Animal: Rat F344/N M 28–30 days Study duration: 104 weeks | | 2,000 | 1/25 (4%)
DeAngelo et al. (1997) Animal: Rat F344/N M 28–30 days Study duration: 104 weeks | | Liver – Carcinoma
DeAngelo et al. (1997) Animal: Rat F344/N M 28–30 days Study duration: 104 weeks | | 0 | 0/23
DeAngelo et al. (1997) Animal: Rat F344/N M 28–30 days Study duration: 104 weeks | | 50 | 0/25
DeAngelo et al. (1997) Animal: Rat F344/N M 28–30 days Study duration: 104 weeks | | 500 | 0/23
DeAngelo et al. (1997) Animal: Rat F344/N M 28–30 days Study duration: 104 weeks | | 2,000 | 0/25
DeAngelo et al. (1997) Animal: Rat F344/N M 28–30 days Study duration: 104 weeks | | Liver – Adenoma or carcinoma
DeAngelo et al. (1997) Animal: Rat F344/N M 28–30 days Study duration: 104 weeks | | 0 | 1/23 (4%)
DeAngelo et al. (1997) Animal: Rat F344/N M 28–30 days Study duration: 104 weeks | | 50 | 2/25 (8%)
DeAngelo et al. (1997) Animal: Rat F344/N M 28–30 days Study duration: 104 weeks | | 500 | 0/23
DeAngelo et al. (1997) Animal: Rat F344/N M 28–30 days Study duration: 104 weeks | | 2,000 | 1/25 (4%)
DeAngelo et al. (1996) Animal: Rat (Study 1) F344 M 28–30 days (59–79g bw) Study duration: 100 weeks | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 50 500 5,000++ mg/L in drinking water ad libitum × 100 weeks + 2 g/L NaCl (~isomolar to 5,000 mg/l DCA) ++ 2,500 mg/L at 9 weeks then 2,000 mg/L after 23 wks then 1,000 mg/L after 52 wks and stopped at 60 weeks due to peripheral neuropathy and was not included in the study results. | Liver – Adenoma | | Survival: There were no significant differences in survival in the 0.05 or 0.5 g/l groups. The 5 g/l group rats had irreversible peripheral neuropathy and were sacrificed at 60 weeks and were excluded from the study analysis. Body weight: Body weights did not differ after 100 weeks of treatment. Significantly increased preneoplastic lesions: Hyperplastic nodules were not significantly increased. They are likely considered part of the continuum toward neoplasia as it was reported combined with adenomas and carcinomas as proliferative lesions and other publications by this author under similar studies reported that a similar lesion (large foci of cellular alteration) was only distinguishable from adenomas because the nodules caused compression at less than 80% of its surface (DeAngelo et al. 2008). Other comments: The exact value for N at the beginning of the study is not confirmed as the paper did not clearly report them. Water consumption did not differ among groups. The percent incidence was reported and fractional incidence was extrapolated from that and the original number of animals per group, however these calculations did not exactly match the percent incidence. All non-hepatic neoplasms were considered spontaneous and not treatment related and included, testicular cancer (97%–100%, 100%) and leukemia (24%–20%, 43%). Strengths and limitations: Animals were certified pathogen free, though were not reported to be continuously monitored for disease. Only two exposed dose levels were effectively reported and only males were tested. The duration was near life-span and historical controls were considered during data analysis. However, only liver lesion incidences were reported.
DeAngelo et al. (1996) Animal: Rat (Study 1) F344 M 28–30 days (59–79g bw) Study duration: 100 weeks | | 0 | 1/23 (4.4%)
DeAngelo et al. (1996) Animal: Rat (Study 1) F344 M 28–30 days (59–79g bw) Study duration: 100 weeks | | 50 | 0/26
DeAngelo et al. (1996) Animal: Rat (Study 1) F344 M 28–30 days (59–79g bw) Study duration: 100 weeks | | 500 | 5/29 (17.2%)
DeAngelo et al. (1996) Animal: Rat (Study 1) F344 M 28–30 days (59–79g bw) Study duration: 100 weeks | | Trend p value: <0.05
DeAngelo et al. (1996) Animal: Rat (Study 1) F344 M 28–30 days (59–79g bw) Study duration: 100 weeks | | Liver – Carcinoma
DeAngelo et al. (1996) Animal: Rat (Study 1) F344 M 28–30 days (59–79g bw) Study duration: 100 weeks | | 0 | 0/23
DeAngelo et al. (1996) Animal: Rat (Study 1) F344 M 28–30 days (59–79g bw) Study duration: 100 weeks | | 50 | 0/26
DeAngelo et al. (1996) Animal: Rat (Study 1) F344 M 28–30 days (59–79g bw) Study duration: 100 weeks | | 500 | 3/29 (10.3%)
DeAngelo et al. (1996) Animal: Rat (Study 1) F344 M 28–30 days (59–79g bw) Study duration: 100 weeks | | Trend p value: <0.05
DeAngelo et al. (1996) Animal: Rat (Study 1) F344 M 28–30 days (59–79g bw) Study duration: 100 weeks | | Liver – Adenoma or carcinoma
DeAngelo et al. (1996) Animal: Rat (Study 1) F344 M 28–30 days (59–79g bw) Study duration: 100 weeks | | 0 | 1/23 (4.4%)
DeAngelo et al. (1996) Animal: Rat (Study 1) F344 M 28–30 days (59–79g bw) Study duration: 100 weeks | | 50 | 0/21
DeAngelo et al. (1996) Animal: Rat (Study 1) F344 M 28–30 days (59–79g bw) Study duration: 100 weeks | | 500 | 6/23* (24.1%)
DeAngelo et al. (1996) Animal: Rat (Study 1) F344 M 28–30 days (59–79g bw) Study duration: 100 weeks | | Trend p value: <0.01
DeAngelo et al. (1996) Animal: Rat (Study 2) F344 M 28–30 days (59–79g bw) Study duration: 103 weeks | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 2,500++ mg/L in deionized water ad libitum × 103 weeks + NaCl in the first experiment had no effect on water consumption or tumor incidence, so was not included here ++ 1,500 mg/L at 8 weeks then 1,000 mg/L after 26 weeks due to mild transient neurotoxicity | Liver – Adenoma | | Survival: There were no significant differences in survival in the 0.05 or 0.5 g/l groups. The 5 g/l group rats had irreversible peripheral neuropathy and were sacrificed at 60 weeks and were excluded from the study analysis. Body weight: Body weights in the exposed group were significantly less than (73%) those in the untreated control group after 103 weeks of treatment. Significantly increased preneoplastic lesions: Hyperplastic nodules were not significantly increased. They are likely considered part of the continuum toward neoplasia as it was reported combined with adenomas and carcinomas as proliferative lesions and other publications by this author under similar studies reported that a similar lesion (large foci of cellular alteration) was only distinguishable from adenomas because the nodules caused compression at less than 80% of its surface (DeAngelo et al. 2008). Other comments: The exact value for N at the beginning of the study is not confirmed as the paper did not clearly report them. Water consumption did not differ among groups. The percent incidence was reported and fractional incidence was extrapolated from that and the original number of animals per group, however these calculations did not exactly match the percent incidence. All non-hepatic neoplasms were considered spontaneous and not treatment related and included, testicular cancer (97%–100%) and leukemia (9%– 11%). Strengths and limitations: Animals were certified pathogen free, though were not reported to be continuously monitored for disease. Only one exposed dose level was tested and only males were tested. The duration was near life-span and historical controls were considered during data analysis. However, only liver lesion incidences were reported.
DeAngelo et al. (1996) Animal: Rat (Study 2) F344 M 28–30 days (59–79g bw) Study duration: 103 weeks | | 0 | 0/33
DeAngelo et al. (1996) Animal: Rat (Study 2) F344 M 28–30 days (59–79g bw) Study duration: 103 weeks | | 2,500 | 3/28 (10.7%)
DeAngelo et al. (1996) Animal: Rat (Study 2) F344 M 28–30 days (59–79g bw) Study duration: 103 weeks | | Liver – Carcinoma
DeAngelo et al. (1996) Animal: Rat (Study 2) F344 M 28–30 days (59–79g bw) Study duration: 103 weeks | | 0 | 1/33 (3%)
DeAngelo et al. (1996) Animal: Rat (Study 2) F344 M 28–30 days (59–79g bw) Study duration: 103 weeks | | 2,500 | 6/28* (21.4%)
DeAngelo et al. (1996) Animal: Rat (Study 2) F344 M 28–30 days (59–79g bw) Study duration: 103 weeks | | Liver – Adenoma or carcinoma
DeAngelo et al. (1996) Animal: Rat (Study 2) F344 M 28–30 days (59–79g bw) Study duration: 103 weeks | | 0 | 1/28 (3%)
DeAngelo et al. (1996) Animal: Rat (Study 2) F344 M 28–30 days (59–79g bw) Study duration: 103 weeks | | 2,500 | 8/27** (28.6%)
Richmond et al. (1995) Animal: Rat F344 M 28 days Study duration: 104 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0+ 50 500 2,400 mg/L in drinking water (pH 7.0) × 60++ or 104 weeks + 2,000 mg/L NaCl ++ high dose (2,400 mg/L) stopped at 60 weeks due to tumors and hind limb paralysis | Liver – Adenoma | | Survival: Survival was not clearly reported, but based on 7 animals sacrificed at 15, 30, 45, and for all but the high dose group, 60 week time points survival was estimated from the 60 animals per group at the beginning of the study to be: 51/60–54/60, 57/60, 51/60. Body weight: Not reported. Significantly increased preneoplastic lesions: Hyperplastic nodules were significantly increased at 2,400 mg/L (all high-dose animals were sacrificed at 60 d due to hind limb paralysis and tumors. They are likely considered part of the continuum toward neoplasia as it was reported combined with adenomas and carcinomas as proliferative lesions and other publications by this author under similar studies reported that a similar lesion (large foci of cellular alteration) was only distinguishable from adenomas because the nodules caused compression at less than 80% of its surface (DeAngelo et al. 2008). Interim (60d) values: Adenoma: 0/7, 0/7, 0/7, 7/27 (26%); Carcinoma: 0/7, 0/7, 0/7, 1/27 (4%). Strengths and limitations: The chemical and animal husbandry conditions were not characterized and only a low to moderate number of males rats were tested. However, they were tested at three dose levels spanning a 50-fold range and the exposure duration was near life span for all but the high dose group. Survival and body weights were not clearly reported and only the liver was histologically evaluated.
Richmond et al. (1995) Animal: Rat F344 M 28 days Study duration: 104 weeks | | 0 | 1/23 (4%)
Richmond et al. (1995) Animal: Rat F344 M 28 days Study duration: 104 weeks | | 50 | 0/26
Richmond et al. (1995) Animal: Rat F344 M 28 days Study duration: 104 weeks | | 500 | 6/29 (21%)
Richmond et al. (1995) Animal: Rat F344 M 28 days Study duration: 104 weeks | | Liver – Carcinoma
Richmond et al. (1995) Animal: Rat F344 M 28 days Study duration: 104 weeks | | 0 | 0/23
Richmond et al. (1995) Animal: Rat F344 M 28 days Study duration: 104 weeks | | 50 | 0/26
Richmond et al. (1995) Animal: Rat F344 M 28 days Study duration: 104 weeks | | 500 | 3/29 (10%)
DeAngelo et al. (1991) Animal: Mouse (Study 1) B6C3F1 M 28 days Study duration: 60 weeks (high dose), 75 weeks (low and medium dose levels) | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 50 500 5,000++ mg/l in distilled water (pH 6.8–7.2) ad libitum × 75 weeks + 2,000 mg/l NaCl ++ Exposure duration was reduced to 60 weeks | Liver – Adenoma | | Survival: No difference. Body weight: The high dose group had significantly lower body weight than controls (17% lower, p < 0.001). Body weights of the medium and low doses did not differ from controls. Significantly increased preneoplastic lesions: Hyperplastic nodules were significantly increased at 5,000 mg/L. They are likely considered part of the continuum toward neoplasia as it was reported combined with adenomas and carcinomas as proliferative lesions and other publications by this author under similar studies reported that a similar lesion (large foci of cellular alteration) was only distinguishable from adenomas because the nodules caused compression at less than 80% of its surface (DeAngelo et al. 2008). Other comments: Only the high dose group was quantitatively reported (as a percentage-fractional incidence was back calculated from percent), the other groups were extrapolated from a graph. Nine animals from each group were scarified at 60 weeks, with the remainder sacrificed at 75 weeks. All high dose animals were sacrificed at 60 weeks. Strengths and limitations: Three dose levels, which spanned a 100-fold range were tested in only males for up to 75 weeks. Only a few select organs were necropsied.
DeAngelo et al. (1991) Animal: Mouse (Study 1) B6C3F1 M 28 days Study duration: 60 weeks (high dose), 75 weeks (low and medium dose levels) | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 50 500 5,000++ mg/l in distilled water (pH 6.8–7.2) ad libitum × 75 weeks + 2,000 mg/l NaCl ++ Exposure duration was reduced to 60 weeks | 0 | 0/28
DeAngelo et al. (1991) Animal: Mouse (Study 1) B6C3F1 M 28 days Study duration: 60 weeks (high dose), 75 weeks (low and medium dose levels) | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 50 500 5,000++ mg/l in distilled water (pH 6.8–7.2) ad libitum × 75 weeks + 2,000 mg/l NaCl ++ Exposure duration was reduced to 60 weeks | 50 | 2/29 (7%)
DeAngelo et al. (1991) Animal: Mouse (Study 1) B6C3F1 M 28 days Study duration: 60 weeks (high dose), 75 weeks (low and medium dose levels) | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 50 500 5,000++ mg/l in distilled water (pH 6.8–7.2) ad libitum × 75 weeks + 2,000 mg/l NaCl ++ Exposure duration was reduced to 60 weeks | 500 | 1/27 (4%)
DeAngelo et al. (1991) Animal: Mouse (Study 1) B6C3F1 M 28 days Study duration: 60 weeks (high dose), 75 weeks (low and medium dose levels) | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 50 500 5,000++ mg/l in distilled water (pH 6.8–7.2) ad libitum × 75 weeks + 2,000 mg/l NaCl ++ Exposure duration was reduced to 60 weeks | 5,000 | 24/30*** (80%)
DeAngelo et al. (1991) Animal: Mouse (Study 1) B6C3F1 M 28 days Study duration: 60 weeks (high dose), 75 weeks (low and medium dose levels) | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 50 500 5,000++ mg/l in distilled water (pH 6.8–7.2) ad libitum × 75 weeks + 2,000 mg/l NaCl ++ Exposure duration was reduced to 60 weeks | Liver – Carcinoma
DeAngelo et al. (1991) Animal: Mouse (Study 1) B6C3F1 M 28 days Study duration: 60 weeks (high dose), 75 weeks (low and medium dose levels) | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 50 500 5,000++ mg/l in distilled water (pH 6.8–7.2) ad libitum × 75 weeks + 2,000 mg/l NaCl ++ Exposure duration was reduced to 60 weeks | 0 | 2/28 (7%)
DeAngelo et al. (1991) Animal: Mouse (Study 1) B6C3F1 M 28 days Study duration: 60 weeks (high dose), 75 weeks (low and medium dose levels) | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 50 500 5,000++ mg/l in distilled water (pH 6.8–7.2) ad libitum × 75 weeks + 2,000 mg/l NaCl ++ Exposure duration was reduced to 60 weeks | 50 | 6/29 (21%)
DeAngelo et al. (1991) Animal: Mouse (Study 1) B6C3F1 M 28 days Study duration: 60 weeks (high dose), 75 weeks (low and medium dose levels) | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 50 500 5,000++ mg/l in distilled water (pH 6.8–7.2) ad libitum × 75 weeks + 2,000 mg/l NaCl ++ Exposure duration was reduced to 60 weeks | 500 | 2/27 (7%)
DeAngelo et al. (1991) Animal: Mouse (Study 1) B6C3F1 M 28 days Study duration: 60 weeks (high dose), 75 weeks (low and medium dose levels) | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 50 500 5,000++ mg/l in distilled water (pH 6.8–7.2) ad libitum × 75 weeks + 2,000 mg/l NaCl ++ Exposure duration was reduced to 60 weeks | 5,000 | 25/30*** (83%)
DeAngelo et al. (1991) Animal: Mouse (Study 1) B6C3F1 M 28 days Study duration: 60 weeks (high dose), 75 weeks (low and medium dose levels) | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 50 500 5,000++ mg/l in distilled water (pH 6.8–7.2) ad libitum × 75 weeks + 2,000 mg/l NaCl ++ Exposure duration was reduced to 60 weeks | Liver – Adenoma or carcinoma
DeAngelo et al. (1991) Animal: Mouse (Study 1) B6C3F1 M 28 days Study duration: 60 weeks (high dose), 75 weeks (low and medium dose levels) | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 50 500 5,000++ mg/l in distilled water (pH 6.8–7.2) ad libitum × 75 weeks + 2,000 mg/l NaCl ++ Exposure duration was reduced to 60 weeks | 0 | 2/28 (7%)
DeAngelo et al. (1991) Animal: Mouse (Study 1) B6C3F1 M 28 days Study duration: 60 weeks (high dose), 75 weeks (low and medium dose levels) | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 50 500 5,000++ mg/l in distilled water (pH 6.8–7.2) ad libitum × 75 weeks + 2,000 mg/l NaCl ++ Exposure duration was reduced to 60 weeks | 50 | 7/29 (24%)
DeAngelo et al. (1991) Animal: Mouse (Study 1) B6C3F1 M 28 days Study duration: 60 weeks (high dose), 75 weeks (low and medium dose levels) | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 50 500 5,000++ mg/l in distilled water (pH 6.8–7.2) ad libitum × 75 weeks + 2,000 mg/l NaCl ++ Exposure duration was reduced to 60 weeks | 500 | 3/27 (11%)
DeAngelo et al. (1991) Animal: Mouse (Study 1) B6C3F1 M 28 days Study duration: 60 weeks (high dose), 75 weeks (low and medium dose levels) | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 50 500 5,000++ mg/l in distilled water (pH 6.8–7.2) ad libitum × 75 weeks + 2,000 mg/l NaCl ++ Exposure duration was reduced to 60 weeks | 5,000 | 27/30*** (90%)
DeAngelo et al. (1991) Animal: Mouse (Study 2) B6C3F1 M 28 days Study duration: 60 weeks | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 3,500 mg/l in distilled water (pH 6.8–7.2) ad libitum × 60 weeks + 1,500 mg/l acetic acid | Liver – Adenoma | | Survival: No difference. Body weight: The high dose group had significantly lower body weight than controls (13% lower, p < 0.001). Body weights of the medium and low doses did not differ from controls. Significantly increased preneoplastic lesions: Hyperplastic nodules were significantly increased at 3,500 mg/L. They are likely considered part of the continuum toward neoplasia as it was reported combined with adenomas and carcinomas as proliferative lesions and other publications by this author under similar studies reported that a similar lesion (large foci of cellular alteration) was only distinguishable from adenomas because the nodules caused compression at less than 80% of its surface (DeAngelo et al. 2008). Other comments: Incidences were only reported as a percentage-fractional incidence was back calculated from percent. All animals were sacrificed at 60 weeks. Strengths and limitations: One dose level was tested in a small number of males for 60 weeks. Only a few select organs were necropsied.
DeAngelo et al. (1991) Animal: Mouse (Study 2) B6C3F1 M 28 days Study duration: 60 weeks | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 3,500 mg/l in distilled water (pH 6.8–7.2) ad libitum × 60 weeks + 1,500 mg/l acetic acid | 0 | 0/10
DeAngelo et al. (1991) Animal: Mouse (Study 2) B6C3F1 M 28 days Study duration: 60 weeks | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 3,500 mg/l in distilled water (pH 6.8–7.2) ad libitum × 60 weeks + 1,500 mg/l acetic acid | 3,500 | 12/12*** (100%)
DeAngelo et al. (1991) Animal: Mouse (Study 2) B6C3F1 M 28 days Study duration: 60 weeks | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 3,500 mg/l in distilled water (pH 6.8–7.2) ad libitum × 60 weeks + 1,500 mg/l acetic acid | Liver – Carcinoma
DeAngelo et al. (1991) Animal: Mouse (Study 2) B6C3F1 M 28 days Study duration: 60 weeks | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 3,500 mg/l in distilled water (pH 6.8–7.2) ad libitum × 60 weeks + 1,500 mg/l acetic acid | 0 | 0/10
DeAngelo et al. (1991) Animal: Mouse (Study 2) B6C3F1 M 28 days Study duration: 60 weeks | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 3,500 mg/l in distilled water (pH 6.8–7.2) ad libitum × 60 weeks + 1,500 mg/l acetic acid | 3,500 | 8/12*** (67%)
DeAngelo et al. (1991) Animal: Mouse (Study 2) B6C3F1 M 28 days Study duration: 60 weeks | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 3,500 mg/l in distilled water (pH 6.8–7.2) ad libitum × 60 weeks + 1,500 mg/l acetic acid | Liver – Adenoma or carcinoma
DeAngelo et al. (1991) Animal: Mouse (Study 2) B6C3F1 M 28 days Study duration: 60 weeks | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 3,500 mg/l in distilled water (pH 6.8–7.2) ad libitum × 60 weeks + 1,500 mg/l acetic acid | 0 | 0/10
DeAngelo et al. (1991) Animal: Mouse (Study 2) B6C3F1 M 28 days Study duration: 60 weeks | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 3,500 mg/l in distilled water (pH 6.8–7.2) ad libitum × 60 weeks + 1,500 mg/l acetic acid | 3,500 | 12/12*** (100%)
DeAngelo et al. (1999) Animal: Mouse B6C3F1 M 28–30 days (18–21 g bw) Study duration: 90–100 weeks | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 50+ 500 1,000 2,000 3,500 mg/L in drinking water (pH 6.9–7.1) ad libitum × 90 or 100 weeks + started 1 month after the other groups (10 mice from each group were sacrificed at 26, 52, and 78 weeks – data not reported here) | Liver – Adenoma | | Survival: Significant decrease in survival at the two highest doses and a significant trend (<0.05): 50/53–33/35, 24/25, 32/41, 14/25*, 8/16*. Body weight: The high dose group (3.5 g/l) had significantly lower body weight after 52 weeks and continued throughout the study, while the 2 g/l group was significantly lower after 100 weeks. Significantly increased preneoplastic lesions: Hyperplastic nodule multiplicity was significantly increased at all exposed levels 500 to 3,500 mg/L. They are likely considered part of the continuum toward neoplasia as it was reported combined with adenomas and carcinomas as proliferative lesions and other publications by this author under similar studies reported that a similar lesion (large foci of cellular alteration) was only distinguishable from adenomas because the nodules caused compression at less than 80% of its surface (DeAngelo et al. 2008). Other comments: Water consumption was lower in the high dose group. The percent incidence was reported and fractional incidence was extrapolated from that and the original number of animals per group, however these calculations did not exactly match the percent incidence. Strengths and limitations: Only male mice, initially confirmed pathogen free, were used with differing numbers per group (as low was 16 in the high dose group). Continual disease surveillance was not reported. Multiple dose levels ranging 100-fold, were tested for a near life-span duration. However, only 5 high dose group mice received histological evaluations of all major organs, with histological evaluations of only gross lesions in the other groups.
DeAngelo et al. (1999) Animal: Mouse B6C3F1 M 28–30 days (18–21 g bw) Study duration: 90–100 weeks | | 0 | 5/53 (10%)
DeAngelo et al. (1999) Animal: Mouse B6C3F1 M 28–30 days (18–21 g bw) Study duration: 90–100 weeks | | 500 | 5/25 (20%)
DeAngelo et al. (1999) Animal: Mouse B6C3F1 M 28–30 days (18–21 g bw) Study duration: 90–100 weeks | | 1,000 | 21/41* (51.4%)
DeAngelo et al. (1999) Animal: Mouse B6C3F1 M 28–30 days (18–21 g bw) Study duration: 90–100 weeks | | 2,000 | 11/25* (42.9%)
DeAngelo et al. (1999) Animal: Mouse B6C3F1 M 28–30 days (18–21 g bw) Study duration: 90–100 weeks | | 3,500 | 7/16* (45%)
DeAngelo et al. (1999) Animal: Mouse B6C3F1 M 28–30 days (18–21 g bw) Study duration: 90–100 weeks | | Liver – Carcinoma
DeAngelo et al. (1999) Animal: Mouse B6C3F1 M 28–30 days (18–21 g bw) Study duration: 90–100 weeks | | 0 | 14/53 (26%)
DeAngelo et al. (1999) Animal: Mouse B6C3F1 M 28–30 days (18–21 g bw) Study duration: 90–100 weeks | | 500 | 12/25 (48%)
DeAngelo et al. (1999) Animal: Mouse B6C3F1 M 28–30 days (18–21 g bw) Study duration: 90–100 weeks | | 1,000 | 29/41*** (71%)
DeAngelo et al. (1999) Animal: Mouse B6C3F1 M 28–30 days (18–21 g bw) Study duration: 90–100 weeks | | 2,000 | 24/25*** (95%)
DeAngelo et al. (1999) Animal: Mouse B6C3F1 M 28–30 days (18–21 g bw) Study duration: 90–100 weeks | | 3,500 | 16/16*** (100%)
DeAngelo et al. (1999) Animal: Mouse B6C3F1 M 28–30 days (18–21 g bw) Study duration: 90–100 weeks | | [Trend p value: <0.001]
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 4 weeks Study duration: 61 weeks | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 5,000 mg/l in drinking water (pH 6.5–7.5) ad libitum × 61 weeks + 2,000 mg/l of NaCl | Liver – Adenoma | | Survival: Not reported. Body weight: Body weights were significantly decreased. (p < 0.001). Calculations were done by one-way analysis of variance with a Tukey's comparison. Significantly increased preneoplastic lesions: Not reported. Strengths and limitations: The durations were less than near life-span. Only males were tested at a single dose level and only livers were histologically evaluated.
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 4 weeks Study duration: 61 weeks | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 5,000 mg/l in drinking water (pH 6.5–7.5) ad libitum × 61 weeks + 2,000 mg/l of NaCl | 0 | 2/22 (9%)
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 4 weeks Study duration: 61 weeks | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 5,000 mg/l in drinking water (pH 6.5–7.5) ad libitum × 61 weeks + 2,000 mg/l of NaCl | 5,000 | 25/26** (96%)
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 4 weeks Study duration: 61 weeks | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 5,000 mg/l in drinking water (pH 6.5–7.5) ad libitum × 61 weeks + 2,000 mg/l of NaCl | Liver – Carcinoma
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 4 weeks Study duration: 61 weeks | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 5,000 mg/l in drinking water (pH 6.5–7.5) ad libitum × 61 weeks + 2,000 mg/l of NaCl | 0 | 0/22
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 4 weeks Study duration: 61 weeks | Agent: Dichloroacetic acid >99% Treatment: Drinking water 0+ 5,000 mg/l in drinking water (pH 6.5–7.5) ad libitum × 61 weeks + 2,000 mg/l of NaCl | 5,000 | 21/26** (81%)
Wood et al. (2015) Animal: Mouse B6C3F1 M 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 3,500 mg/L deionized water (pH 6.8–7.1) ad libitum × 10 weeks | Liver – Adenoma | | Survival: Survival was similar in all groups. Body weight: Body weight of the high dose group, after DCA exposure had stopped, was decreased by 12% compared to controls. Other comments: The original number of mice used were reported as those given a specific dose of DCA and were not differentiated by those given phenobarbital and those that were not. The incidence denominator was differentiated by co-administration of phenobarbital and only represents those animals given only dichloroacetic acid. Water consumption was decreased at the medium and high dose groups, which limited the daily intake to (target dose mg/kg/d: 0–168, 315, 429; Measured dose mg/kg/d: 0–136, 232, 297), so the high dose was not nearly as high as expected. Strengths and limitations: Chemical stability was reported and target concentrations were verified, but purity was not reported. Disease surveillance was not reported. Three dose levels, previously shown to be carcinogenic were used. The exposure duration was short, but the observation duration was near life-span. Only livers were examined during necropsy.
Wood et al. (2015) Animal: Mouse B6C3F1 M 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 3,500 mg/L deionized water (pH 6.8–7.1) ad libitum × 10 weeks | 0 | 5/27 (19%)
Wood et al. (2015) Animal: Mouse B6C3F1 M 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 3,500 mg/L deionized water (pH 6.8–7.1) ad libitum × 10 weeks | 1,000 | 13/27 (48%)
Wood et al. (2015) Animal: Mouse B6C3F1 M 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 3,500 mg/L deionized water (pH 6.8–7.1) ad libitum × 10 weeks | 2,000 | 11/27 (41%)
Wood et al. (2015) Animal: Mouse B6C3F1 M 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 3,500 mg/L deionized water (pH 6.8–7.1) ad libitum × 10 weeks | 3,500 | 15/26* (58%)
Wood et al. (2015) Animal: Mouse B6C3F1 M 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 3,500 mg/L deionized water (pH 6.8–7.1) ad libitum × 10 weeks | Trend p value: <0.05
Wood et al. (2015) Animal: Mouse B6C3F1 M 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 3,500 mg/L deionized water (pH 6.8–7.1) ad libitum × 10 weeks | Liver – Carcinoma
Wood et al. (2015) Animal: Mouse B6C3F1 M 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 3,500 mg/L deionized water (pH 6.8–7.1) ad libitum × 10 weeks | 0 | 8/27 (30%)
Wood et al. (2015) Animal: Mouse B6C3F1 M 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 3,500 mg/L deionized water (pH 6.8–7.1) ad libitum × 10 weeks | 1,000 | 8/27 (30%)
Wood et al. (2015) Animal: Mouse B6C3F1 M 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 3,500 mg/L deionized water (pH 6.8–7.1) ad libitum × 10 weeks | 2,000 | 6/27 (22%)
Wood et al. (2015) Animal: Mouse B6C3F1 M 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 3,500 mg/L deionized water (pH 6.8–7.1) ad libitum × 10 weeks | 3,500 | 19/26* (73%)
Wood et al. (2015) Animal: Mouse B6C3F1 M 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 3,500 mg/L deionized water (pH 6.8–7.1) ad libitum × 10 weeks | Trend p value: <0.01
Wood et al. (2015) Animal: Mouse B6C3F1 M 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 3,500 mg/L deionized water (pH 6.8–7.1) ad libitum × 10 weeks | Liver – Hepatoblastoma
Wood et al. (2015) Animal: Mouse B6C3F1 M 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 3,500 mg/L deionized water (pH 6.8–7.1) ad libitum × 10 weeks | 0 | 0/27
Wood et al. (2015) Animal: Mouse B6C3F1 M 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 3,500 mg/L deionized water (pH 6.8–7.1) ad libitum × 10 weeks | 1,000 | 1/27 (4%)
Wood et al. (2015) Animal: Mouse B6C3F1 M 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 3,500 mg/L deionized water (pH 6.8–7.1) ad libitum × 10 weeks | 2,000 | 0/27
Wood et al. (2015) Animal: Mouse B6C3F1 M 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 3,500 mg/L deionized water (pH 6.8–7.1) ad libitum × 10 weeks | 3,500 | 0/26
Wood et al. (2015) Animal: Mouse B6C3F1 M 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 3,500 mg/L deionized water (pH 6.8–7.1) ad libitum × 10 weeks | Liver – Adenoma, carcinoma, and hepatoblastoma
Wood et al. (2015) Animal: Mouse B6C3F1 M 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 3,500 mg/L deionized water (pH 6.8–7.1) ad libitum × 10 weeks | 0 | 12/27 (44%)
Wood et al. (2015) Animal: Mouse B6C3F1 M 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 3,500 mg/L deionized water (pH 6.8–7.1) ad libitum × 10 weeks | 1,000 | 15/27 (56%)
Wood et al. (2015) Animal: Mouse B6C3F1 M 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 3,500 mg/L deionized water (pH 6.8–7.1) ad libitum × 10 weeks | 2,000 | 14/27 (52%)
Wood et al. (2015) Animal: Mouse B6C3F1 M 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 3,500 mg/L deionized water (pH 6.8–7.1) ad libitum × 10 weeks | 3,500 | 24/26** (92%)
Wood et al. (2015) Animal: Mouse B6C3F1 M 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 3,500 mg/L deionized water (pH 6.8–7.1) ad libitum × 10 weeks | Trend p value: <0.01
Wood et al. (2015) Animal: Mouse B6C3F1 F 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 mg/L in deionized water (pH 6.8–7.1) ad libitum × 10 weeks | Liver – Adenoma | | Survival: Survival was similar in all groups. Body weight: Body weight of the high dose group, after DCA exposure had stopped, was decreased by 12% compared to controls. Other comments: The original number of mice used were reported as those given a specific dose of DCA and were not differentiated by those given phenobarbital and those that were not. The incidence denominator was differentiated by co-administration of phenobarbital and only represents those animals given only dichloroacetic acid. Water consumption was decreased at the medium and high dose groups, which limited the daily intake to (target dose mg/kg/d: 0–168, 315, 429; Measured dose mg/kg/d: 0–136, 232, 297), so the high dose was not nearly as high as expected. Strengths and limitations: Chemical stability was reported and target concentrations were verified, but purity was not reported. Disease surveillance was not reported. Two dose levels, previously shown to be carcinogenic, were used. The exposure duration was short, but the observation duration was near life-span. Only livers were examined during necropsy.
Wood et al. (2015) Animal: Mouse B6C3F1 F 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 mg/L in deionized water (pH 6.8–7.1) ad libitum × 10 weeks | 0 | 0/27
Wood et al. (2015) Animal: Mouse B6C3F1 F 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 mg/L in deionized water (pH 6.8–7.1) ad libitum × 10 weeks | 1,000 | 9/26** (35%)
Wood et al. (2015) Animal: Mouse B6C3F1 F 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 mg/L in deionized water (pH 6.8–7.1) ad libitum × 10 weeks | 2,000 | 6/28 (21%)
Wood et al. (2015) Animal: Mouse B6C3F1 F 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 mg/L in deionized water (pH 6.8–7.1) ad libitum × 10 weeks | Liver – Carcinoma
Wood et al. (2015) Animal: Mouse B6C3F1 F 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 mg/L in deionized water (pH 6.8–7.1) ad libitum × 10 weeks | 0 | 0/27
Wood et al. (2015) Animal: Mouse B6C3F1 F 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 mg/L in deionized water (pH 6.8–7.1) ad libitum × 10 weeks | 1,000 | 2/26 (8%)
Wood et al. (2015) Animal: Mouse B6C3F1 F 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 mg/L in deionized water (pH 6.8–7.1) ad libitum × 10 weeks | 2,000 | 3/28 (11%)
Wood et al. (2015) Animal: Mouse B6C3F1 F 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 mg/L in deionized water (pH 6.8–7.1) ad libitum × 10 weeks | Liver – Hepatoblastoma
Wood et al. (2015) Animal: Mouse B6C3F1 F 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 mg/L in deionized water (pH 6.8–7.1) ad libitum × 10 weeks | 0 | 0/27
Wood et al. (2015) Animal: Mouse B6C3F1 F 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 mg/L in deionized water (pH 6.8–7.1) ad libitum × 10 weeks | 1,000 | 0/26
Wood et al. (2015) Animal: Mouse B6C3F1 F 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 mg/L in deionized water (pH 6.8–7.1) ad libitum × 10 weeks | 2,000 | 0/28
Wood et al. (2015) Animal: Mouse B6C3F1 F 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 mg/L in deionized water (pH 6.8–7.1) ad libitum × 10 weeks | Liver – Adenoma, carcinoma, and hepatoblastoma
Wood et al. (2015) Animal: Mouse B6C3F1 F 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 mg/L in deionized water (pH 6.8–7.1) ad libitum × 10 weeks | 0 | 0/27
Wood et al. (2015) Animal: Mouse B6C3F1 F 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 mg/L in deionized water (pH 6.8–7.1) ad libitum × 10 weeks | 1,000 | 10/26** (38%)
Wood et al. (2015) Animal: Mouse B6C3F1 F 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 mg/L in deionized water (pH 6.8–7.1) ad libitum × 10 weeks | 2,000 | 9/28** (32%)
Wood et al. (2015) Animal: Mouse B6C3F1 F 28 days Study duration: 94 weeks | Agent: Dichloroacetic acid Not reported Treatment: Drinking water 0 1,000 2,000 mg/L in deionized water (pH 6.8–7.1) ad libitum × 10 weeks | [Trend p value: <0.01]
Pereira (1996) Animal: Mouse (Study 1) B6C3F1 F 7–8 weeks Study duration: 576 days | Agent: Dichloroacetic acid (DCA) Not reported Treatment: Drinking water 0+ 260++ 860++ 2,600+++ 2,600++ mg/L in drinking water ad libitum × 360 days + 20 mmol/L NaCl ++ Concentrations were reported at mmol/L and NTP converted them to mg/L based on a mw of 28.942g/mol +++ intermittent cycles of 24 days on, 48 days off | Liver – Adenoma | | Survival: Not reported Body weight: The high dose level of DCA was caused significant weight loss after 35 weeks and beyond, while the high dose of TCA caused it at 51 weeks, with near significant decreases beyond. Significantly increased preneoplastic lesions: The foci of altered hepatocytes were reported combined with neoplasms, but not separately. They are likely considered part of the continuum toward neoplasia as it was reported combined with adenomas and carcinomas as proliferative lesions and other publications by this author under similar studies reported that a similar lesion (large foci of cellular alteration) was only distinguishable from adenomas because the nodules caused compression at less than 80% of its surface (DeAngelo et al. 2008). Strengths and limitations: The chemicals were not characterized, not even purity was reported. Disease surveillance was not continually monitored. A variable number of only females was tested, with only their livers examined histologically. The study duration was near life-span.
Pereira (1996) Animal: Mouse (Study 1) B6C3F1 F 7–8 weeks Study duration: 576 days | | 0 | 2/90 (2.2%)
Pereira (1996) Animal: Mouse (Study 1) B6C3F1 F 7–8 weeks Study duration: 576 days | | 260 | 3/50 (6%)
Pereira (1996) Animal: Mouse (Study 1) B6C3F1 F 7–8 weeks Study duration: 576 days | | 860 | 7/28* (25%)
Pereira (1996) Animal: Mouse (Study 1) B6C3F1 F 7–8 weeks Study duration: 576 days | | 2,600 intermittent | 3/34 (8.8%)
Pereira (1996) Animal: Mouse (Study 1) B6C3F1 F 7–8 weeks Study duration: 576 days | | 2,600 | 16/19* (84.2%)
Pereira (1996) Animal: Mouse (Study 1) B6C3F1 F 7–8 weeks Study duration: 576 days | | Liver – Carcinoma
Pereira (1996) Animal: Mouse (Study 1) B6C3F1 F 7–8 weeks Study duration: 576 days | | 0 | 2/90 (2.2%)
Pereira (1996) Animal: Mouse (Study 1) B6C3F1 F 7–8 weeks Study duration: 576 days | | 260 | 0/50
Pereira (1996) Animal: Mouse (Study 1) B6C3F1 F 7–8 weeks Study duration: 576 days | | 860 | 1/28 (3.6%)
Pereira (1996) Animal: Mouse (Study 1) B6C3F1 F 7–8 weeks Study duration: 576 days | | 2,600 intermittent | 1/34 (2.9%)
Pereira (1996) Animal: Mouse (Study 1) B6C3F1 F 7–8 weeks Study duration: 576 days | | 2,600 | 5/19[**] (26.3%)
Pereira (1996) Animal: Mouse (Study 1) B6C3F1 F 7–8 weeks Study duration: 576 days | | [Trend p value: <0.001]
Pereira (1996) Animal: Mouse (Study 2) B6C3F1 F 7–8 weeks Study duration: 360 days | Agent: Dichloroacetic acid (DCA) Not reported Treatment: Drinking water 0+ 260++ 860++ 2,600+++ 2,600++ mg/L in drinking water ad libitum × 360 days + 20 mmol/L NaCl ++ Concentrations were reported at mmol/L and NTP converted them to mg/L based on a mw of 28.942g/mol +++ intermittent cycles of 24 days on, 48 days off | Liver – Adenoma | | Survival: Not reported Body weight: The high dose level of DCA was caused significant weight loss after 35 weeks and beyond, while the high dose of TCA caused it at 51 weeks, with near significant decreases beyond. Significantly increased preneoplastic lesions: The foci of altered hepatocytes were reported combined with neoplasms, but not separately. They are likely considered part of the continuum toward neoplasia as it was reported combined with adenomas and carcinomas as proliferative lesions and other publications by this author under similar studies reported that a similar lesion (large foci of cellular alteration) was only distinguishable from adenomas because the nodules caused compression at less than 80% of its surface (DeAngelo et al. 2008). Strengths and limitations: The chemicals were not characterized, not even purity was reported. Disease surveillance was not continually monitored. A variable number of only females was tested, with only their livers examined histologically. Study duration was less than life-span.
Pereira (1996) Animal: Mouse (Study 2) B6C3F1 F 7–8 weeks Study duration: 360 days | | 0 | 1/40 (2.5%)
Pereira (1996) Animal: Mouse (Study 2) B6C3F1 F 7–8 weeks Study duration: 360 days | | 260 | 0/40
Pereira (1996) Animal: Mouse (Study 2) B6C3F1 F 7–8 weeks Study duration: 360 days | | 860 | 3/20 (15%)
Pereira (1996) Animal: Mouse (Study 2) B6C3F1 F 7–8 weeks Study duration: 360 days | | 2,600 intermittent | 0/15
Pereira (1996) Animal: Mouse (Study 2) B6C3F1 F 7–8 weeks Study duration: 360 days | | 2,600 | 7/20* (35%)
Pereira (1996) Animal: Mouse (Study 2) B6C3F1 F 7–8 weeks Study duration: 360 days | | Liver – Carcinoma
Pereira (1996) Animal: Mouse (Study 2) B6C3F1 F 7–8 weeks Study duration: 360 days | | 0 | 0/40
Pereira (1996) Animal: Mouse (Study 2) B6C3F1 F 7–8 weeks Study duration: 360 days | | 260 | 0/40
Pereira (1996) Animal: Mouse (Study 2) B6C3F1 F 7–8 weeks Study duration: 360 days | | 860 | 0/20
Pereira (1996) Animal: Mouse (Study 2) B6C3F1 F 7–8 weeks Study duration: 360 days | | 2,600 intermittent | 0/15
Pereira (1996) Animal: Mouse (Study 2) B6C3F1 F 7–8 weeks Study duration: 360 days | | 2,600 | 1/20 (5%)
Bull et al. (1990) Animal: Mouse B6C3F1 M 5 weeks Study duration: 52 weeks | Agent: Dichloroacetic acid Analytical grade Treatment: Drinking water 0 1,000 2,000 mg/L in drinking water (pH 6.8–7.2) ad libitum × 52 weeks | Liver – Adenoma | | Survival: All mice survived. Significantly increased preneoplastic lesions: A non-significant increase in hyperplasia was reported. Strengths and limitations: The chemical was not characterized, disease surveillance was not reported. A low number of mice per group were exposed for a less than near life-span duration and only males had results reported. Only livers were histologically examined. Not all lesions were histologically evaluated, but instead samples of lesions were evaluated. Results were reported so that incidences of specific neoplasms could not be determined but could be estimated.
Bull et al. (1990) Animal: Mouse B6C3F1 M 5 weeks Study duration: 52 weeks | Agent: Dichloroacetic acid Analytical grade Treatment: Drinking water 0 1,000 2,000 mg/L in drinking water (pH 6.8–7.2) ad libitum × 52 weeks | 0 | 0/2
Bull et al. (1990) Animal: Mouse B6C3F1 M 5 weeks Study duration: 52 weeks | Agent: Dichloroacetic acid Analytical grade Treatment: Drinking water 0 1,000 2,000 mg/L in drinking water (pH 6.8–7.2) ad libitum × 52 weeks | 1,000 | 0/1
Bull et al. (1990) Animal: Mouse B6C3F1 M 5 weeks Study duration: 52 weeks | Agent: Dichloroacetic acid Analytical grade Treatment: Drinking water 0 1,000 2,000 mg/L in drinking water (pH 6.8–7.2) ad libitum × 52 weeks | 2,000 | 2/10 (20%)
Bull et al. (1990) Animal: Mouse B6C3F1 M 5 weeks Study duration: 52 weeks | Agent: Dichloroacetic acid Analytical grade Treatment: Drinking water 0 1,000 2,000 mg/L in drinking water (pH 6.8–7.2) ad libitum × 52 weeks | Liver – Carcinoma
Bull et al. (1990) Animal: Mouse B6C3F1 M 5 weeks Study duration: 52 weeks | Agent: Dichloroacetic acid Analytical grade Treatment: Drinking water 0 1,000 2,000 mg/L in drinking water (pH 6.8–7.2) ad libitum × 52 weeks | 0 | 0/2
Bull et al. (1990) Animal: Mouse B6C3F1 M 5 weeks Study duration: 52 weeks | Agent: Dichloroacetic acid Analytical grade Treatment: Drinking water 0 1,000 2,000 mg/L in drinking water (pH 6.8–7.2) ad libitum × 52 weeks | 1,000 | 0/1
Bull et al. (1990) Animal: Mouse B6C3F1 M 5 weeks Study duration: 52 weeks | Agent: Dichloroacetic acid Analytical grade Treatment: Drinking water 0 1,000 2,000 mg/L in drinking water (pH 6.8–7.2) ad libitum × 52 weeks | 2,000 | 5/10 (50%)
Daniel et al. (1992) Animal: Mouse B6C3F1 M 28 days Study duration: 104 weeks | Agent: Dichloroacetic acid >95% Treatment: Drinking water 0 0 500 500 mg/l in distilled water (pH 6.8–7.2) ad libitum × 104 weeks Two sets of animals were used as they were born, both groups are the same, just started at different times. Except for the body weights, the two groups were statistically analyzed as one combined group. | Liver – Adenoma | | Survival: Survival was not significantly different: 13/10, 10/10–16/18, 8/10 Body weight: No significant differences in body weight. Significantly increased preneoplastic lesions: Hyperplastic nodules were not significantly increased. They are likely considered part of the continuum toward neoplasia as it was reported combined with adenomas and carcinomas as proliferative lesions and other publications by this author under similar studies reported that a similar lesion (large foci of cellular alteration) was only distinguishable from adenomas because the nodules caused compression at less than 80% of its surface (DeAngelo et al. 2008). Other comments: All tumors occurred at necropsy and did not cause premature mortality. Both groups of controls and exposed mice were combined into one group each. Fractional incidence was based on surviving animals as the denominator and percent incidence was also reported. Strengths and limitations: Continual disease surveillance was not reported. Only males were tested and only at one dose level. Histological evaluations from all major organs only occurred in five mice per group, with histological evaluations in the other mice only occurring on tissues with gross lesions.
Daniel et al. (1992) Animal: Mouse B6C3F1 M 28 days Study duration: 104 weeks | | 0 | 1/20 (5%)
Daniel et al. (1992) Animal: Mouse B6C3F1 M 28 days Study duration: 104 weeks | | 500 | 10/24** (42%)
Daniel et al. (1992) Animal: Mouse B6C3F1 M 28 days Study duration: 104 weeks | | Liver – Carcinoma
Daniel et al. (1992) Animal: Mouse B6C3F1 M 28 days Study duration: 104 weeks | | 0 | 2/20 (10%)
Daniel et al. (1992) Animal: Mouse B6C3F1 M 28 days Study duration: 104 weeks | | 500 | 15/24** (63%)
Daniel et al. (1992) Animal: Mouse B6C3F1 M 28 days Study duration: 104 weeks | | Liver – Adenoma or carcinoma
Daniel et al. (1992) Animal: Mouse B6C3F1 M 28 days Study duration: 104 weeks | | 0 | 3/20 (15%)
Daniel et al. (1992) Animal: Mouse B6C3F1 M 28 days Study duration: 104 weeks | | 500 | 18/24** (75%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | Liver – Adenoma^a^ | | Survival: Survival was similar in all groups. 31/50–38/50, 34/50, 31/50 Body weight: Body weights were greater in the 50 and 500 mg/l groups compared to the untreated controls after 85 weeks. Significantly increased preneoplastic lesions: Spleen hematopoiesis 18/49–20/50, 28/50, 38/50 Other comments: Water consumption was similar to controls. Onset was reported in days. Strengths and limitations: Large numbers of animals per group were used in both sexes and were continuously monitored for disease. Three dose levels spanning a range of 200-fold were used. Lesions and all major organs were histologically evaluated and statistics were clearly reported.
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 0 | 18/49 (42%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 50 | 37/50***^b^ (78%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 500 | 37/50***^b^ (80%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 1,000 | 42/50***^b^ (89%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | Trend p value: <0.001
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | Liver – Carcinoma^a^
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 0 | 14/49 (31%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 50 | 9/50 (19%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 500 | 19/50 (41%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 1,000 | 26/50*^c^ (55%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | Trend p value: <0.001
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | Liver – Adenoma or carcinoma^a^
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 0 | 28/49 (61%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 50 | 41/50**^d^ (86%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 500 | 42/50***^d^ (88%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 1,000 | 47/50***^d^ (96%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | Trend p value: <0.001
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | Liver – Hepatoblastoma^a^
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 0 | 0/49
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 50 | 4/50 (9%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 500 | 6/50* (13%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 1,000 | 18/50***^e^ (39%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | Trend p value: <0.001
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | Liver – Adenoma, carcinoma or hepatoblastoma^a^
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 0 | 28/49 (61%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 50 | 41/50** (86%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 500 | 43/50*** (90%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 1,000 | 48/50*** (97%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | Trend p value: <0.001
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0 – 4, 35, 65 mg/kg | Liver – Adenoma^a^ | | Survival: Survival was similar in all groups. 38/50 – 35/50, 32/50, 32/50 Body weight: Body weights were similar to the untreated controls. Other comments: Water consumption was similar to controls. Onset was reported in days. Strengths and limitations: Large numbers of animals per group were used in both sexes and were continuously monitored for disease. Three dose levels spanning a range of 200-fold were used. Lesions and all major organs were histologically evaluated and statistics were clearly reported.
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0 – 4, 35, 65 mg/kg | 0 | 19/49 (41%)
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0 – 4, 35, 65 mg/kg | 50 | 26/50 (57%)
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0 – 4, 35, 65 mg/kg | 500 | 32/50**^f^ (70%)
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0 – 4, 35, 65 mg/kg | 1,000 | 35/49***^f^ (76%)
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0 – 4, 35, 65 mg/kg | Trend p value: <0.001
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0 – 4, 35, 65 mg/kg | Liver – Carcinoma^a^
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0 – 4, 35, 65 mg/kg | 0 | 3/49 (7%)
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0 – 4, 35, 65 mg/kg | 50 | 3/50 (7%)
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0 – 4, 35, 65 mg/kg | 500 | 12/50**^g^ (27%)
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0 – 4, 35, 65 mg/kg | 1,000 | 8/49 (18%)
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0 – 4, 35, 65 mg/kg | Trend p value: =0.019
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0 – 4, 35, 65 mg/kg | Liver – Adenoma or carcinoma^a^
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0 – 4, 35, 65 mg/kg | 0 | 22/49 (48%)
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0 – 4, 35, 65 mg/kg | 50 | 28/50 (61%)
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0 – 4, 35, 65 mg/kg | 500 | 37/50***^h^ (80%)
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0 – 4, 35, 65 mg/kg | 1,000 | 37/49***^h^ (80%)
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0 – 4, 35, 65 mg/kg | Trend p value: <0.001
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0 – 4, 35, 65 mg/kg | Liver – Hepatoblastoma
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0 – 4, 35, 65 mg/kg | 0 | 1/49 (2%)
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0 – 4, 35, 65 mg/kg | 50 | 0/50
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0 – 4, 35, 65 mg/kg | 500 | 1/50 (2%)
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water ad libitum × 106 weeks Average daily dose: 0 – 4, 35, 65 mg/kg | 1,000 | 0/49
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Liver – Adenoma^a^ | | Survival: No significant difference: 31/50–26/50, 25/50, 29/50 Body weight: 1,000 mg/l group was 10% less than controls after 69 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 2/50^i^ (4.6%)
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 0/50
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 3/50^i^ (7.5%)
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 4/50^i^ (9.5%)
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Liver – Adenoma^a^ | | Survival: No significant difference: 34/50–31/50, 37/50, 35/50 Body weight: 1,000 mg/l group was <10% of controls. after 85 weeks. Significantly increased preneoplastic lesions: Lung alveolar epithelium hyperplasia occurred at increased incidences. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 0/50
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 0/50
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 0/50
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 3/50^j^ (6.6%)
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Trend p value: =0.012
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Liver – Adenoma^a^ | | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 27/50 (58.7%) | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 40/50**^k^ (83.6%) | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 40/50**^k^ (83.7%) | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 31/50 (67.4%) | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Liver – Carcinoma^a^ | | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 19/50 (39.6%) | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 25/50^l^ (52.5%) | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 36/50***^l^ (76.9%) | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 45/50***^l^ (92.7%) | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Trend p value: <0.001 | | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Liver – Adenoma or carcinoma^a^ | | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 34/50 (70.6%) | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 44/50*^m^ (89.7%) | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 49/50***^m^ (99.9%) | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 49/50***^m^ (98.6%) | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Trend p value: <0.001 | | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Liver – Hepatoblastoma^a^ | | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 4/50 (8.8%) | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 11/50* (23.8%) | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 28/50***^n^ (61.3%) | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 34/50***^n^ (73.7%) | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Trend p value: <0.001 | | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Liver – Adenoma, carcinoma, or hepatoblastoma^a^ | | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 21/50 (43.8%) | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 32/50* (66.3%) | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 43/50*** (90.7%) | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 49/50*** (98%) | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Trend p value: <0.001 | | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Liver – Adenoma^a^ | | Survival: 36/50–42/50, 32/50, 40/50 Body weight: No significant difference. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 27/50 (59.4%) | Survival: 36/50–42/50, 32/50, 40/50 Body weight: No significant difference. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 48/50***^o^ (96%) | Survival: 36/50–42/50, 32/50, 40/50 Body weight: No significant difference. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 44/50***^o^ (90.9%) | Survival: 36/50–42/50, 32/50, 40/50 Body weight: No significant difference. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 46/50***^o^ (95.2%) | Survival: 36/50–42/50, 32/50, 40/50 Body weight: No significant difference. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Trend p value: <0.001 | | Survival: 36/50–42/50, 32/50, 40/50 Body weight: No significant difference. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Liver – Carcinoma^a^ | | Survival: 36/50–42/50, 32/50, 40/50 Body weight: No significant difference. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 14/50^p^ (31.1%) | Survival: 36/50–42/50, 32/50, 40/50 Body weight: No significant difference. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 23/50^p^ (48.3%) | Survival: 36/50–42/50, 32/50, 40/50 Body weight: No significant difference. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 26/50*^p^ (56.1%) | Survival: 36/50–42/50, 32/50, 40/50 Body weight: No significant difference. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 20/50^p^ (42.3%) | Survival: 36/50–42/50, 32/50, 40/50 Body weight: No significant difference. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Liver – Adenoma or carcinoma^a^ | | Survival: 36/50–42/50, 32/50, 40/50 Body weight: No significant difference. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 31/50^q^ (67.6%) | Survival: 36/50–42/50, 32/50, 40/50 Body weight: No significant difference. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 49/50***^q^ (98%) | Survival: 36/50–42/50, 32/50, 40/50 Body weight: No significant difference. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 46/50***^q^ (94.6%) | Survival: 36/50–42/50, 32/50, 40/50 Body weight: No significant difference. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 46/50***^q^ (95.2%) | Survival: 36/50–42/50, 32/50, 40/50 Body weight: No significant difference. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Trend p value: <0.001 | | Survival: 36/50–42/50, 32/50, 40/50 Body weight: No significant difference. Strengths and limitations: A very high-quality study, with no major concerns.
DeAngelo et al. (1997) Animal: Rat F344/N M 28–30 days Study duration: 104 weeks | Agent: Trichloroacetic acid >99% Treatment: Drinking water 0+ 2,500++ mg/L in drinking water (pH 6.9–7.1) ad libitum × 104 weeks + 31–32 mM NaCl (~isomolar to 5,000 mg/l of TCA) ++ 1,500 mg/L × 8 weeks then 1,000 mg/L after 24 weeks, because of significant differences in body weight gain | Liver – Adenoma | | Survival: No significant difference in survival: 23/29–24/32, 19/32, 22/29 Body weight: Body weights were similar among the 0.05 and 0.5 g/l groups but decreased more than 10% compared to controls in the 5 g/l group. Significantly increased preneoplastic lesions: Hyperplastic nodules were reported but were not significantly increased. They are likely considered part of the continuum toward neoplasia as it was reported combined with adenomas and carcinomas as proliferative lesions and other publications by this author under similar studies reported that a similar lesion (large foci of cellular alteration) was only distinguishable from adenomas because the nodules caused compression at less than 80% of its surface (DeAngelo et al. 2008). Other comments: Amount of water consumed was similar among groups (76.9 ml/kg/d–71.2, ml/kg/d, 70.6 ml/kg/d, 74,2 ml/kg/d). Strengths and limitations: A well conducted study on almost all aspects but only involved male rats.
DeAngelo et al. (1997) Animal: Rat F344/N M 28–30 days Study duration: 104 weeks | | 0 | 1/23 (4%)
DeAngelo et al. (1997) Animal: Rat F344/N M 28–30 days Study duration: 104 weeks | | 50 | 1/24 (4%)
DeAngelo et al. (1997) Animal: Rat F344/N M 28–30 days Study duration: 104 weeks | | 500 | 3/20 (15%)
DeAngelo et al. (1997) Animal: Rat F344/N M 28–30 days Study duration: 104 weeks | | 5,000 | 1/22 (5%)
DeAngelo et al. (1997) Animal: Rat F344/N M 28–30 days Study duration: 104 weeks | | Liver – Carcinoma
DeAngelo et al. (1997) Animal: Rat F344/N M 28–30 days Study duration: 104 weeks | | 0 | 0/23
DeAngelo et al. (1997) Animal: Rat F344/N M 28–30 days Study duration: 104 weeks | | 50 | 0/24
DeAngelo et al. (1997) Animal: Rat F344/N M 28–30 days Study duration: 104 weeks | | 500 | 0/20
DeAngelo et al. (1997) Animal: Rat F344/N M 28–30 days Study duration: 104 weeks | | 5,000 | 1/22 (5%)
DeAngelo et al. (1997) Animal: Rat F344/N M 28–30 days Study duration: 104 weeks | | Liver – Adenoma or carcinoma
DeAngelo et al. (1997) Animal: Rat F344/N M 28–30 days Study duration: 104 weeks | | 0 | 1/23 (4%)
DeAngelo et al. (1997) Animal: Rat F344/N M 28–30 days Study duration: 104 weeks | | 50 | 1/24 (4%)
DeAngelo et al. (1997) Animal: Rat F344/N M 28–30 days Study duration: 104 weeks | | 500 | 3/20 (15%)
DeAngelo et al. (1997) Animal: Rat F344/N M 28–30 days Study duration: 104 weeks | | 5,000 | 1/22 (5%)
DeAngelo et al. (2008) Animal: Mouse (Study 1) B6C3F1 M 28–30 days Study duration: 60 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0+ 50 500 5,000 mg/L in drinking water ad libitum × 60 weeks + 2,000 mg/L NaCl | Liver – Adenoma | | Survival: No difference in survival: 30/30–27/30, 29/30, 29/30 Body weight: Not reported. Significantly increased preneoplastic lesions: Large foci of cellular alteration were significantly increased at 5,000 mg/L (p < 0.05). Large foci of cellular alteration were considered preneoplastic. Other comments: Denominators of incidences are based on surviving mice. Water consumption decreased in 0.5 and 5.0 g/l groups. Strengths and limitations: Three dose levels were used that spanned a 100-fold range. Most organs were histologically evaluated and evaluations were confirmed by an independent pathologist.
DeAngelo et al. (2008) Animal: Mouse (Study 1) B6C3F1 M 28–30 days Study duration: 60 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0+ 50 500 5,000 mg/L in drinking water ad libitum × 60 weeks + 2,000 mg/L NaCl | 0 | 2/30 (7%)
DeAngelo et al. (2008) Animal: Mouse (Study 1) B6C3F1 M 28–30 days Study duration: 60 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0+ 50 500 5,000 mg/L in drinking water ad libitum × 60 weeks + 2,000 mg/L NaCl | 50 | 4/27 (15%)
DeAngelo et al. (2008) Animal: Mouse (Study 1) B6C3F1 M 28–30 days Study duration: 60 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0+ 50 500 5,000 mg/L in drinking water ad libitum × 60 weeks + 2,000 mg/L NaCl | 500 | 6/29 (21%)
DeAngelo et al. (2008) Animal: Mouse (Study 1) B6C3F1 M 28–30 days Study duration: 60 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0+ 50 500 5,000 mg/L in drinking water ad libitum × 60 weeks + 2,000 mg/L NaCl | 5,000 | 11/29^r^ (38%)
DeAngelo et al. (2008) Animal: Mouse (Study 1) B6C3F1 M 28–30 days Study duration: 60 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0+ 50 500 5,000 mg/L in drinking water ad libitum × 60 weeks + 2,000 mg/L NaCl | Liver – Carcinoma
DeAngelo et al. (2008) Animal: Mouse (Study 1) B6C3F1 M 28–30 days Study duration: 60 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0+ 50 500 5,000 mg/L in drinking water ad libitum × 60 weeks + 2,000 mg/L NaCl | 0 | 2/30 (7%)
DeAngelo et al. (2008) Animal: Mouse (Study 1) B6C3F1 M 28–30 days Study duration: 60 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0+ 50 500 5,000 mg/L in drinking water ad libitum × 60 weeks + 2,000 mg/L NaCl | 50 | 1/27 (4%)
DeAngelo et al. (2008) Animal: Mouse (Study 1) B6C3F1 M 28–30 days Study duration: 60 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0+ 50 500 5,000 mg/L in drinking water ad libitum × 60 weeks + 2,000 mg/L NaCl | 500 | 6/29 (21%)
DeAngelo et al. (2008) Animal: Mouse (Study 1) B6C3F1 M 28–30 days Study duration: 60 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0+ 50 500 5,000 mg/L in drinking water ad libitum × 60 weeks + 2,000 mg/L NaCl | 5,000 | 11/29^r^ (38%)
DeAngelo et al. (2008) Animal: Mouse (Study 1) B6C3F1 M 28–30 days Study duration: 60 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0+ 50 500 5,000 mg/L in drinking water ad libitum × 60 weeks + 2,000 mg/L NaCl | Liver – Adenoma or carcinoma
DeAngelo et al. (2008) Animal: Mouse (Study 1) B6C3F1 M 28–30 days Study duration: 60 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0+ 50 500 5,000 mg/L in drinking water ad libitum × 60 weeks + 2,000 mg/L NaCl | 0 | 4/30 (13%)
DeAngelo et al. (2008) Animal: Mouse (Study 1) B6C3F1 M 28–30 days Study duration: 60 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0+ 50 500 5,000 mg/L in drinking water ad libitum × 60 weeks + 2,000 mg/L NaCl | 50 | 4/27 (15%)
DeAngelo et al. (2008) Animal: Mouse (Study 1) B6C3F1 M 28–30 days Study duration: 60 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0+ 50 500 5,000 mg/L in drinking water ad libitum × 60 weeks + 2,000 mg/L NaCl | 500 | 11/29^r^ (38%)
DeAngelo et al. (2008) Animal: Mouse (Study 1) B6C3F1 M 28–30 days Study duration: 60 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0+ 50 500 5,000 mg/L in drinking water ad libitum × 60 weeks + 2,000 mg/L NaCl | 5,000 | 16/29^r^ (55%)
DeAngelo et al. (2008) Animal: Mouse (Study 2) B6C3F1 M 28–30 days Study duration: 104 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0+ 4,500 mg/L in drinking water ad libitum × 104 weeks + 1.5 g/L of neutralized acetic acid | Liver – Adenoma | | Survival: No difference in survival: 34/51–30/42 Body weight: No reported. Significantly increased preneoplastic lesions: Large foci of cellular alteration were not significantly increased. Large foci of cellular alteration were considered preneoplastic. Other comments: Denominators of incidences are based on surviving mice. Water consumption decreased in 0.5 and 5.0 g/l groups. Strengths and limitations: Only one dose level was tested but was given for a near life-span of a large number of animals. Most organs were histologically evaluated and evaluations were confirmed by an independent pathologist.
DeAngelo et al. (2008) Animal: Mouse (Study 2) B6C3F1 M 28–30 days Study duration: 104 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0+ 4,500 mg/L in drinking water ad libitum × 104 weeks + 1.5 g/L of neutralized acetic acid | 0 | 0/25
DeAngelo et al. (2008) Animal: Mouse (Study 2) B6C3F1 M 28–30 days Study duration: 104 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0+ 4,500 mg/L in drinking water ad libitum × 104 weeks + 1.5 g/L of neutralized acetic acid | 4,500 | 21/36^r^ (59%)
DeAngelo et al. (2008) Animal: Mouse (Study 2) B6C3F1 M 28–30 days Study duration: 104 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0+ 4,500 mg/L in drinking water ad libitum × 104 weeks + 1.5 g/L of neutralized acetic acid | Liver – Carcinoma
DeAngelo et al. (2008) Animal: Mouse (Study 2) B6C3F1 M 28–30 days Study duration: 104 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0+ 4,500 mg/L in drinking water ad libitum × 104 weeks + 1.5 g/L of neutralized acetic acid | 0 | 3/25 (12%)
DeAngelo et al. (2008) Animal: Mouse (Study 2) B6C3F1 M 28–30 days Study duration: 104 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0+ 4,500 mg/L in drinking water ad libitum × 104 weeks + 1.5 g/L of neutralized acetic acid | 4,500 | 28/36^r^ (78%)
DeAngelo et al. (2008) Animal: Mouse (Study 2) B6C3F1 M 28–30 days Study duration: 104 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0+ 4,500 mg/L in drinking water ad libitum × 104 weeks + 1.5 g/L of neutralized acetic acid | Liver – Adenoma or carcinoma
DeAngelo et al. (2008) Animal: Mouse (Study 2) B6C3F1 M 28–30 days Study duration: 104 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0+ 4,500 mg/L in drinking water ad libitum × 104 weeks + 1.5 g/L of neutralized acetic acid | 0 | 3/25 (12%)
DeAngelo et al. (2008) Animal: Mouse (Study 2) B6C3F1 M 28–30 days Study duration: 104 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0+ 4,500 mg/L in drinking water ad libitum × 104 weeks + 1.5 g/L of neutralized acetic acid | 4,500 | 32/36^r^ (89%)
DeAngelo et al. (2008) Animal: Mouse (Study 3) B6C3F1 M 28–30 days Study duration: 104 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0 50 500 mg/L in neutralized drinking water ad libitum × 104 weeks | Liver – Adenoma | | Survival: No difference in survival: 34/51–29/53, 27/51 Body weight: No reported. Significantly increased preneoplastic lesions: Large foci of cellular alteration were significantly increased at 500 mg/L (p < 0.05. Large foci of cellular alteration were considered preneoplastic. Other comments: Denominators of incidences are based on surviving mice. No difference in water consumption occurred. Strengths and limitations: Only two dose levels were tested, but they were low compared to other studies and were given for near a life-span of time to a large number of animals. Most organs were histologically evaluated and evaluations were confirmed by an independent pathologist.
DeAngelo et al. (2008) Animal: Mouse (Study 3) B6C3F1 M 28–30 days Study duration: 104 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0 50 500 mg/L in neutralized drinking water ad libitum × 104 weeks | 0 | 9/42 (21%)
DeAngelo et al. (2008) Animal: Mouse (Study 3) B6C3F1 M 28–30 days Study duration: 104 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0 50 500 mg/L in neutralized drinking water ad libitum × 104 weeks | 50 | 8/35 (23%)
DeAngelo et al. (2008) Animal: Mouse (Study 3) B6C3F1 M 28–30 days Study duration: 104 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0 50 500 mg/L in neutralized drinking water ad libitum × 104 weeks | 500 | 19/37^r^ (51%)
DeAngelo et al. (2008) Animal: Mouse (Study 3) B6C3F1 M 28–30 days Study duration: 104 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0 50 500 mg/L in neutralized drinking water ad libitum × 104 weeks | Liver – Carcinoma
DeAngelo et al. (2008) Animal: Mouse (Study 3) B6C3F1 M 28–30 days Study duration: 104 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0 50 500 mg/L in neutralized drinking water ad libitum × 104 weeks | 0 | 23/42 (55%)
DeAngelo et al. (2008) Animal: Mouse (Study 3) B6C3F1 M 28–30 days Study duration: 104 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0 50 500 mg/L in neutralized drinking water ad libitum × 104 weeks | 50 | 14/35 (40%)
DeAngelo et al. (2008) Animal: Mouse (Study 3) B6C3F1 M 28–30 days Study duration: 104 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0 50 500 mg/L in neutralized drinking water ad libitum × 104 weeks | 500 | 29/37^r^ (78%)
DeAngelo et al. (2008) Animal: Mouse (Study 3) B6C3F1 M 28–30 days Study duration: 104 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0 50 500 mg/L in neutralized drinking water ad libitum × 104 weeks | [Trend p value: <0.01]
DeAngelo et al. (2008) Animal: Mouse (Study 3) B6C3F1 M 28–30 days Study duration: 104 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0 50 500 mg/L in neutralized drinking water ad libitum × 104 weeks | Liver – Adenoma or carcinoma
DeAngelo et al. (2008) Animal: Mouse (Study 3) B6C3F1 M 28–30 days Study duration: 104 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0 50 500 mg/L in neutralized drinking water ad libitum × 104 weeks | 0 | 27/42 (64%)
DeAngelo et al. (2008) Animal: Mouse (Study 3) B6C3F1 M 28–30 days Study duration: 104 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0 50 500 mg/L in neutralized drinking water ad libitum × 104 weeks | 50 | 20/35 (57%)
DeAngelo et al. (2008) Animal: Mouse (Study 3) B6C3F1 M 28–30 days Study duration: 104 weeks | Agent: Trichloroacetic acid 99% Treatment: Drinking water 0 50 500 mg/L in neutralized drinking water ad libitum × 104 weeks | 500 | 32/37^r^ (87%)
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 4 weeks Study duration: 61 weeks | Agent: Trichloroacetic acid >99% Treatment: Drinking water 0+ 5,000 mg/L in drinking water (pH 6.5–7.5) ad libitum × 61 weeks + 2,000 mg/L NaCl | Liver – Adenoma | | Survival: Not reported. Body weight: Body weights were significantly decreased (p < 0.001). Calculations were done by one-way analysis of variance with a Tukey's comparison. Significantly increased preneoplastic lesions: Not reported. Strengths and limitations: The durations were less than near life-span. Only males were tested at a single dose level and only livers were histologically evaluated.
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 4 weeks Study duration: 61 weeks | Agent: Trichloroacetic acid >99% Treatment: Drinking water 0+ 5,000 mg/L in drinking water (pH 6.5–7.5) ad libitum × 61 weeks + 2,000 mg/L NaCl | 0 | 2/22 (9%)
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 4 weeks Study duration: 61 weeks | Agent: Trichloroacetic acid >99% Treatment: Drinking water 0+ 5,000 mg/L in drinking water (pH 6.5–7.5) ad libitum × 61 weeks + 2,000 mg/L NaCl | 5,000 | 8/22** (36%)
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 4 weeks Study duration: 61 weeks | Agent: Trichloroacetic acid >99% Treatment: Drinking water 0+ 5,000 mg/L in drinking water (pH 6.5–7.5) ad libitum × 61 weeks + 2,000 mg/L NaCl | Liver – Carcinoma
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 4 weeks Study duration: 61 weeks | Agent: Trichloroacetic acid >99% Treatment: Drinking water 0+ 5,000 mg/L in drinking water (pH 6.5–7.5) ad libitum × 61 weeks + 2,000 mg/L NaCl | 0 | 0/22
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 4 weeks Study duration: 61 weeks | Agent: Trichloroacetic acid >99% Treatment: Drinking water 0+ 5,000 mg/L in drinking water (pH 6.5–7.5) ad libitum × 61 weeks + 2,000 mg/L NaCl | 5,000 | 7/22** (32%)
Pereira (1996) Animal: Mouse (Study 1) B6C3F1 F 7–8 weeks Study duration: 576 days | Agent: Trichloroacetic acid (TCA) Not reported Treatment: Drinking water 0+ 330++ 1,100++ 3,300++ mg/L in filtered and deionized water, pH 6.5–7.5 ad libitum × 576 days + 20.0 mmol/L NaCl ++ Concentrations were reported as mmol/L and calculated to mg/L based on a mw of 163.3869 g/mol | Liver – Adenoma | | Survival: Not reported Body weight: The high dose level of DCA was caused significant weight loss after 35 weeks and beyond, while the high dose of TCA caused it at 51 weeks, with near significant decreases beyond. Significantly increased preneoplastic lesions: The foci of altered hepatocytes were reported combined with neoplasms but not separately. They are likely considered part of the continuum toward neoplasia as it was reported combined with adenomas and carcinomas as proliferative lesions and other publications by this author under similar studies reported that a similar lesion (large foci of cellular alteration) was only distinguishable from adenomas because the nodules caused compression at less than 80% of its surface (DeAngelo et al. 2008). Strengths and limitations: The chemicals were not characterized, not even purity was reported. Disease surveillance was not continually monitored. A variable number of only females were tested, with only their livers examined histologically.
Pereira (1996) Animal: Mouse (Study 1) B6C3F1 F 7–8 weeks Study duration: 576 days | | 0 | 2/90 (2.2%)
Pereira (1996) Animal: Mouse (Study 1) B6C3F1 F 7–8 weeks Study duration: 576 days | | 330 | 4/53 (7.6%)
Pereira (1996) Animal: Mouse (Study 1) B6C3F1 F 7–8 weeks Study duration: 576 days | | 1,100 | 3/27 (11.1%)
Pereira (1996) Animal: Mouse (Study 1) B6C3F1 F 7–8 weeks Study duration: 576 days | | 3,300 | 7/18* (38.9%)
Pereira (1996) Animal: Mouse (Study 1) B6C3F1 F 7–8 weeks Study duration: 576 days | | Liver – Carcinoma
Pereira (1996) Animal: Mouse (Study 1) B6C3F1 F 7–8 weeks Study duration: 576 days | | 0 | 2/90 (2.2%)
Pereira (1996) Animal: Mouse (Study 1) B6C3F1 F 7–8 weeks Study duration: 576 days | | 330 | 0/53
Pereira (1996) Animal: Mouse (Study 1) B6C3F1 F 7–8 weeks Study duration: 576 days | | 1,100 | 5/27** (18.5%)
Pereira (1996) Animal: Mouse (Study 1) B6C3F1 F 7–8 weeks Study duration: 576 days | | 3,300 | 5/18** (27.8%)
Pereira (1996) Animal: Mouse (Study 1) B6C3F1 F 7–8 weeks Study duration: 576 days | | [Trend p value: <0.001]
Pereira (1996) Animal: Mouse (Study 2) B6C3F1 F 7–8 weeks Study duration: 360 days | Agent: Trichloroacetic acid (TCA) Not reported Treatment: Drinking water 0+ 330++ 1,100++ 3,300++mg/L in filtered and deionized water, pH 6.5–7.5 ad libitum × 360 days + 20 mmol/L NaCl ++ Concentrations were reported as mmol/L and were calculated to mg/L based on a mw of 163.3869g/mol | Liver – Adenoma | | Survival: Not reported Body weight: The high dose level of DCA was caused significant weight loss after 35 weeks and beyond, while the high dose of TCA caused it at 51 weeks, with near significant decreases beyond. Significantly increased preneoplastic lesions: The foci of altered hepatocytes were reported combined with neoplasms but not separately. They are likely considered part of the continuum toward neoplasia as it was reported combined with adenomas and carcinomas as proliferative lesions and other publications by this author under similar studies reported that a similar lesion (large foci of cellular alteration) was only distinguishable from adenomas because the nodules caused compression at less than 80% of its surface (DeAngelo et al. 2008). Strengths and limitations: The chemicals were not characterized, not even purity was reported. Disease surveillance was not continually monitored. A variable number of only females were tested, with only their livers examined histologically.
Pereira (1996) Animal: Mouse (Study 2) B6C3F1 F 7–8 weeks Study duration: 360 days | | 0 | 1/40 (2.5%)
Pereira (1996) Animal: Mouse (Study 2) B6C3F1 F 7–8 weeks Study duration: 360 days | | 330 | 3/40 (7.5%)
Pereira (1996) Animal: Mouse (Study 2) B6C3F1 F 7–8 weeks Study duration: 360 days | | 1,100 | 3/19 (15.8%)
Pereira (1996) Animal: Mouse (Study 2) B6C3F1 F 7–8 weeks Study duration: 360 days | | 3,300 | 2/20 (10%)
Pereira (1996) Animal: Mouse (Study 2) B6C3F1 F 7–8 weeks Study duration: 360 days | | Liver – Carcinoma
Pereira (1996) Animal: Mouse (Study 2) B6C3F1 F 7–8 weeks Study duration: 360 days | | 0 | 0/40
Pereira (1996) Animal: Mouse (Study 2) B6C3F1 F 7–8 weeks Study duration: 360 days | | 330 | 0/40
Pereira (1996) Animal: Mouse (Study 2) B6C3F1 F 7–8 weeks Study duration: 360 days | | 1,100 | 0/19
Pereira (1996) Animal: Mouse (Study 2) B6C3F1 F 7–8 weeks Study duration: 360 days | | 3,300 | 5/20* (25%)
Bull et al. (1990) Animal: Mouse B6C3F1 M 5 weeks Study duration: 52 weeks | Agent: Trichloroacetic acid Analytical grade Treatment: Drinking water 0 1,000 2,000 mg/L in drinking water (pH 6.8–7.2) ad libitum × 52 wk | Liver – Adenoma | | Survival: All mice survived. Significantly increased preneoplastic lesions: A non-significant increase in hyperplasia was reported. Strengths and limitations: The chemical was not characterized; disease surveillance was not reported. A low number of mice per group were exposed for a less than near life-span duration and only males had results reported. Only livers were histologically examined. Not all lesions were histologically evaluated but, instead, samples of lesions were evaluated. Results were reported so that incidences of specific neoplasms could not be determined but could be estimated.
Bull et al. (1990) Animal: Mouse B6C3F1 M 5 weeks Study duration: 52 weeks | Agent: Trichloroacetic acid Analytical grade Treatment: Drinking water 0 1,000 2,000 mg/L in drinking water (pH 6.8–7.2) ad libitum × 52 wk | 0 | 0/2
Bull et al. (1990) Animal: Mouse B6C3F1 M 5 weeks Study duration: 52 weeks | Agent: Trichloroacetic acid Analytical grade Treatment: Drinking water 0 1,000 2,000 mg/L in drinking water (pH 6.8–7.2) ad libitum × 52 wk | 1,000 | 2/5 (40%)
Bull et al. (1990) Animal: Mouse B6C3F1 M 5 weeks Study duration: 52 weeks | Agent: Trichloroacetic acid Analytical grade Treatment: Drinking water 0 1,000 2,000 mg/L in drinking water (pH 6.8–7.2) ad libitum × 52 wk | 2,000 | 1/11 (9%)
Bull et al. (1990) Animal: Mouse B6C3F1 M 5 weeks Study duration: 52 weeks | Agent: Trichloroacetic acid Analytical grade Treatment: Drinking water 0 1,000 2,000 mg/L in drinking water (pH 6.8–7.2) ad libitum × 52 wk | Liver – Carcinoma
Bull et al. (1990) Animal: Mouse B6C3F1 M 5 weeks Study duration: 52 weeks | Agent: Trichloroacetic acid Analytical grade Treatment: Drinking water 0 1,000 2,000 mg/L in drinking water (pH 6.8–7.2) ad libitum × 52 wk | 0 | 0/2
Bull et al. (1990) Animal: Mouse B6C3F1 M 5 weeks Study duration: 52 weeks | Agent: Trichloroacetic acid Analytical grade Treatment: Drinking water 0 1,000 2,000 mg/L in drinking water (pH 6.8–7.2) ad libitum × 52 wk | 1,000 | 2/5 (40%)
Bull et al. (1990) Animal: Mouse B6C3F1 M 5 weeks Study duration: 52 weeks | Agent: Trichloroacetic acid Analytical grade Treatment: Drinking water 0 1,000 2,000 mg/L in drinking water (pH 6.8–7.2) ad libitum × 52 wk | 2,000 | 4/11 (36.4%)
Von Tungeln et al. (2002) Animal: Mouse (Study 1) B6C3F1 M 8 days (neonatal) Study duration: 20 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 1,000 nmol 1/3 of the dose was injected at age 8 days and 2/3 at age 15 days + DMSO | Liver – Adenoma | | Survival: One mouse died after the age of 28 days in the 20 month vehicle control group. All other groups had no mortality after 28 days of age. Body weight: Not reported. Other comments: Early mortality, before 28 days of age was not reported, but was as high as 29% in some groups (which may have included testing of other chemicals). Strengths and limitations: The study used both positive and negative controls but did not characterize the chemicals and used a small, number of male mice per group. Only two doses were administered at two narrow dose levels, though the duration of observation was almost near life-span. Early mortality was not reported.
Von Tungeln et al. (2002) Animal: Mouse (Study 1) B6C3F1 M 8 days (neonatal) Study duration: 20 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 1,000 nmol 1/3 of the dose was injected at age 8 days and 2/3 at age 15 days + DMSO | 0 | 0/23
Von Tungeln et al. (2002) Animal: Mouse (Study 1) B6C3F1 M 8 days (neonatal) Study duration: 20 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 1,000 nmol 1/3 of the dose was injected at age 8 days and 2/3 at age 15 days + DMSO | 1,000 | 4/23 (17%)
Von Tungeln et al. (2002) Animal: Mouse (Study 1) B6C3F1 M 8 days (neonatal) Study duration: 20 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 1,000 nmol 1/3 of the dose was injected at age 8 days and 2/3 at age 15 days + DMSO | Liver – Carcinoma
Von Tungeln et al. (2002) Animal: Mouse (Study 1) B6C3F1 M 8 days (neonatal) Study duration: 20 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 1,000 nmol 1/3 of the dose was injected at age 8 days and 2/3 at age 15 days + DMSO | 0 | 0/23
Von Tungeln et al. (2002) Animal: Mouse (Study 1) B6C3F1 M 8 days (neonatal) Study duration: 20 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 1,000 nmol 1/3 of the dose was injected at age 8 days and 2/3 at age 15 days + DMSO | 1,000 | 1/23 (4%)
Von Tungeln et al. (2002) Animal: Mouse (Study 1) B6C3F1 M 8 days (neonatal) Study duration: 20 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 1,000 nmol 1/3 of the dose was injected at age 8 days and 2/3 at age 15 days + DMSO | Liver – Adenoma or carcinoma
Von Tungeln et al. (2002) Animal: Mouse (Study 1) B6C3F1 M 8 days (neonatal) Study duration: 20 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 1,000 nmol 1/3 of the dose was injected at age 8 days and 2/3 at age 15 days + DMSO | 0 | 0/23
Von Tungeln et al. (2002) Animal: Mouse (Study 1) B6C3F1 M 8 days (neonatal) Study duration: 20 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 1,000 nmol 1/3 of the dose was injected at age 8 days and 2/3 at age 15 days + DMSO | 1,000 | 5/23[*] (22%)
Von Tungeln et al. (2002) Animal: Mouse (Study 1) B6C3F1 F 8 days (neonatal) Study duration: 20 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 1,000 nmol 1/3 of the dose was injected at age 8 days and 2/3 at age 15 days + DMSO | Liver – Adenoma | | Survival: One mouse died after the age of 28 days in the 20 month vehicle control group. All other groups had no mortality after 28 days of age. Body weight: Not reported. Other comments: Early mortality, before 28 days of age was not reported, but was as high as 29% in some groups (which may have included testing of other chemicals). Strengths and limitations: The study used both positive and negative controls but did not characterize the chemicals and used a small, number of male mice per group. Only two doses were administered at two narrow dose levels, though the duration of observation was almost near life-span. Early mortality was not reported.
Von Tungeln et al. (2002) Animal: Mouse (Study 1) B6C3F1 F 8 days (neonatal) Study duration: 20 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 1,000 nmol 1/3 of the dose was injected at age 8 days and 2/3 at age 15 days + DMSO | 0 | 0/23
Von Tungeln et al. (2002) Animal: Mouse (Study 1) B6C3F1 F 8 days (neonatal) Study duration: 20 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 1,000 nmol 1/3 of the dose was injected at age 8 days and 2/3 at age 15 days + DMSO | 1,000 | 0/23
Von Tungeln et al. (2002) Animal: Mouse (Study 1) B6C3F1 F 8 days (neonatal) Study duration: 20 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 1,000 nmol 1/3 of the dose was injected at age 8 days and 2/3 at age 15 days + DMSO | Liver – Carcinoma
Von Tungeln et al. (2002) Animal: Mouse (Study 1) B6C3F1 F 8 days (neonatal) Study duration: 20 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 1,000 nmol 1/3 of the dose was injected at age 8 days and 2/3 at age 15 days + DMSO | 0 | 0/23
Von Tungeln et al. (2002) Animal: Mouse (Study 1) B6C3F1 F 8 days (neonatal) Study duration: 20 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 1,000 nmol 1/3 of the dose was injected at age 8 days and 2/3 at age 15 days + DMSO | 1,000 | 0/23
Von Tungeln et al. (2002) Animal: Mouse (Study 1) B6C3F1 F 8 days (neonatal) Study duration: 20 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 1,000 nmol 1/3 of the dose was injected at age 8 days and 2/3 at age 15 days + DMSO | Liver – Adenoma or carcinoma
Von Tungeln et al. (2002) Animal: Mouse (Study 1) B6C3F1 F 8 days (neonatal) Study duration: 20 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 1,000 nmol 1/3 of the dose was injected at age 8 days and 2/3 at age 15 days + DMSO | 0 | 0/23
Von Tungeln et al. (2002) Animal: Mouse (Study 1) B6C3F1 F 8 days (neonatal) Study duration: 20 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 1,000 nmol 1/3 of the dose was injected at age 8 days and 2/3 at age 15 days + DMSO | 1,000 | 0/23
Von Tungeln et al. (2002) Animal: Mouse (Study 2) B6C3F1 M 8 days (neonatal) Study duration: 12 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 2,000 nmol 3/7 of the dose was injected at age 8 days and 4/7 at age 15 days. + DMSO | Liver – Adenoma | | Survival: One mouse died after the age of 28 days in the 20 month vehicle control group. All other groups had no mortality after 28 days of age. Body weight: Not reported. Other comments: Early mortality, before 28 days of age was not reported, but was as high as 29% in some groups (which may have included testing of other chemicals). Strengths and limitations: The study used both positive and negative controls but did not characterize the chemicals and used a small, number of male mice per group. Only two doses were administered at two narrow dose levels, though the duration of observation was almost near life-span. Early mortality was not reported.
Von Tungeln et al. (2002) Animal: Mouse (Study 2) B6C3F1 M 8 days (neonatal) Study duration: 12 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 2,000 nmol 3/7 of the dose was injected at age 8 days and 4/7 at age 15 days. + DMSO | 0 | 0/24
Von Tungeln et al. (2002) Animal: Mouse (Study 2) B6C3F1 M 8 days (neonatal) Study duration: 12 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 2,000 nmol 3/7 of the dose was injected at age 8 days and 4/7 at age 15 days. + DMSO | 2,000 | 4/24 (17%)
Von Tungeln et al. (2002) Animal: Mouse (Study 2) B6C3F1 M 8 days (neonatal) Study duration: 12 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 2,000 nmol 3/7 of the dose was injected at age 8 days and 4/7 at age 15 days. + DMSO | Liver – Carcinoma
Von Tungeln et al. (2002) Animal: Mouse (Study 2) B6C3F1 M 8 days (neonatal) Study duration: 12 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 2,000 nmol 3/7 of the dose was injected at age 8 days and 4/7 at age 15 days. + DMSO | 0 | 0/24
Von Tungeln et al. (2002) Animal: Mouse (Study 2) B6C3F1 M 8 days (neonatal) Study duration: 12 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 2,000 nmol 3/7 of the dose was injected at age 8 days and 4/7 at age 15 days. + DMSO | 2,000 | 0/24
Von Tungeln et al. (2002) Animal: Mouse (Study 2) B6C3F1 M 8 days (neonatal) Study duration: 12 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 2,000 nmol 3/7 of the dose was injected at age 8 days and 4/7 at age 15 days. + DMSO | Liver – Adenoma or carcinoma
Von Tungeln et al. (2002) Animal: Mouse (Study 2) B6C3F1 M 8 days (neonatal) Study duration: 12 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 2,000 nmol 3/7 of the dose was injected at age 8 days and 4/7 at age 15 days. + DMSO | 0 | 0/24
Von Tungeln et al. (2002) Animal: Mouse (Study 2) B6C3F1 M 8 days (neonatal) Study duration: 12 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 2,000 nmol 3/7 of the dose was injected at age 8 days and 4/7 at age 15 days. + DMSO | 2,000 | 4/24 (17%)
Von Tungeln et al. (2002) Animal: Mouse (Study 2) B6C3F1 F 8 days (neonatal) Study duration: 12 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 2,000 nmol 3/7 of the dose was injected at age 8 days and 4/7 at age 15 days. + DMSO | Liver – Adenoma | | Survival: One mouse died after the age of 28 days in the 20 month vehicle control group. All other groups had no mortality after 28 days of age. Body weight: Not reported. Other comments: Early mortality, before 28 days of age was not reported, but was as high as 29% in some groups (which may have included testing of other chemicals). Strengths and limitations: The study used both positive and negative controls but did not characterize the chemicals and used a small, number of male mice per group. Only two doses were administered at two narrow dose levels, though the duration of observation was almost near life-span. Early mortality was not reported.
Von Tungeln et al. (2002) Animal: Mouse (Study 2) B6C3F1 F 8 days (neonatal) Study duration: 12 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 2,000 nmol 3/7 of the dose was injected at age 8 days and 4/7 at age 15 days. + DMSO | 0 | 0/24
Von Tungeln et al. (2002) Animal: Mouse (Study 2) B6C3F1 F 8 days (neonatal) Study duration: 12 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 2,000 nmol 3/7 of the dose was injected at age 8 days and 4/7 at age 15 days. + DMSO | 2,000 | 0/24
Von Tungeln et al. (2002) Animal: Mouse (Study 2) B6C3F1 F 8 days (neonatal) Study duration: 12 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 2,000 nmol 3/7 of the dose was injected at age 8 days and 4/7 at age 15 days. + DMSO | Liver – Carcinoma
Von Tungeln et al. (2002) Animal: Mouse (Study 2) B6C3F1 F 8 days (neonatal) Study duration: 12 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 2,000 nmol 3/7 of the dose was injected at age 8 days and 4/7 at age 15 days. + DMSO | 0 | 0/24
Von Tungeln et al. (2002) Animal: Mouse (Study 2) B6C3F1 F 8 days (neonatal) Study duration: 12 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 2,000 nmol 3/7 of the dose was injected at age 8 days and 4/7 at age 15 days. + DMSO | 2,000 | 0/24
Von Tungeln et al. (2002) Animal: Mouse (Study 2) B6C3F1 F 8 days (neonatal) Study duration: 12 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 2,000 nmol 3/7 of the dose was injected at age 8 days and 4/7 at age 15 days. + DMSO | Liver – Adenoma or carcinoma
Von Tungeln et al. (2002) Animal: Mouse (Study 2) B6C3F1 F 8 days (neonatal) Study duration: 12 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 2,000 nmol 3/7 of the dose was injected at age 8 days and 4/7 at age 15 days. + DMSO | 0 | 0/24
Von Tungeln et al. (2002) Animal: Mouse (Study 2) B6C3F1 F 8 days (neonatal) Study duration: 12 months | Agent: Trichloroacetic acid Purity not reported Treatment: ip injection 0+ 2,000 nmol 3/7 of the dose was injected at age 8 days and 4/7 at age 15 days. + DMSO | 2,000 | 0/24
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Liver – Adenoma^a^ | | Survival: Significant decrease in survival. Body weight: Significant decreased in body weight after 57 weeks at 1,000 mg/l and after 73 weeks at 500 mg/l. Strengths and limitations: Well reported and designed study, with a large number of animals of both sexes exposed for near life-span at three exposure levels.
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 39/50 (87%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 41/50 (90%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 42/49 (91%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 40/51 (91%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Liver – Carcinoma^a^
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 12/50 (29%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 22/50* (50%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 27/49***^t^ (66%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 39/51***^t^ (87%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Trend p value: <0.001
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Liver – Adenoma or carcinoma^a^
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 42/50 (91%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 47/50 (98%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 46/49 (97%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 48/51 (98%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Liver – Hepatoblastoma^a^
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 4/50 (10%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 24/50***^u^ (54%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 40/49***^u^ (87%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 34/51***^u^ (78%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Trend p value: <0.001
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Liver – Adenoma, carcinoma, or hepatoblastoma
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 42/50 (91%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 50/50* (100%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 48/49 (98%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 49/51* (99%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Trend p value: =0.036
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Liver – Hemangiosarcoma^a^
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 1/50 (3%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 4/50 (10%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 2/49 (6%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 weeks Study duration: 105 weeks | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 4/51 (12%)
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Liver – Adenoma^a^ | | Survival: No effect on survival. 30/50–33/50, 29/50, 27/50 Body weight: Significant decrease in body weight after 73 weeks at 1,000 mg/l and after 89 weeks at 250 mg/L. Strengths and limitations: Well reported and designed study, with a large number of animals of both sexes exposed for near life-span at three exposure levels.
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 33/49^v^ (75%)
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 42/50*^v^ (91%)
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 42/49*^v^ (93%)
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 44/50**^v^ (93%)
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Trend p value: =0.009
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Liver – Carcinoma^a^
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 9/49 (21%)
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 17/50^w^ (38%)
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 22/49**^x^ (50%)
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 26/50***^x^ (59%)
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Trend p value: <0.001
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Liver – Adenoma or carcinoma^a^
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 36/49 (81.1%)
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 44/50* (93.7%)
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 43/49* (94.7%)
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 46/50* (95.5%)
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Trend p value: =0.013
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Liver – Hepatoblastoma^a^
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 0/49
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 1/50 (2%)
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 4/49 (9%)
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 6/50*^y^ (14%)
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Trend p value: =0.003
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Liver – Hemangiosarcoma^a^
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 2/49 (5%)
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 4/50 (9%)
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 4/49 (9%)
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 8/50* (19%)
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Trend p value: =0.026

* < 0.05; ** < 0.01; *** < 0.00 p value.

[ ] = p value calculated by NTP using Fisher’s Exact Test for pairwise comparisons or Cochran-Armitage Trend Test.

^a^ Adjusted percent incidence based on Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^b^ Exceeds historical controls from drinking water studies: 84/197 (range 34%–63%); exceeds historical controls from studies of all routes: 490/1,506 (range 12%–63%).

^c^ Exceeds historical controls from drinking water studies: 57/197 (range 18%–42%); exceeds historical controls from studies of all routes: 344/1,506 (range 8%–46%).

^d^ Exceeds historical controls from drinking water studies: 122/197 (range 48%–85%); exceeds historical controls from studies of all routes: 745/1,506 (range 20%–85%).

^e^ Exceeds historical controls from drinking water studies: 11/197 (range 0%–13%); exceeds historical controls from studies of all routes: 22/1,506 (range 0%–13%).

^f^ Exceeds historical controls from drinking water studies: 93/248 (range 18%–61%): exceeds historical controls from studies of all routes: 312/1,549 (range 6%–61%).

^g^ Exceeds historical controls from drinking water studies: 28/248 (range 4%–26%); exceeds historical controls from studies of all routes: 128/1,549 (range 0%–26%).

^h^ Exceeds historical controls from drinking water studies: 110/248 (range 20%–63%); exceeds historical controls from studies of all routes: 408/1,549 (range 8%–63%).

^i^ Exceeds historical controls from drinking water studies: 4/300 (range 0%–4%); exceeds historical controls from studies of all routes: 10/1,199 (range 0%–4%).

^j^ Exceeds historical controls from drinking water studies: 3/250 (range 0%–4%).

^k^ Exceeds historical controls from drinking water studies: 140/247 (range 37%–72%); exceeds historical controls from studies of all routes: 544/1,146 (range 14%–72%).

^l^ Exceeds historical controls from drinking water studies: 91/247 (range 28%–48%); exceeds historical controls from studies of all routes: 317/1,146 (range 8%–48%).

^m^ Exceeds historical controls from drinking water studies: 182/247 (range 57%–85%); exceeds historical controls from studies of all routes: 729/1,146 (range 20%–85%).

^n^ Exceeds historical controls from drinking water studies: 28/247 (range 0%–34%); exceeds historical controls from studies of all routes: 43/1,146 (range 0%–34%).

^o^ Exceeds historical controls from drinking water studies: 133/297 (range 29%–61%); exceeds historical controls from studies of all routes: 345/1,245 (range 6%–62%).

^p^ Exceeds historical controls from drinking water studies: 51/297 (range 6%–28%); exceeds historical controls from studies of all routes: 131/1,245 (range 0%–28%).

^q^ Exceeds historical controls from drinking water studies: 158/297 (range 35%–63%); exceeds historical controls from studies of all routes: 419/1,245 (range 8%–64%).

^r^ p < 0.03.

^s^ p = 0.054.

^t^ Exceeds historical controls from drinking water studies: 38/100 (range 24%–52%); exceeds historical controls from studies of all routes: 348/949 (range 22%–56%).

^u^ Exceeds historical controls from drinking water studies: 10/100 (range 8%–12%); exceeds historical controls from studies of all routes: 40/949 (range 0%–12%).

^v^ Exceeds historical controls from drinking water studies: 71/98 (range 67%–78%); exceeds historical controls from studies of all routes: 378/948 (range 14%–78%).

^w^ Exceeds historical controls from drinking water studies: 20/98 (range 18%–22%).

^x^ Exceeds historical controls from drinking water studies: 20/98 (range 18%–22%); exceeds historical controls from studies of all routes: 152/948 (range 4%–46%).

^y^ Exceeds historical controls from drinking water studies: 10/98 (range 8%–12%); exceeds historical controls from studies of all routes: 40/948 (range 0%–12%).

Table C-57 All Other Tumors

Reference and Study Design | Exposure | Dose Levels | Tumor Incidence (n/N) (%) | Comments
(1992) Animal: Mouse B6C3F1 M 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg bw in deionized water 5 doses/week × 104 weeks | All organs – Tumor NOS | | Survival: The 100 mg/kg group was lower than controls and there was a significant trend: 46/60***(trend <0.001) – 39/60, 21/60***(<0.001) Body weight: Body weights were similar to controls. Significantly increased preneoplastic lesions: The incidence of forestomach pre-neoplasia (squamous cell hyperplasia) was significantly increased at 100 mg/kg. The incidence of nasal cavity pre-neoplasia (olfactory epithelium metaplasia) was not significantly increased. Metaplasia was from olfactory epithelium to ciliated columnar respiratory epithelium. Strengths and limitations: The study was well conducted to rule out confounding and with a strong power to detect tumor induction. However, only two exposed dose levels were tested, which limit the detection of dose response relationships.
(1992) Animal: Mouse B6C3F1 M 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg bw in deionized water 5 doses/week × 104 weeks | 0 | None
(1992) Animal: Mouse B6C3F1 M 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg bw in deionized water 5 doses/week × 104 weeks | 50 | None
(1992) Animal: Mouse B6C3F1 M 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg bw in deionized water 5 doses/week × 104 weeks | 100 | None
NTP (1992) Animal: Mouse B6C3F1 F 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg bw in deionized water 5 doses/week × 104 weeks | All organs – Tumor NOS | | Survival: Survival of the exposed groups were similar to controls: 42/60–40/60, 44/60 Body weight: Body weights of the low dose group were similar to controls, but after a year the high dose group had significantly lower body weight. Significantly increased preneoplastic lesions: The incidences of pre-neoplasia in the forestomach (squamous cell hyperplasia) and nasal cavity were significantly increased at 100 mg/kg. Hyperplasia included diffuse, focal, and multifocal lesions. Metaplasia was from olfactory epithelium to ciliated columnar respiratory epithelium. Strengths and limitations: The study was well conducted to rule out confounding and with a strong power to detect tumor induction. However, only two exposed dose levels were tested, which limit the detection of dose response relationships.
NTP (1992) Animal: Mouse B6C3F1 F 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg bw in deionized water 5 doses/week × 104 weeks | 0 | None
NTP (1992) Animal: Mouse B6C3F1 F 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg bw in deionized water 5 doses/week × 104 weeks | 50 | None
NTP (1992) Animal: Mouse B6C3F1 F 7–8 weeks Study duration: 104 weeks | Agent: Monochloroacetic acid 99% Treatment: Gavage 0 50 100 mg/kg bw in deionized water 5 doses/week × 104 weeks | 100 | None
NTP (2007a) Animal: Rat F344/N M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 20, 40 mg/kg bw) | Whole body – Malignant mesothelioma^a^ | | Survival: Survival was similar in all groups. 34/50–24/50, 30/50, 28/50 Body weight: Body weights were lower in the 500 (after 57 weeks) and 1,000 (after 29 weeks) mg/l groups compared to the untreated controls. Significantly increased preneoplastic lesions: Liver cystic degeneration (3/50–9/50*, 11/50*, 15/50**) Other comments: Water consumption was reduced in the 1,000 mg/l group after 2 years. Strengths and limitations: Large numbers of animals per group were used in both sexes and were continuously monitored for disease. Three dose levels spanning a range of 200-fold were used. Lesions and all major organs were histologically evaluated and statistics were clearly reported.
NTP (2007a) Animal: Rat F344/N M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 20, 40 mg/kg bw) | 0 | 3/50 (7%)
NTP (2007a) Animal: Rat F344/N M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 20, 40 mg/kg bw) | 50 | 1/50 (2%)
NTP (2007a) Animal: Rat F344/N M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 20, 40 mg/kg bw) | 500 | 0/50
NTP (2007a) Animal: Rat F344/N M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 20, 40 mg/kg bw) | 1,000 | 10/50*^b^ (23%)
NTP (2007a) Animal: Rat F344/N M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 20, 40 mg/kg bw) | Trend p value: <0.001
NTP (2007a) Animal: Rat F344/N M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 20, 40 mg/kg bw) | Whole body – Mononuclear cell leukemia^a^
NTP (2007a) Animal: Rat F344/N M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 20, 40 mg/kg bw) | 0 | 17/50^c^ (37%)
NTP (2007a) Animal: Rat F344/N M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 20, 40 mg/kg bw) | 50 | 31/50**^c^ (66%)
NTP (2007a) Animal: Rat F344/N M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 20, 40 mg/kg bw) | 500 | 24/50^c^ (56%)
NTP (2007a) Animal: Rat F344/N M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 20, 40 mg/kg bw) | 1,000 | 13/50 (30%)
NTP (2007a) Animal: Rat F344/N M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 20, 40 mg/kg bw) | Lung – Adenoma^a^
NTP (2007a) Animal: Rat F344/N M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 20, 40 mg/kg bw) | 0 | 2/50 (4.6%)
NTP (2007a) Animal: Rat F344/N M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 20, 40 mg/kg bw) | 50 | 0/50
NTP (2007a) Animal: Rat F344/N M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 20, 40 mg/kg bw) | 500 | 4/50 (10.1%)
NTP (2007a) Animal: Rat F344/N M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 20, 40 mg/kg bw) | 1,000 | 2/50 (4.9%)
NTP (2007a) Animal: Rat F344/N M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 20, 40 mg/kg bw) | Lung – Adenoma or carcinoma ^a^
NTP (2007a) Animal: Rat F344/N M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 20, 40 mg/kg bw) | 0 | 2/50 (4.6%)
NTP (2007a) Animal: Rat F344/N M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 20, 40 mg/kg bw) | 50 | 1/50 (2.4%)
NTP (2007a) Animal: Rat F344/N M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 20, 40 mg/kg bw) | 500 | 5/50 (12.6%)
NTP (2007a) Animal: Rat F344/N M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 20, 40 mg/kg bw) | 1,000 | 2/50 (4.9%)
NTP (2007a) Animal: Rat F344/N F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 25, 45 mg/kg bw) | Whole body – Malignant mesothelioma | | Survival: Survival was similar in all groups. 34/50–39/50, 35/50, 32/50 Body weight: Body weights were lower in the 1,000 (after 49 weeks) mg/l groups compared to the untreated controls. Significantly increased preneoplastic lesions: Significant increases in the incidence of lung per-neoplasia (alveolar epithelium hyperplasia) occurred at 500 and 1,000 mg/L. Kidney nephropathy (18/50–32/50**, 37/50**, 40/50**) Other comments: Water consumption was reduced in the 1,000 mg/l group after 2 years. Strengths and limitations: Large numbers of animals per group were used in both sexes and were continuously monitored for disease. Three dose levels spanning a range of 200-fold were used. Lesions and all major organs were histologically evaluated and statistics were clearly reported.
NTP (2007a) Animal: Rat F344/N F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 25, 45 mg/kg bw) | 0 | 0/50
NTP (2007a) Animal: Rat F344/N F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 25, 45 mg/kg bw) | 50 | 0/50
NTP (2007a) Animal: Rat F344/N F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 25, 45 mg/kg bw) | 500 | 1/50 (2%)
NTP (2007a) Animal: Rat F344/N F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 25, 45 mg/kg bw) | 1,000 | 0/50
NTP (2007a) Animal: Rat F344/N F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 25, 45 mg/kg bw) | Whole body – Mononuclear cell leukemiaᵃ
NTP (2007a) Animal: Rat F344/N F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 25, 45 mg/kg bw) | 0 | 11/50 (24%)
NTP (2007a) Animal: Rat F344/N F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 25, 45 mg/kg bw) | 50 | 13/50 (27%)
NTP (2007a) Animal: Rat F344/N F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 25, 45 mg/kg bw) | 500 | 16/50^d^ (35%)
NTP (2007a) Animal: Rat F344/N F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 25, 45 mg/kg bw) | 1,000 | 22/50*^d^ (47%)
NTP (2007a) Animal: Rat F344/N F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 25, 45 mg/kg bw) | Trend p value: =0.006
NTP (2007a) Animal: Rat F344/N F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 25, 45 mg/kg bw) | Lung – Adenoma or carcinoma
NTP (2007a) Animal: Rat F344/N F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 25, 45 mg/kg bw) | 0 | 2/50 (4%)
NTP (2007a) Animal: Rat F344/N F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 25, 45 mg/kg bw) | 50 | 3/50 (8%)
NTP (2007a) Animal: Rat F344/N F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 25, 45 mg/kg bw) | 500 | 2/50 (4%)
NTP (2007a) Animal: Rat F344/N F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Mean daily doses (0–2, 25, 45 mg/kg bw) | 1,000 | 5/50^e^ (10%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | Lung – Adenoma ^a^ | | Survival: Survival was similar in all groups. 31/50–38/50, 34/50, 31/50 Body weight: Body weights were greater in the 50 and 500 mg/l groups compared to the untreated controls after 85 weeks. Significantly increased preneoplastic lesions: The incidence of lung pre-neoplasia (Alveolar epithelium hyperplasia) was not significantly increased compared to controls. Spleen hematopoiesis occurred at an significant increased incidences at 500 and 1,000 mg/L. Other comments: Water consumption was similar to controls. Strengths and limitations: Large numbers of animals per group were used in both sexes and were continuously monitored for disease. Three dose levels spanning a range of 200-fold were used. Lesions and all major organs were histologically evaluated and statistics were clearly reported.
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 0 | 7/49 (16%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 50 | 5/50 (11%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 500 | 17/50*^f^ (38%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 1,000 | 12/50^g^ (27%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | Trend p value: =0.019
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | Lung – Carcinoma
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 0 | 5/49 (10%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 50 | 8/50^h^ (16%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 500 | 8/50^h^ (16%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 1,000 | 7/50^h^ (14%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | Lung – Adenoma or carcinomaᵃ
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 0 | 12/49^i^ (28%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 50 | 12/50 (26%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 500 | 22/50*^j^ (49%)
NTP (2007a) Animal: Mouse B6C3F1 M 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 45, 87 mg/kg | 1,000 | 17/50^i^ (37%)
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 35, 65 mg/kg | Lung – Adenoma ^a^ | | Survival: Survival was similar in all groups. 38/50–35/50, 32/50, 32/50 Body weight: Body weights were similar to the untreated controls. Other comments: Water consumption was similar to controls. Strengths and limitations: Large numbers of animals per group were used in both sexes and were continuously monitored for disease. Three dose levels spanning a range of 200-fold were used. Lesions and all major organs were histologically evaluated and statistics were clearly reported.
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 35, 65 mg/kg | 0 | 1/50 (2%)
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 35, 65 mg/kg | 50 | 3/50 (7%)
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 35, 65 mg/kg | 500 | 3/50 (7%)
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 35, 65 mg/kg | 1,000 | 6/50^k^ (13%)
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 35, 65 mg/kg | Trend p value: =0.044
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 35, 65 mg/kg | Lung – Carcinoma
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 35, 65 mg/kg | 0 | 1/50 (2%)
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 35, 65 mg/kg | 50 | 2/50 (4%)
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 35, 65 mg/kg | 500 | 2/50 (4%)
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 35, 65 mg/kg | 1,000 | 2/50 (4%)
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 35, 65 mg/kg | Lung – Adenoma or carcinoma ^a^
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 35, 65 mg/kg | 0 | 2/50 (4%)
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 35, 65 mg/kg | 50 | 5/50 (11%)
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 35, 65 mg/kg | 500 | 5/50 (11%)
NTP (2007a) Animal: Mouse B6C3F1 F 6 weeks Study duration: 106 weeks | Agent: Dibromoacetic acid >99% Treatment: Drinking water 0 50 500 1,000 mg/L of drinking water (pH 5) ad libitum × 106 weeks Average daily dose: 0–4, 35, 65 mg/kg | 1,000 | 7/50^l^ (15%)
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water × 105 weeks | Mammary gland – Fibroadenoma | | Survival: No significant difference: 31/50–26/50, 25/50, 29/50 Body weight: 1,000 mg/l group was 10% less than controls after 69 weeks. Significantly increased preneoplastic lesions: The incidence of lung pre-neoplasia (alveolar epithelium hyperplasia) was not significantly increased. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water × 105 weeks | 0 | 3/50 (6%)
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water × 105 weeks | 250 | 4/50 (8%)
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water × 105 weeks | 500 | 3/50 (6%)
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water × 105 weeks | 1,000 | 4/50 (8%)
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water × 105 weeks | Lung – Adenoma or carcinoma ^a^
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water × 105 weeks | 0 | 3/50 (7%)
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water × 105 weeks | 250 | 1/50 (2.5%)
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water × 105 weeks | 500 | 0/50
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water × 105 weeks | 1,000 | 3/50 (7.1%)
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water × 105 weeks | Pancreatic islets – Adenoma^a^
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water × 105 weeks | 0 | 3/50 (7%)
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water × 105 weeks | 250 | 4/50 (9.4%)
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water × 105 weeks | 500 | 9/50* (21.6%)
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water × 105 weeks | 1,000 | 3/50 (7.1%)
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water × 105 weeks | All organs – Malignant mesothelioma^a^
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water × 105 weeks | 0 | 1/50 (2.3%)
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water × 105 weeks | 250 | 5/50 (11.7%)
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water × 105 weeks | 500 | 10/50** (23.7%)
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water × 105 weeks | 1,000 | 6/50 (14%)
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water × 105 weeks | Large intestine – Adenoma ^a^
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water × 105 weeks | 0 | 0/50
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water × 105 weeks | 250 | 2/50 (4.8%)
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water × 105 weeks | 500 | 0/50
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water × 105 weeks | 1,000 | 4/50 (9.5%)
NTP (2009) Animal: Rat F344/N M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water × 105 weeks | Trend p value: =0.031
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Mammary gland – Fibroadenoma^a^ | | Survival: No significant difference: 34/50–31/50, 37/50, 35/50 Body weight: 1,000 mg/l group was <10% of controls. after 85 weeks. Significantly increased preneoplastic lesions: The incidence of lung pre-neoplasia (alveolar epithelium hyperplasia) was significantly increased at 1,000 mg/L. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 43/50 (92%)
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 43/50 (90%)
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 47/50 (96.9%)
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 46/50 (96.9%)
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Mammary gland – Fibroadenoma (multiple only)^a^
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 22/50 (44%)
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 24/50 (48%)
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 43/50** (86%)
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 38/50** (76%)
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Lung – Adenoma or carcinoma
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 1/50 (2%)
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 1/50 (2%)
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 2/50 (4%)
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 2/50 (4%)
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Pancreatic islets – Adenoma^a^
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 3/49 (7%)
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 1/50 (2.3%)
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 1/50 (2.2%)
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 2/50 (4.4%)
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Large intestine – Adenoma^a^
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 0/50
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 0/50
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 3/50 (6.6%)
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 7/50** (15.5%)
NTP (2009) Animal: Rat F344/N F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Trend p value: <0.001
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Harderian gland – Adenoma^a^ | | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 5/50 (11.1%) | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 9/50 (20%) | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 9/50 (20.7%) | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 M 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 8/50 (18.5%) | Survival: 38/50–35/50, 30/50, 21/50 Body weight: 1,000 mg/l group was 12% lower than controls after 97 weeks. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Harderian gland – Adenoma^a^ | | Survival: 36/50–42/50, 32/50, 40/50 Body weight: No significant difference. Significantly increased preneoplastic lesions: Harderian gland focal hyperplasia was also significantly increased in the 250 mg/l group. Other comments: The significance was possibly found because of the low incidence of the untreated controls, which were at the bottom end of the historical control range. Strengths and limitations: A very high-quality study, with no major concerns.
NTP (2009) Animal: Mouse B6C3F1 F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 1/50 (2.2%)
NTP (2009) Animal: Mouse B6C3F1 F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 7/50* (14.5%)
NTP (2009) Animal: Mouse B6C3F1 F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 1/50 (2.2%)
NTP (2009) Animal: Mouse B6C3F1 F 6–7 weeks Study duration: 105 weeks | Agent: Bromochloroacetic acid 96% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 7/50* (14.7%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Whole body – Malignant mesothelioma^a^ | | Survival: No effect on survival. 19/50–21/50, 25/50, 19/50 Body weight: Significant decrease of body weight after 89 weeks with 1,000 mg/l, associated with a 10% in water consumption. Other comments: Large intestine includes cecum, colon, and rectum. Strengths and limitations: Well reported and designed study, with a large number of animals of both sexes exposed for near life-span at three exposure levels.
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 1/50 (3%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 12/50*** (28%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 18/50*** (41%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 37/50*** (78%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Trend p value: <0.001
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Mammary gland – Fibroadenoma^a^
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 0/50
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 2/50 (5%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 3/50 (7%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 1/50 (3%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Brain – Glioma or oligodendroglioma (original evaluation and extended evaluations)^a^
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 1/50 (3%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 1/50 (3%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 4/50 (10%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 3/50 (8%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Skin – Fibroma^a^
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 4/50 (10%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 6/50 (15%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 10/50 (23%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 15/50** (36%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Trend p value: <0.001
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Skin – Keratoacanthoma^a^
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 7/50 (17%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 3/50 (8%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 10/50 (23%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 15/50* (37%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Trend p value: =0.003
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Skin – Squamous cell papilloma^a^
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 3/50 (8%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 1/50 (3%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 0/50
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 1/50 (3%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Skin – Basal cell adenoma^a^
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 0/50
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 0/50
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 4/50 (9%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 4/50 (10%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Trend p value: =0.012
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Skin – Squamous cell papilloma, keratoacanthoma, sebaceous gland adenoma, basal cell adenoma, basal cell carcinoma, or squamous cell carcinoma^a^
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 9/50 (22%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 7/50 (17%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 15/50 (34%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 21/50** (50%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Trend p value: <0.001
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Large intestine – Adenoma
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 0/50
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 0/50
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 2/50 (4%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 2/50 (4%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Oral cavity – Squamous cell papilloma or squamous cell carcinoma^a^
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 1/50 (3%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 0/50
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 3/50 (7%)
NTP (2015) Animal: Rat F344/NTac M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 3/50 (8%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | Brain – Glioma or oligodendroglioma (original evaluation and extended evaluations)^a^ | | Survival: Survival significantly decrease for the 500 and 1,000 mg/l groups and there was a significant negative trend of survival with exposure level. 34/50–26/50, 7/50***, 2/50*** Body weight: Significant body weight loss compared to controls (10% lower than control) from 1,000 mg/l after 13 weeks and (20% lower than control) after 52 weeks. Water consumption was decreased during the first year but was similar to controls during the second year. Body weight loss was not related to decreased water consumption. Other comments: Large intestine includes the colon and rectum. The cecum was not reported, suggesting an incidence of zero. Strengths and limitations: Well reported and designed study, with a large number of animals of both sexes exposed for near life-span at three exposure levels.
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 0 | 1/50 (2.2%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 250 | 0/50
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 500 | 3/50 (9%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 1000 | 1/50 (3.5%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | Mammary gland – Fibroadenoma^a^
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 0 | 28/50 (60.1%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 250 | 47/50*** (96.6%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 500 | 47/50*** (99.1%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 1000 | 39/50*** (89.6%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | Trend p value: <0.001
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | Mammary gland – Adenoma
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 0 | 1/50 (2%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 250 | 2/50 (4%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 500 | 3/50 (6%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 1000 | 1/50 (2%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | Mammary gland – Carcinoma^a^
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 0 | 0/50
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 250 | 1/50 (2.3%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 500 | 3/50 (9.1%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 1000 | 8/50*** (25.8%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | Trend p value: <0.001
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | Mammary gland – Adenoma or carcinoma
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 0 | 1/50 (2%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 250 | 3/50 (6%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 500 | 6/50* (12%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 1000 | 9/50** (18%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | Mammary gland – Adenoma, carcinoma, or fibroadenoma^a^
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 0 | 28/50 (60.1%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 250 | 47/50*** (96.6%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 500 | 48/50*** (99.4%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 1000 | 42/50*** (92.5%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | Trend p value: <0.001
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | Skin – Fibromaᵃ
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 0 | 2/50 (4.4%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 250 | 0/50
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 500 | 3/50 (8.9%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 1000 | 2/50 (6.9%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | Skin – Basal cell adenoma
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 0 | 0/50
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 250 | 0/50
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 500 | 0/50
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 1000 | 1/50 (2%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | Large intestine – Adenoma^a^
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 0 | 1/50 (2.2%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 250 | 0/50
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 500 | 1/50 (3.1%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 1000 | 2/50 (7%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | Oral cavity – Squamous cell papilloma or squamous cell carcinoma^a^
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 0 | 0/50
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 250 | 2/50 (4.6%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 500 | 1/50 (3.1%)
NTP (2015) Animal: Rat F344/NTac F 5–6 wk Study duration: up to 104 wk | Agent: Bromodichloroacetic acid >97% Treatment: Drinking water 0 250 500 1000 mg/L of drinking water ad libitum × 104 weeks | 1000 | 2/50 (6.9%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Harderian gland – Adenoma^a^ | | Survival: Significant decrease in survival. Body weight: Significant decreased in body weight after 57 weeks at 1,000 mg/l and after 73 weeks at 500 mg/lL Strengths and limitations: Well reported and designed study, with a large number of animals of both sexes exposed for near life-span at three exposure levels.
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 6/50 (15%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 11/50 (26%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 14/49* (38%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 19/51*** (49%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Trend p value: <0.001
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Harderian gland – Carcinoma^a^
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 0/50
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 0/50
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 0/49
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 3/51 (9%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Trend p value: =0.008
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Harderian gland – Adenoma or carcinoma ^a^
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 6/50 (15%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 11/50 (26%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 14/49* (38%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 20/51*** (51%)
NTP (2015) Animal: Mouse B6C3F1/N M 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Trend p value: <0.001
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | Harderian gland – Adenoma or carcinoma ^a^ | | Survival: No significant change in survival. Body weight: Significant decrease in body weight after 73 weeks at 1,000 mg/l and after 89 weeks at 250 mg/L. Strengths and limitations: Well reported and designed study, with a large number of animals of both sexes exposed for near life-span at three exposure levels.
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 0 | 5/50 (12%)
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 250 | 4/50 (9%)
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 500 | 7/50 (16%)
NTP (2015) Animal: Mouse B6C3F1/N F 5–6 wk Study duration: 105 wk | Agent: Bromodichloroacetic acid 97% Treatment: Drinking water 0 250 500 1,000 mg/L of drinking water ad libitum × 105 weeks | 1,000 | 6/50 (14%)

* < 0.05, ** < 0.01, *** < 0.001 p value.

^a^ Adjusted percent incidence based on Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^b^ Exceeds historical controls from drinking water studies: 15/250 (range 0%–12%); exceeds historical controls from studies of all routes: 57/1,459 (range 0%–12%).

^c^ Exceeds historical controls from drinking water studies: 79/250 (range 26%–34%); exceeds historical controls from studies of all routes: 622/1,459 (range 22–68%).

^d^ Exceeds historical controls from drinking water studies: 47/200 (range 20%–30%); exceeds historical controls from studies of all routes: 383/1,459 (range 12–52%).

^e^ Exceeds historical controls from drinking water studies: 8/200 (range 2%–6%).

^f^ Exceeds historical controls from drinking water studies: 26/199 (range 6%–20%); exceeds historical controls from studies of all routes: 258/1,507 (range 4–28%).

^g^ Exceeds historical controls from drinking water studies: 26/199 (range 6%–20%).

^h^ Exceeds historical controls from drinking water studies: 16/199 (range 6%–10%).

^i^ Exceeds historical controls from drinking water studies: 41/199 (range 12%–26%).

^j^ Exceeds historical controls from drinking water studies: 41/199 (range 12%–26%); exceeds historical controls from studies of all routes: 385/1,507 (range 12–44%).

^k^ Exceeds historical controls from drinking water studies: 13/250 (range 2%–12%); exceeds historical controls from studies of all routes: 80/1,552 (range 0%–12%).

^l^ Exceeds historical controls from drinking water studies: 16/250 (range 2%–12%); exceeds historical controls from studies of all routes: 117/1,552 (range 0%–14%).

Table C-58 Transgenic Studies

Reference and Study Design | Exposure | Dose Levels | Tumor Incidence (n/N) (%) | Comments
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) M 6 weeks Study duration: 39 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Dermal 0 31.25 125 500 mg/kg bw in Water:Acetone (1:2) (pH 6–8) 5 doses/week × 39 weeks | Skin – Squamous cell papilloma | | Survival: Survival was similar to untreated controls: 9/10– 6/10, 8/10, 7/10 Body weight: Body weights were significantly lower in 31.25 mg/kg group after 22 weeks, 500 mg/kg after 21 weeks, and 125 mg/kg temporarily was lower from weeks 28 to 38 but were the same as controls by the end of the study. Significantly increased preneoplastic lesions: The incidence of pre-neoplasia of the skin (epidermis hyperplasia) was significantly increased at 125 and 500 mg/kg. Other comments: Only reporting neoplasms at the site of application. Strengths and limitations: The study was well conducted except for a low number of transgenic animals per group, which may overestimate carcinogenic potential. The ability to translate hazards in this model to non-transgenic mice is limited.
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) M 6 weeks Study duration: 39 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Dermal 0 31.25 125 500 mg/kg bw in Water:Acetone (1:2) (pH 6–8) 5 doses/week × 39 weeks | 0 | 0/10
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) M 6 weeks Study duration: 39 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Dermal 0 31.25 125 500 mg/kg bw in Water:Acetone (1:2) (pH 6–8) 5 doses/week × 39 weeks | 31.25 | 0/10
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) M 6 weeks Study duration: 39 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Dermal 0 31.25 125 500 mg/kg bw in Water:Acetone (1:2) (pH 6–8) 5 doses/week × 39 weeks | 125 | 2/10 (20%)
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) M 6 weeks Study duration: 39 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Dermal 0 31.25 125 500 mg/kg bw in Water:Acetone (1:2) (pH 6–8) 5 doses/week × 39 weeks | 500 | 8/10** (80%)
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) F 6 weeks Study duration: 39 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Dermal 0 31.25 125 500 mg/kg bw in Water:Acetone (1:2) (pH 6–8) 5 doses/week × 39 weeks | Skin – Squamous cell papilloma | | Survival: Survival was similar to untreated controls: 8/10– 5/10, 6/10, 8/10 Body weight: Body weights of 31.25 and 125 mg/kg groups were greater than controls at the end of the study, and 500 mg/kg were greater after 17 weeks. Significantly increased preneoplastic lesions: The incidence of pre-neoplasia of the skin (epidermis hyperplasia) was significantly increased at 500 mg/kg. Other comments: Only reporting neoplasms at the site of application. Strengths and limitations: The study was well conducted except for a low number of transgenic animals per group, which may overestimate carcinogenic potential. The ability to translate hazards in this model to non-transgenic mice is limited.
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) F 6 weeks Study duration: 39 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Dermal 0 31.25 125 500 mg/kg bw in Water:Acetone (1:2) (pH 6–8) 5 doses/week × 39 weeks | 0 | 0/10
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) F 6 weeks Study duration: 39 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Dermal 0 31.25 125 500 mg/kg bw in Water:Acetone (1:2) (pH 6–8) 5 doses/week × 39 weeks | 31.25 | 0/10
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) F 6 weeks Study duration: 39 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Dermal 0 31.25 125 500 mg/kg bw in Water:Acetone (1:2) (pH 6–8) 5 doses/week × 39 weeks | 125 | 0/10
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) F 6 weeks Study duration: 39 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Dermal 0 31.25 125 500 mg/kg bw in Water:Acetone (1:2) (pH 6–8) 5 doses/week × 39 weeks | 500 | 6/10** (60%)
NTP (2007b) Animal: Mouse (Study 2) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) M 6 weeks Study duration: 26 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Dermal 0 31.25 125 500 mg/kg bw in Water:Acetone (1:2) (pH 6–8) 5 doses/week × 26 weeks | Skin – Squamous cell papilloma | | Survival: Survival was similar to untreated controls: 13/15–14/15, 14/15, 12/15 Body weight: Body weights were similar to untreated controls. Significantly increased preneoplastic lesions: The incidence of pre-neoplasia of the skin (epidermis hyperplasia) was significantly increased at 125 and 500 mg/kg. The severity grades of the hyperplasia in all cases were minimal. Other comments: Only reporting neoplasms at the site of application. Strengths and limitations: The study was well conducted except for a low number of transgenic animals per group, which may overestimate carcinogenic potential. The ability to translate hazards in this model to non-transgenic mice is limited.
NTP (2007b) Animal: Mouse (Study 2) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) M 6 weeks Study duration: 26 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Dermal 0 31.25 125 500 mg/kg bw in Water:Acetone (1:2) (pH 6–8) 5 doses/week × 26 weeks | 0 | 0/15
NTP (2007b) Animal: Mouse (Study 2) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) M 6 weeks Study duration: 26 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Dermal 0 31.25 125 500 mg/kg bw in Water:Acetone (1:2) (pH 6–8) 5 doses/week × 26 weeks | 31.25 | 0/15
NTP (2007b) Animal: Mouse (Study 2) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) M 6 weeks Study duration: 26 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Dermal 0 31.25 125 500 mg/kg bw in Water:Acetone (1:2) (pH 6–8) 5 doses/week × 26 weeks | 125 | 1/15 (7%)
NTP (2007b) Animal: Mouse (Study 2) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) M 6 weeks Study duration: 26 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Dermal 0 31.25 125 500 mg/kg bw in Water:Acetone (1:2) (pH 6–8) 5 doses/week × 26 weeks | 500 | 2/15 (13%)
NTP (2007b) Animal: Mouse (Study 2) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) F 6 weeks Study duration: 26 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Dermal 0 31.25 125 500 mg/kg bw in Water:Acetone (1:2) (pH 6–8) 5 doses/week × 26 weeks | Skin – Squamous cell papilloma | | Survival: Survival was similar to untreated controls: 11/15–12/15, 14/15, 15/15 Body weight: Body weights were similar to untreated controls. Significantly increased preneoplastic lesions: The incidence of pre-neoplasia of the skin (epidermis hyperplasia) was significantly increased at 125 and 500 mg/kg. The severity grades of the hyperplasia in all cases were minimal. Other comments: Only reporting neoplasms at the site of application. Strengths and limitations: The study was well conducted except for a low number of transgenic animals per group, which may overestimate carcinogenic potential. The ability to translate hazards in this model to non-transgenic mice is limited.
NTP (2007b) Animal: Mouse (Study 2) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) F 6 weeks Study duration: 26 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Dermal 0 31.25 125 500 mg/kg bw in Water:Acetone (1:2) (pH 6–8) 5 doses/week × 26 weeks | 0 | 0/15
NTP (2007b) Animal: Mouse (Study 2) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) F 6 weeks Study duration: 26 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Dermal 0 31.25 125 500 mg/kg bw in Water:Acetone (1:2) (pH 6–8) 5 doses/week × 26 weeks | 31.25 | 0/15
NTP (2007b) Animal: Mouse (Study 2) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) F 6 weeks Study duration: 26 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Dermal 0 31.25 125 500 mg/kg bw in Water:Acetone (1:2) (pH 6–8) 5 doses/week × 26 weeks | 125 | 0/15
NTP (2007b) Animal: Mouse (Study 2) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) F 6 weeks Study duration: 26 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Dermal 0 31.25 125 500 mg/kg bw in Water:Acetone (1:2) (pH 6–8) 5 doses/week × 26 weeks | 500 | 2/15 (13%)
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) M 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | Lung – Adenoma | | Survival: Survival was similar to untreated controls: 9/1 9/10, 10/10, 10/10 Body weight: Body weights were significantly greater than untreated controls at 500 mg/l after 17 weeks and 1,000 mg/l after 21 weeks. Other comments: Water consumption at 2,000 mg/l was less than controls. Strengths and limitations: The study was well conducted except for a low number of transgenic animals per group, which may overestimate carcinogenic potential. The ability to translate hazards in this model to non-transgenic mice is limited.
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) M 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 0 | 1/10 (10%)
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) M 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 500 | 2/10 (20%)
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) M 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 1,000 | 7/10** (70%)
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) M 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 2,000 | 3/10 (30%)
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) M 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | Forestomach – Squamous cell papilloma
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) M 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 0 | 5/10 (50%)
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) M 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 500 | 9/10 (90%)
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) M 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 1,000 | 6/10 (60%)
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) M 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 2,000 | 7/10 (70%)
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) F 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | Lung – Adenoma | | Survival: Survival was similar to untreated controls: 7/10– 9/10, 7/10, 8/10 Body weight: Body weights of 1,000 and 2,000 mg/l were significantly lower than untreated controls after 15 and 15 weeks, respectively. Other comments: Water consumption at 2,000 mg/l was less than controls. Strengths and limitations: The study was well conducted except for a low number of transgenic animals per group, which may overestimate carcinogenic potential. The ability to translate hazards in this model to non-transgenic mice is limited.
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) F 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 0 | 0/10
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) F 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 500 | 0/10
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) F 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 1,000 | 0/10
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) F 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 2,000 | 2/10 (20%)
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) F 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | Forestomach – Squamous cell papilloma
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) F 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 0 | 6/10 (60%)
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) F 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 500 | 7/10 (70%)
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) F 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 1,000 | 7/10 (70%)
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) F 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 2,000 | 6/10 (60%)
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) F 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | Forestomach – Squamous cell papilloma (multiple only)
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) F 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 0 | 1/10 (10%)
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) F 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 500 | 6/10* (60%)
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) F 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 1,000 | 4/10 (40%)
NTP (2007b) Animal: Mouse (Study 1) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) F 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 2,000 | 4/10 (40%)
NTP (2007b) Animal: Mouse (Study 2) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) M 6 weeks Study duration: 26 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | Lung – Carcinoma | | Survival: Survival was similar to untreated controls: 14/15–13/15, 11/15, 14/15 Body weight: Body weights were significantly greater than untreated controls at 500 mg/l after 17 weeks and 1,000 mg/l after 21 weeks. Other comments: Water consumption at 2,000 mg/l was less than controls. Strengths and limitations: The study was well conducted except for a low number of transgenic animals per group, which may overestimate carcinogenic potential. The ability to translate hazards in this model to non-transgenic mice is limited.
NTP (2007b) Animal: Mouse (Study 2) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) M 6 weeks Study duration: 26 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 0 | 0/15
NTP (2007b) Animal: Mouse (Study 2) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) M 6 weeks Study duration: 26 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 500 | 0/15
NTP (2007b) Animal: Mouse (Study 2) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) M 6 weeks Study duration: 26 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 1,000 | 1/15 (7%)
NTP (2007b) Animal: Mouse (Study 2) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) M 6 weeks Study duration: 26 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 2,000 | 0/15
NTP (2007b) Animal: Mouse (Study 2) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) F 6 weeks Study duration: 26 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | Lung – Carcinoma | | Survival: Survival was significantly lower than untreated controls at 500 and 2,000 mg/l: 15/15–8/15*(=0.009), 13/15, 10/15*(=0.05) Body weight: Body weights of 1,000 and 2,000 mg/l were significantly lower than untreated controls after 15 and 15 weeks, respectively. Other comments: Water consumption at 2,000 mg/l was less than controls. Strengths and limitations: The study was well conducted except for a low number of transgenic animals per group, which may overestimate carcinogenic potential. The ability to translate hazards in this model to non-transgenic mice is limited.
NTP (2007b) Animal: Mouse (Study 2) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) F 6 weeks Study duration: 26 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 0 | 0/15
NTP (2007b) Animal: Mouse (Study 2) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) F 6 weeks Study duration: 26 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 500 | 1/15 (7%)
NTP (2007b) Animal: Mouse (Study 2) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) F 6 weeks Study duration: 26 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 1,000 | 0/15
NTP (2007b) Animal: Mouse (Study 2) FVB Tg.AC hemizygous (FVB/N-TgN(v-Ha-ras)Led) F 6 weeks Study duration: 26 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 2,000 | 1/15 (7%)
NTP (2007b) Animal: Mouse (Study 3) p53 Haploinsufficient M 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | Lung – Adenoma or carcinoma | | Survival: Survival was similar to untreated controls: 9/10– 10/10, 9/10, 10/10 Body weight: Body weights of 500, 1,000, and 2,000 mg/l were significantly lower than untreated controls after 4, 3, and 1 weeks, respectively. Other comments: Water consumption at 1,000 and 2,000 mg/l were less than controls. Strengths and limitations: The study was well conducted except for a low number of transgenic animals per group, which may overestimate carcinogenic potential. The ability to translate hazards in this model to non-transgenic mice is limited.
NTP (2007b) Animal: Mouse (Study 3) p53 Haploinsufficient M 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 0 | 0/10
NTP (2007b) Animal: Mouse (Study 3) p53 Haploinsufficient M 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 500 | 0/10
NTP (2007b) Animal: Mouse (Study 3) p53 Haploinsufficient M 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 1,000 | 0/10
NTP (2007b) Animal: Mouse (Study 3) p53 Haploinsufficient M 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 2,000 | 0/10
NTP (2007b) Animal: Mouse (Study 3) p53 Haploinsufficient F 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | Lung – Adenoma or carcinoma | | Survival: Survival was similar to untreated controls: 10/10–9/10, 10/10, 9/10 Body weight: Body weights of 500, 1,000 and 2,000 mg/l were significantly lower than untreated controls after 27, 9, and 9 weeks, respectively. Other comments: Water consumption at 1,000 and 2,000 mg/l were less than controls. Strengths and limitations: The study was well conducted except for a low number of transgenic animals per group, which may overestimate carcinogenic potential. The ability to translate hazards in this model to non-transgenic mice is limited.
NTP (2007b) Animal: Mouse (Study 3) p53 Haploinsufficient F 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 0 | 0/10
NTP (2007b) Animal: Mouse (Study 3) p53 Haploinsufficient F 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 500 | 0/10
NTP (2007b) Animal: Mouse (Study 3) p53 Haploinsufficient F 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 1,000 | 0/10
NTP (2007b) Animal: Mouse (Study 3) p53 Haploinsufficient F 6 weeks Study duration: 41 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 2,000 | 0/10
NTP (2007b) Animal: Mouse (Study 4) p53 Haploinsufficient M 6 weeks Study duration: 26 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | Lung – Adenoma or carcinoma | | Survival: Survival was similar to untreated controls: 15/15– 15/15, 15/15, 15/15 Body weight: Body weights of 1,000 and 2,000 mg/l were significantly lower than untreated controls after 4 and 2 weeks, respectively. Other comments: Water consumption at 1,000 and 2,000 mg/l were less than controls. Strengths and limitations: The study was well conducted except for a low number of transgenic animals per group, which may overestimate carcinogenic potential. The ability to translate hazards in this model to non-transgenic mice is limited.
NTP (2007b) Animal: Mouse (Study 4) p53 Haploinsufficient M 6 weeks Study duration: 26 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 0 | 0/15
NTP (2007b) Animal: Mouse (Study 4) p53 Haploinsufficient M 6 weeks Study duration: 26 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 500 | 0/15
NTP (2007b) Animal: Mouse (Study 4) p53 Haploinsufficient M 6 weeks Study duration: 26 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 1,000 | 0/15
NTP (2007b) Animal: Mouse (Study 4) p53 Haploinsufficient M 6 weeks Study duration: 26 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 2,000 | 0/15
NTP (2007b) Animal: Mouse (Study 4) p53 Haploinsufficient F 6 weeks Study duration: 26 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | Lung – Adenoma or carcinoma | | Survival: Survival was similar to untreated controls: 15/15– 15/15, 14/15, 14/15 Body weight: Body weights of 1,000 and 2,000 mg/l were significantly lower than untreated controls after 11 and 10 weeks, respectively. Other comments: Water consumption at 1,000 and 2,000 mg/l were less than controls. Strengths and limitations: The study was well conducted except for a low number of transgenic animals per group, which may overestimate carcinogenic potential. The ability to translate hazards in this model to non-transgenic mice is limited.
NTP (2007b) Animal: Mouse (Study 4) p53 Haploinsufficient F 6 weeks Study duration: 26 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 0 | 0/15
NTP (2007b) Animal: Mouse (Study 4) p53 Haploinsufficient F 6 weeks Study duration: 26 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 500 | 0/15
NTP (2007b) Animal: Mouse (Study 4) p53 Haploinsufficient F 6 weeks Study duration: 26 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 1,000 | 0/15
NTP (2007b) Animal: Mouse (Study 4) p53 Haploinsufficient F 6 weeks Study duration: 26 weeks | Agent: Dichloroacetic acid 98.5%–99% Treatment: Drinking water 0 500 1,000 2,000 mg/L in drinking water ad libitum × 26 weeks | 2,000 | 0/15

* p < 0.05; ** p < 0.01.

Table C-59 Initiation-Promotion Studies

Reference and Study Design | Exposure | Dose Levels | Tumor Incidence (n/N) (%) | Comments
Gwynn and Salaman (1953) Animal: Mouse Stock albino “S” strain NR NR Study duration: 30 weeks | Agent: Monoiodoacetic acid Not reported Treatment: Dermal Initiator: 9,10-dimethyl-1,2-benzanthracene (DMBA) in acetone: single dose 0.15% in 3 ml Promotor: Iodoacetic acid in acetone: start 21 days after DMBA 1.4% (2/wk × 12wk, then 1/wk × 15wk) | Skin – Papilloma | | Survival: Only two of the exposed mice died. Body weight: Not reported. Strengths and limitations: The chemicals were not characterized and purity was not reported. The sex of the animals were not reported and only a single dose level was tested on a very low number of animals per group. Histology of the neoplasms were carried out, but the skin tumors were classified as benign papillomas based on their appearance “macroscopically.” Statistical significance was not calculated.
Gwynn and Salaman (1953) Animal: Mouse Stock albino “S” strain NR NR Study duration: 30 weeks | | 0 (acetone) | 1/12 (8.3%)
Gwynn and Salaman (1953) Animal: Mouse Stock albino “S” strain NR NR Study duration: 30 weeks | | 0 (acetic acid) | 1/16 (6.25%)
Gwynn and Salaman (1953) Animal: Mouse Stock albino “S” strain NR NR Study duration: 30 weeks | | 1.4 | 8/10[^@@^][^##^] (80%)
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 4 weeks Study duration: 61 weeks | Agent: Dichloroacetic acid >99% Treatment: Drinking water Initiator: Ethylnitrosourea (ENU): ip injection at 15 days old 0+ 2.5 μg/g bw Promotor: DCA: in drinking water at 4 weeks old 0++ 2,000 5,000 mg/L in drinking water (pH 6.5–7.5) × 61 weeks + 2 μg/g bw of 0.1 M sodium acetate ++ 2,000 mg/l of sodium chloride | Liver – Adenoma | | Survival: Not reported. Body weight: Body weights were significantly decreased (p < 0.001). Calculations were done by one-way analysis of variance with a Tukey's comparison. Strengths and limitations: The duration was less than near life-span. Only males were tested at two narrow dose levels and only livers were histologically evaluated.
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 4 weeks Study duration: 61 weeks | | 0/0 | 2/22 (9%)
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 4 weeks Study duration: 61 weeks | | 0/5,000 | 25/26** (96%)
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 4 weeks Study duration: 61 weeks | | 2.5/0 | 1/22 (5%)
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 4 weeks Study duration: 61 weeks | | 2.5/2,000 | 22/29** (76%)
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 4 weeks Study duration: 61 weeks | | 2.5/5,000 | 31/32** (97%)
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 4 weeks Study duration: 61 weeks | | Liver – Carcinoma
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 4 weeks Study duration: 61 weeks | | 0/0 | 0/22
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 4 weeks Study duration: 61 weeks | | 0/5,000 | 21/26** (81%)
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 4 weeks Study duration: 61 weeks | | 2.5/0 | 1/22 (5%)
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 4 weeks Study duration: 61 weeks | | 2.5/2,000 | 19/29** (66%)
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 4 weeks Study duration: 61 weeks | | 2.5/5,000 | 25/32** (72%)
Pereira et al. (1997) Animal: Mouse B6C3F1 F Initiator: 15 d; Promotor: 6 wks Study duration: 50 weeks | Agent: Dichloroacetic acid NR Treatment: Drinking water Initiator: Methylnitrosourea (MNU): single ip dose 25 mg/kg bw in sterile saline Promotor: DCA: in drinking water, ad libitum × 44 weeks, starting 4 weeks after MNU 0 25.0 15.6 7.8 mmol/L in filtered and deionized water, pH 6.5-7.5 | Liver – Adenoma | | Survival: No significant difference in survival: 29/30, 19/20, 17/20, 29/30 (# of mice at scarified/# of mice as the start of promotion). Body weight: There was a decrease in body weight of less than 10% of the control weight in the groups receiving TCA and top two highest levels of DCA. Significantly increased preneoplastic lesions: The liver foci of altered hepatocytes were distinguished from adenomas by compression at less than 80% of its boarder. This suggests that it was considered preneoplastic. The multiplicity of these preneoplastic lesions was significantly increased at 25 mmol/L of DCA. Strengths and limitations: The chemicals were not characterized, not even purity was reported. Disease surveillance was not reported. A low number of only females were tested, with only their livers examined histologically. The statistical methods were not reported.
Pereira et al. (1997) Animal: Mouse B6C3F1 F Initiator: 15 d; Promotor: 6 wks Study duration: 50 weeks | | 0 DCA/TCA | None
Pereira et al. (1997) Animal: Mouse B6C3F1 F Initiator: 15 d; Promotor: 6 wks Study duration: 50 weeks | | 7.8 DCA | None
Pereira et al. (1997) Animal: Mouse B6C3F1 F Initiator: 15 d; Promotor: 6 wks Study duration: 50 weeks | | 15.6 DCA | None
Pereira et al. (1997) Animal: Mouse B6C3F1 F Initiator: 15 d; Promotor: 6 wks Study duration: 50 weeks | | 25 DCA | None
Pereira et al. (1997) Animal: Mouse B6C3F1 F Initiator: 15 d; Promotor: 6 wks Study duration: 50 weeks | | Liver – Carcinoma
Pereira et al. (1997) Animal: Mouse B6C3F1 F Initiator: 15 d; Promotor: 6 wks Study duration: 50 weeks | | 0 DCA/TCA | 0/29
Pereira et al. (1997) Animal: Mouse B6C3F1 F Initiator: 15 d; Promotor: 6 wks Study duration: 50 weeks | | 7.8 DCA | 0/17
Pereira et al. (1997) Animal: Mouse B6C3F1 F Initiator: 15 d; Promotor: 6 wks Study duration: 50 weeks | | 15.6 DCA | 0/19
Pereira et al. (1997) Animal: Mouse B6C3F1 F Initiator: 15 d; Promotor: 6 wks Study duration: 50 weeks | | 25 DCA | 3/29 (10.3%)
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 15 days Study duration: 61 weeks | Agent: Trichloroacetic acid >99% Treatment: Drinking water Initiator: Ethylnitrosourea (ENU): ip injection at 15 days old 0+ 2.5 10 μg/g bw Promotor: TCA: in drinking water (pH 6.5–7.5) at 4 weeks old 0++ 2,000 5,000 mg/L in drinking water (pH 6.5–7.5) × 61 weeks + 2 μg/g bw of 0.1 M sodium acetate ++ 2,000 mg/L NaCl | Liver – Adenoma | | Survival: Not reported. Body weight: Body weights were significantly decreased (p < 0.001). Calculations were done by one-way analysis of variance with a Tukey's comparison. Strengths and limitations: The duration was less than near life-span. Only males were tested at two narrow dose levels and only livers were histologically evaluated.
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 15 days Study duration: 61 weeks | | 0/0 | 2/22 (9%)
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 15 days Study duration: 61 weeks | | 0/5,000 | 8/22** (36%)
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 15 days Study duration: 61 weeks | | 2.5/0 | 1/22 (5%)
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 15 days Study duration: 61 weeks | | 2.5/2,000 | 11/33** (33%)
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 15 days Study duration: 61 weeks | | 2.5/5,000 | 6/23** (26%)
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 15 days Study duration: 61 weeks | | 10/0 | 9/23 (39%)
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 15 days Study duration: 61 weeks | | 10/5,000 | 11/28 (39%)
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 15 days Study duration: 61 weeks | | Liver – Carcinoma
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 15 days Study duration: 61 weeks | | 0/0 | 0/22
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 15 days Study duration: 61 weeks | | 0/5,000 | 7/22** (32%)
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 15 days Study duration: 61 weeks | | 2.5/0 | 1/22 (5%)
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 15 days Study duration: 61 weeks | | 2.5/2,000 | 16/33** (48%)
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 15 days Study duration: 61 weeks | | 2.5/5,000 | 11/23** (48%)
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 15 days Study duration: 61 weeks | | 10/0 | 9/23 (39%)
Herren-Freund et al. (1987) Animal: Mouse B6C3F1 M 15 days Study duration: 61 weeks | | 10/5,000 | 15/28 (54%)
Pereira et al. (1997) Animal: Mouse B6C3F1 F Initiator: 15 d; Promotor: 6 wks Study duration: 50 weeks | Agent: Trichloroacetic acid Vendor, but not purity given Treatment: Drinking water Initiator: Methylnitrosourea (MNU): single ip dose in sterile saline 25 mg/kg Promotor: TCA: in drinking water ad libitum × 44 weeks, starting 4 wk after MNU 0 25.0 6.0 mmol/L in filtered and deionized water, pH 6.5–7.5 | Liver – Adenoma | | Survival: No significant difference in survival: 29/30, 20/20, 29/30 (# of mice at scarified/# of mice as the start of promotion). Body weight: There was a decrease in body weight of less than 10% of the control weight in the groups receiving TCA and top two highest levels of DCA. Significantly increased preneoplastic lesions: The liver foci of altered hepatocytes were distinguished from adenomas by compression at less than 80% of its boarder. This suggests that it was considered preneoplastic. The multiplicity of these preneoplastic lesions was not significantly increased over controls. Strengths and limitations: The chemicals were not characterized, not even purity was reported. Disease surveillance was not reported. A low number of only females were tested, with only their livers examined histologically. The statistical methods were not reported.
Pereira et al. (1997) Animal: Mouse B6C3F1 F Initiator: 15 d; Promotor: 6 wks Study duration: 50 weeks | | 0 DCA/TCA | None
Pereira et al. (1997) Animal: Mouse B6C3F1 F Initiator: 15 d; Promotor: 6 wks Study duration: 50 weeks | | 6 TCA | None
Pereira et al. (1997) Animal: Mouse B6C3F1 F Initiator: 15 d; Promotor: 6 wks Study duration: 50 weeks | | 25 TCA | None
Pereira et al. (1997) Animal: Mouse B6C3F1 F Initiator: 15 d; Promotor: 6 wks Study duration: 50 weeks | | Liver – Carcinoma
Pereira et al. (1997) Animal: Mouse B6C3F1 F Initiator: 15 d; Promotor: 6 wks Study duration: 50 weeks | | 0 DCA/TCA | 0/29
Pereira et al. (1997) Animal: Mouse B6C3F1 F Initiator: 15 d; Promotor: 6 wks Study duration: 50 weeks | | 6 TCA | 0/20
Pereira et al. (1997) Animal: Mouse B6C3F1 F Initiator: 15 d; Promotor: 6 wks Study duration: 50 weeks | | 25 TCA | 4/29 (13.8%)

** < 0.01 (compared to the control group without a promotor), ^@@^ <0.01 (compared to acetone), ^##^ < 0.001 (compared to acetic acid) p value.

[ ] = p value calculated by NTP using Fisher’s Exact Test.