# Appendix B Disposition and Toxicokinetics

Table B-1 Pharmaco- or Toxicokinetic Parameters of Haloacetic Acids in Humans

HAA | Dose, mg/kg (Route) | Vd (mL/kg) | AUC (mg/L•h) | Plasma T½ (h) | Clearance (mL/min•kg) | Comments | Reference
DCA | 10 (i.v.) 20 (i.v.) | 337 190 | 14.9 76.7 | 0.34 0.51 | 11.31 4.55 | Two adults/dose (sex not specified). Data are mean values for two subjects. | Lukas et al. (1980)
DCA | 10 × 5 (i.v.) 25 × 5 (i.v.) 50 × 5 (i.v.) | 260 270 340 290 330 | increased with dose | 1.06 1.84 3.14 3.50 6.23 | 1393.8 mg/kg/h 1089.1 mg/kg/h 881.7 mg/kg/h 950.2 mg/kg/h 723.8 mg/kg/h | 7 men + 4 women, 5 doses administered at 2-h intervals; 3 subjects at low dose, 5 subjects at mid dose (including one from low dose group) and 4 subjects at high dose. Vd, T½ and elimination rate constants shown after each dose interval; however, the dose was not specified. | Curry et al. (1985)
DCA | 50 (i.v.) + 50 × 2 (oral) | 19.9 L | 609 | 2.65 | 102.1 mL/min | 8 men + 4 women; one i.v. and 2 oral doses given 4 days apart (randomized) | Curry et al. (1991)
DCA | 46 (i.v.) | [750] | 261 | 2.3 | [5.33] | 13 adults (sex not specified) with severe malaria) | Krishna et al. (1994)
DCA | 50 (i.v.) | 323 | 378 | 1.8 | 2.68 | 4 boys + 4 girls with lactic acidosis from malaria | Krishna et al. (1995)
DCA | 46 (i.v.) 46 × 2 (i.v.) | 440 | NR | 3.4 4.4 | [2.17] | 8 men + 3 women with severe malaria given one dose and 9 subjects given a 2nd dose 12 h after 1^st^. Vd and Cl data after 2nd dose were reported as similar to those after the 1^st^ dose. | Krishna et al. (1996)
DCA | 40 × 2 (i.v.) | 618 618 | NR | [7.58] [4.65] | 1.0 (paleohepatic) 1.7 (neohepatic) | 33 adults (sex not specified) with end-stage liver disease and liver transplant. 2nd dose 4 h after 1^st^ dose; 2-compartment model. No clearance occurred during the anhepatic phase. | Shangraw and Fisher (1996)
DCA | 35 (i.v.) controls cirrhosis | 413 413 | NR | [ 3.35] [6.78] | 2.14 0.78 | 5 men + 1 women (controls) 5 men + 2 women (cirrhosis) 2-compartment model | Shangraw and Fisher (1999)
DCA | 50 × 2 (i.v.) | 0.51 L^a^ 0.27 L^b^ 0.27 L^c^ | 1233^a^ 1863^b^ NR | 5.94^a^ 18.15^b^ 49.37^c^ | [1.02]^a^ [0.69]^b^ [0.33]^c^ | 66 men + 45 women with lactic acidosis. 2nd dose 2h after 1st . Pharmacokinetics in acidosis patients were complex and differed from those in healthy volunteers. Data for most patients fitted a 1- or 2-compartment model but a few fitted a 3-compartment model or none of these. Plasma drug clearance tended to decrease as the number of compartments required to fit the data increased. | Henderson et al. (1997)
DCA | (50 + 50) × 2 (i.v.) | 0.29 L^a^ 0.28 L^b^ | 1954^a^ 4306^b^ | 8.77^a^ 68.63^b^ | [0.42]^a^ [0.28]^b^ | 15 of the 111 patients mentioned above (sex not specified) received a 2nd treatment. No significant differences compared to patients that received a single treatment but drug clearance tended to decrease with increase in number of drug treatments. | Henderson et al. (1997)
DCA | [underlined: Basal study] 2 (oral) + 0.3 (i.v.) men women [underlined: Chronic study] (0.02 × 14) (oral) + 2 (oral) + 0.3 (i.v) men women | 374 377 377 227 | 212, 755^d^ 243, 935^d^ 281, 1123^d^ 368, 1453^d^ | 0.15 0.16 0.16 0.17 | [29.2] [26.8] [22.0] [16.0] | 8 men + 8 women: For basal study all subjects consumed HAA-free bottled water for 14 days then given unlabeled DCA in 500 mL bottled water and 5 minutes later given i.v. ^13^C-labeled DCA; chronic study used same subjects and began 1 day after the 1^st^ study. Subjects subsequently ingested low concentrations of DCA in drinking water for 14 days and on day 15 repeated protocol of 1^st^ study. Only women were significantly affected by chronic DCA exposure compared to basal study with significantly increased AUC and reduced clearance and Vd. | Schultz and Shangraw (2006)
TCA | 3 (oral) | NR | NR | 50.6 | NR | 3 men administered a single oral dose of TCA | Müller et al. (1974)
TCA | 2.3−73 μg/day (drinking water) | NR | NR | 55.2−88.1 (2.3−3.7 d) | NR | 8 men + 2 women (elimination T½ data based on 3 subjects). Monitored TCA levels in tap water and urine during a 12-day study period. Dose range reflects mean intake over 12 days. | Froese et al. (2002)

Data in [brackets] indicate unit conversion of data reported in the study.

HAA = haloacetic acid, Vd = apparent volume of distribution, AUC = area under the concentration-time curve, DCA = dichloroacetic acid, TCA = trichloroacetic acid, NR = not reported.

^a^ One-compartment model.

^b^ Two-compartment model.

^c^ Three-compartment model.

^d^ AUC values provided for i.v. dose and oral dose, respectively.

Table B-2 Toxicokinetic Parameters of Haloacetic Acids in Rats

Haloacetic Acid | Dose/Route (μmol/kg) | AUC (μM•h) | Vd_ss_ (mL/kg) | Total Body Cl (mL/kg/h) | Renal Cl (mL/kg/h) | Nonrenal Cl (mL/kg/h) | T½ (h) | References
Trichloro- Single Single Single Mixture ^a^ GST-ζ-depleted^a^ | 500 i.v. [610] oral [120] oral 25 i.v. 25 i.v. | 5406 ± 144 10,000 ± 600 2530 ± 70 1561 ± 85 1289 ± 78 | 782 ± 117 485 365 287 ± 23 200 ± 10 | 93 ± 3.0 58 36 17.1 ± 1.4 19.7 ± 1.2 | 42.1 ± 9.9 NR NR NR NR | 50.4 ± 11 NR NR NR NR | 8.0 ± 2.4 5.8 7.0 12.03 ± 0.36 7.49 ± 0.15 | Schultz et al. (1999) Larson and Bull (1992) Saghir and Schultz (2005)
Bromodichloro- Single Single Single Mixture^a^ GST-ζ-depleted^a^ | 500 i.v. 100 i.v. 25 i.v. 25 i.v. 25 i.v. | 1856 ± 579 NR NR 291 ± 31 306 ± 27 | 730 ± 138 573 ± 179 328 ± 62 368 ± 6.0 308 ± 21 | 286 ± 82 138 ± 41 279 ± 53.5 63.9 ± 13.0 83.9 ± 7.0 | 89 ± 2.7 NR NR NR NR | 197 ± 52 NR NR NR NR | 1.85 ± 0.30 3.0 ± 0.40 1.3 ± 0.25 3.49 ± 0.14 2.33 ± 0.10 | Schultz et al. (1999) Saghir and Schultz (2005)
Chlorodibromo- Single Single Mixture^b^ GST-ζ-depleted^b^ | 500 i.v. 25 i.v. 25 i.v. 25 i.v. | 1107 ± 331 NR 246 ± 22 199 ± 10 | 636 ± 268 264 ± 45 247 ± 25 281 ± 12 | 486 ± 153 128 ± 13 105 ± 8 127 ± 6 | 182 ± 58 NR NR NR | 304 ± 137 NR NR NR | 1.26 ± 0.27 1.40 ± 0.25 1.55 ± 0.21 1.62 ± 0.13 | Schultz et al. (1999) Saghir and Schultz (2005)
Tribromo- Single Mixture^b^ GST-ζ-depleted^b^ | 500 i.v. 25 i.v. 25 i.v. | 676 ± 110 121 ± 36 112 ± 5 | 449 ± 175 278 ± 51 237 ± 21 | 754 ± 116 291 ± 77 225 ± 9 | 171 ± 23 NR NR | 582 ± 126 NR NR | 0.58 ± 0.18 0.76 ± 0.03 0.85 ± 0.11 | Schultz et al. (1999) Saghir and Schultz (2005)
Dichloro- Single Single Single Single GST-ζ-depleted Single GST-ζ-depleted Single GST-ζ-depleted Single GST-ζ-depleted Mixture^b^ GST-ζ-depleted^b^ | 500 i.v. [770] oral [160] oral [770] i.v. [770] i.v. [160] i.v. [160] i.v. [40] i.v. [40] i.v. [8] i.v. [8] i.v. 25 i.v. 25 i.v. | 2092 ± 1821 750 ± 40 13 ± 4 [3360 ± 1810] [18,700 ± 3100] [110 ± 6.6] [1060 ± 26] [9.6 ± 0.4] [64 ± 4] [1.2 ± 0.08] [4.7 ± 0.16] 8.8 ± 0.09 145 ± 33 | 618 ± 318 1000 2400 618 ± 319 582 ± 146 223 ± 111 513 ± 18.5 415 ± 47.2 392 ± 31.4 508 ± 68.6 261 ± 13.6 405 ± 82.0 668 ± 128 | 267 ± 104 820 2900 267 ± 105 42.7 ± 8.2 1571 ± 97 168 ± 22 5265 ± 636 614 ± 39 6554 ± 356 1640 ± 57 2980 ± 332 199 ± 42 | 2.9 ± 0.5 NR NR 2.9 ± 0.5 8.9 ± 3.3 NR NR NR NR NR NR NR NR | 264 ± 103 NR NR 265 ± 103 33.8 ± 4.9 NR NR NR NR NR NR NR NR | 2.4 ± 0.80 0.9 0.9 2.4 ± 0.15 10.8 ± 2.0 0.15 ± 0.01 1.81 ± 0.09 0.08 ± 0.003 0.50 ± 0.03 0.07 ± 0.001 0.20 ± 0.05 0.15 ± 0.04 2.30 ± 0.29 | Schultz et al. (1999) Larson and Bull (1992) Gonzalez-Leon et al. (1997) Saghir and Schultz (2002) Saghir and Schultz (2005)
Dichloro- Young (3−4 mo) Young (3−4 mo) Aged (16 mo) | [400] oral [400 × 2] oral [400 × 2] oral | [91 ± 13] [1,870 ± 580] [11,700 ± 1920] | 680 ± 70 390 ± 140 140 ± 20 | NR | NR | NR | 0.11 ± 0.02 5.4 ± 0.76 9.7 ± 0.97 | James et al. (1998)
Bromochloro- Single Single^c^ Single^c^ Single^c^ Single^c^ GST-ζ-depleted^c^ GST-ζ-depleted^c^ GST-ζ-depleted^c^ | 500 i.v. [58] i.v. [58] (oral) [230] (oral) [580] (oral) [16] (oral) [160] (oral) [320] (oral) | 576 ± 286 [16.4; 19.8] [2.7; 2.8] [94; 137] [450; 678] [26; 2.8] [117; 133] [356; 375] | 881 ± 373 NR NR NR NR NR NR NR | 1,037 ± 453 [3510; 2920] [21,240; 20,640] [2460; 1670] [1280; 852] [6420; 5720] [1420; 1190] [940; 850] | 36.9 ± 20.8 NR NR NR NR NR NR NR | 1014 ± 443 NR NR NR NR NR NR NR | 3.93 ± 1.5 0.10; 0.09 0.25; 0.21 0.62; 0.53 0.71; 0.67 0.05; 0.07 0.16; 0.11 0.08; 0.10 | Schultz et al. (1999) NTP (2009)
(−)Bromochloro- Single GST-ζ-depleted Mixture^a^ GST-ζ-depleted^a^ Single^c^ | 520 i.v. 520 i.v. 25 i.v. 25 i.v. [58] i.v. | 74.8 ± 9.0 584 ± 135 1.7 ± 0.1 7.3 ± 1.1 [7.6; 4.7] | 380 ± 41 417 ± 139 680 ± 103 361 ± 53 NR | 3712 ± 140 484 ± 142 7660 ± 478 1997 ± 42 [7560; 12,400] | 31.4 ± 9.5 17.4 ± 10.8 NR NR NR | 3693 ± 155 468 ± 143 NR NR NR | 0.07 ± 0.01 0.40 ± 0.02 0.06 ± 0.01 0.19 ± 0.03 NR | Schultz and Sylvester (2001) Saghir and Schultz (2005) NTP (2009)
(+)Bromochloro- Single GST-ζ-depleted Mixture^a^ GST-ζ-depleted^a^ Single^c^ | 520 i.v. 520 i.v. 25 i.v. 25 i.v. [58] i.v. | 234 ± 25 487 ± 119 7.2 ± 0.6 28.9 ± 3.5 [13.4; 10.4] | 587 ± 104 467 ± 168 393 ± 34 246 ± 25 NR | 1,248 ± 132 591 ± 136 1,773 ± 184 466 ± 56 [4310; 5570] | 13.2 ± 3.0 13.4 ± 7.4 NR NR NR | 1,236 ± 127 580 ± 139 NR NR NR | 0.40 ± 0.09 0.44 ± 0.04 0.19 ± 0.01 0.40 ± 0.02 NR | Schultz and Sylvester (2001) Saghir and Schultz (2005) NTP (2009)
Dibromo- Single Mixture^a^ GST-ζ-depleted^a^ Single^c^ Single^c^ Single^c^ | 500 i.v. 25 i.v. 25 i.v. [115] oral [230] oral [570] oral | 1,120 ± 362 2.4 ± 0.1 13.2 ± 2.5 [36; 50] [95; 121] [251; 353] | 400 ± 112 987 ± 142 599 ± 68 NR NR NR | 491 ± 116 10,540 ± 312 2,390 ± 71 NR NR NR | 12.9 ± 4.0 NR NR NR NR NR | 490 ± 137 NR NR NR NR NR | 0.72 ± 0.12 0.08 ± 0.01 0.22 ± 0.02 0.8; 0.87 0.95; 0.77 1.2; 0.98 | Schultz et al. (1999) Saghir and Schultz (2005) NTP (2007a)
Monochloro- | [2400] oral [110] oral [790] i.v. [110] i.v. | [3120 ± 23] [105 ± 0.8] NR NR | NR NR 1060 3033 | 558 ± 2.4 769 ± 3.8 262 750 | NR NR 154 546 | NR NR NR NR | 2.19 ± 0.79 1.89 ± 0.11 5.40 3.25 | Saghir and Rozman (2003) Saghir et al. (2001)

Data in brackets indicate unit conversions: (dose mg/kg•1000 μg/mg)/(MW μg/μmol) = dose μmoles/kg, (AUC μg/mL•hr •1000 ng/μg)/(MW ng/nmol) = AUC μM•hr], or (Cl mL/min/kg •60 min/h) = Cl mL/kg/h) where MW of trichloroacetic acid = 163.4, dichloroacetic acid = 128.9, bromochloroacetic acid = 173.4, dibromoacetic acid = 217.86, and monochloroacetic acid = 94.5.

Cl = clearance, Vd_ss_ = apparent steady state volume of distribution, t½ = half-life of elimination, NR = not reported.

^a^ Administered as a mixture containing trichlor-, bromodichloro-, bromochloro-, and dibromoacetic acid.

^b^ Administered as a mixture containing chlorodibromo- tribromo- and dichloroacetic acid.

^c^ Males; females.

Table B-3 Toxicokinetic Parameters of Haloacetic Acids in Male B6C3F1 Mice

Haloacetic Acid | Dose/Route (mg/kg) | AUC (μM•h) | Vd_ss_ (mL/kg) | Total Body Cl (mL/kg/h) | Renal Cl (mL/kg/h) | Nonrenal Cl (mL/kg/h) | T½ (h) | Reference
Trichloro- Control TCA-pretreat^a^ DCA-pretreat^a^ | 100 i.v. 100 i.v. 100 i.v. | [19,500 ± 2240] [23,000 ± 3240] [23,100 ± 1,980] | 571 ± 91 483 ± 42 521 ± 15 | 40.1 ± 4.6 37.2 ± 5.2 34.0 ± 3.0 | 28.1 ± 9.1 22.0 ± 3.4 20.2 ± 1.9 | 12 15 14 | 10.0 ± 2.0 9.40 ± 0.7 10.7 ± 1.0 | Gonzalez-Leon et al. (1999)
Trichloro- | 100 oral 20 oral | 7180 ± 210 2020 ± 60 | 555 335 | 66 55 | NR | NR | 5.8 4.2 | Larson and Bull (1992)
Bromodichloro- | 100 i.v. 20 i.v. 5 i.v. | 3127 ± 231 709 ± 255 119 ± 19 | 518 ± 21 380 ± 25 383 ± 26 | 156 ± 10 217 ± 76 222 ± 33 | 3.7 0 0 | 152.3 217 222 | 2.05 ± 0.10 1.94 ± 0.56 1.33 ± 0.15 | Merdink et al. (2001)
Dichloro- | 100 oral 20 oral | 30 ± 0 8 ± 2 | 32,500 34,800 | 14,300 16,000 | NR | NR | 1.6 1.5 | Larson and Bull (1992)
Dichloro- Control TCA-pretreat^a^ DCA-pretreat^a^ | 100 i.v. 100 i.v. 100 i.v. | [690 ± 93] [2310 ± 396] [950 ± 39] | 548 ± 96 534 ± 53 475 ± 26 | 1188 ± 147 387 ± 100 813 ± 37 | 1.61 ± 0.69 3.13 ± 1.8 2.20 ± 0.61 | 1186 384 811 | 0.35 ± 0.1 1.14 ± 0.2 0.40 ± 0.3 | Gonzalez-Leon et al. (1999)
Dichloro- Controls^b^ 6 h 16 h 36 h 48 h aged controls^c^ ≤16 h | 20 i.v. 20 i.v. 20 i.v. 20 i.v. 20 i.v. 20 i.v. 20 i.v. | [22 ± 4.7] [143 ± 10] [123 ± 36] [60 ± 12] [32 ^±^ 5.4] [98 ± 46] [75 ± 2.6] | 497 ± 160 437 ± 29 691 ± 27 334 ± 43 467 ± 62 459 ± 160 597 ± 68 | 7420 ± 1,460 1085 ± 179 1051 ± 204 2408 ± 392 4887 ± 740 1903 ± 850 2296 ± 852 | NR | NR | 0.053 ± 0.02 0.30 ± 0.04 0.33 ± 0.03 0.11 ± 0.01 0.086 ± 0.01 0.23 ± 0.09 0.24 ± 0.05 | Schultz et al. (2002)
Dibromo- single^d^ single^d^ single^d^ | [320] oral [800] oral [1600] oral | [6.5; 5.6] [36.9; 34.1] [112; 113] | NR NR NR | NR NR NR | NR NR NR | NR NR NR | 0.36; 0.33 0.80; 0.67 1.75; 1.99 | NTP (2007a)
Bromochloro- Single^d^ Single^d^ Single^d^ Single^d^ GST-ζ-depleted^d^ GST-ζ-depleted^d^ | [580] i.v. [580 ] (oral) [1150 ] (oral) [2300 ] (oral) [520 ] (oral) [1040 ] (oral) | [135; 128] [25; 14.9] [134; 74] [445; 331] [18.6; 134] [271; 327] | NR NR NR NR NR NR | [4280; 4520] [23,100; 38,760] [8640; 15;600] [5180; 6960] [24,900; 4320] [3400; 3530] | NR NR NR NR NR NR | NR NR NR NR NR NR | 0.089; 0.062 0.15; 0.18 0.25; 0.20 0.32; 0.25 0.10; 0.22 0.22; 0.21 | NTP (2009)
(−)Bromochloro- Single^d^ | [580] i.v. | [50.8; 54.9] | NR | [11,340; 10;500] | NR | NR | 0.03; 0.03 | NTP (2009)
(+)Bromochloro- Single^d^ | [580] i.v. | [83.3; 97.1] | NR | [6900; 5930] | NR | NR | 0.08; 0.08 | NTP (2009)

Data in brackets indicate unit conversion: Cl μg/mL•hr •1000 ng/μg)/(MW ng/nmol) = Cl μM•hr] or (AUC μg/mL•hr •1000 ng/μg)/(MW ng/nmol) = AUC μM•hr).

Cl = clearance, Vd_ss_ = apparent steady state volume of distribution, t½ = half-life of elimination, NR = not reported.

^a^ Animals were pretreated with 2 g/L DCA or TCA in drinking water for 14 days then administered a challenge dose of 100 mg/kg of TCA or DCA 16 h later.

^b^ 8-week old mice exposed to 2 g/L DCA in drinking water for 14 days and i.v. dose administered 6, 16, 36, or 48 h after removal of DCA from drinking water.

^c^ 4-week old mice given 2 g/L DCA in drinking water for 56 weeks and i.v. dose administered within 16 h after removal of DCA from the drinking water

^d^ Males; females.