# Appendix A Literature Search Strategy

## A.1 Introduction

The objective of the literature search approach is to identify published literature that is relevant for evaluating the potential carcinogenicity of the haloacetic acids of interest. As discussed in the Concept Document for haloacetic acids (https://ntp.niehs.nih.gov/ntp/about_ntp/bsc/2016/april/haa_508.pdf), the monograph relies on the IARC monograph and studies published since the monograph (new studies). The literature search strategy was used to identify new human cancer studies and recent reviews of mechanistic data.

## A.2 General Approach

Database searching encompasses selecting databases and search terms and conducting the searches. Searches of several citation databases are generally conducted using search terms for the individual haloacetic acids, combined with search terms for cancer and/or specific topics, including epidemiological and mechanistic studies. A critical step in the process involves consultation with an information specialist to develop relevant search terms. These terms are used to search bibliographic databases. IARC volume 101 used literature found in PubMed before December 2012, so any searches limited by date sought new information published since 2011. The body of literature for haloacetic acids of interest was searched using narrowing terms for the relevant major topics within the bibliographic databases. The results were then processed in EndNote to remove duplicates before being transferred to [underlined: Health Assessment Workplace Collaborative] (https://hawcproject.org/) (HAWC) for screening. Figure A-1 illustrates the overall approach to the searches and screening and the numbers of citations identified. Table A-1 highlights the general concepts searched and databases consulted. To review all the terms used, please refer to the full search strings below.

Figure A-1

Literature Search Strategy and Review

*ERRATUM: Errors were identified in the Report on Carcinogens Monograph on Haloacetic Acids Found as Water Disinfection By-products. The number of included citations for all monograph sections was incorrect in the original figure. These errors have been corrected; 327 was changed to 336 and italicized.

Table A-1 Major Topics Searched

Topic | Search Method | Databases Searched
Exposure | 13 HAAs String AND occur*[tiab] | PubMed
Human Studies | 13 HAAs String AND ORoC Epidemiological (Human) Studies Search AND ORoC Cancer Search | PubMed, Scopus, Web of Science
Animal Studies | 13 HAAs String AND Experimental Animals Studies Search AND ORoC Cancer Search | PubMed, Scopus, Web of Science
Mechanism and Genetox | 13 HAAs String AND ORoC Characteristics of Carcinogens Search | PubMed, Scopus, Web of Science

In addition to the standard search concepts described above, three special targeted searches were run to seek additional detail for the Human Cancer and Mechanistic sections of the monograph. To confirm full coverage on bladder cancer a targeted search was run for that endpoint alone. The primary use for Haloacetic Acids in the treatment and disinfection of water suggests that and research conducted on the subject of water treatment and disinfection methods in general may contain data of interest to the evaluation. A search was conducted to collect human studies referring to the general methods rather than the specific HAAs. Finally, in an effort to categorize the HAAs for possible read-across efforts and specific search was conducted on metabolic and mechanistic concepts thought to be common between some of the HAAs. Table A-2 highlights the general concepts searched and databases consulted for these special searches. To review all the terms used, please refer to the full search strings below in the section Supplementary Searches.

Table A-2 Supplementary Searches

Topic | Search Method | Databases Searched
Bladder Cancer | Supplementary Bladder Cancer Search (see detailed description below) | PubMed, Scopus, Web of Science
Human Studies on Water Treatment or Disinfection | DBPs OR disinfection OR water treatment OR treated water AND ORoC Cancer Search (see detailed description below) | PubMed, Scopus, Web of Science
Read Across | 13 HAAs String AND terms for select metabolic concepts (see detailed description below for Mechanism Special Search,>Mechanism Special Search) | PubMed, Scopus, Web of Science

## A.3 Standard Searches

### A.3.1 13 HAAs

A search of primary and universal terms for the 13 haloacetic acids chemicals and cancer. Limiting terms have been applied to reduce the number of irrelevant results returned that are associated with chemical peel treatments, wart removal methods, and trichloroacetic acid (TCA) precipitation.

This search was used in most cases to characterize the haloacetic acids and was combined with narrowing terms for cancer, animal studies, human epidemiology studies, mechanistic literature (characteristics of carcinogens) and more.

#### A.3.1.1 PubMed

((Haloacetic-acid*[tiab]) OR Dihaloacetic-acid*[tiab]) OR Trihaloacetic-acid*[tiab] OR (“dichloroacetic acid”[nm] OR 79-43-6[rn] OR dichloroacetate[tiab] OR “dichloroacetic acid”[tiab] OR “Bichloracetic acid”[tiab] OR “Dichloracetic acid”[tiab] OR “Dichlorethanoic acid”[tiab] OR “Dichloroethanoic acid”[tiab]) OR (“Trichloroacetic Acid”[mh] OR 76-03-9[rn] OR “Trichloroacetic Acid”[tiab] OR Trichloroacetate[tiab] OR “Trichloracetic acid”[tiab]) OR (“Dibromoacetic acid”[nm] OR 631-64-1[rn] OR dibromoacetate[tiab] OR “Dibromoacetic acid”[tiab]) OR (“tribromoacetic acid”[nm] OR 75-96-7[rn] OR tribromoacetate[tiab] OR “tribromoacetic acid”[tiab]) OR (“Dichlorobromoacetic acid”[tiab] OR Bromodichloroacetate[tiab] OR “bromodichloroacetic acid”[nm] OR bromodichloroacetic-acid[tiab] OR 71133-14-7[rn]) OR (“Dibromochloroacetic acid”[tiab] OR 5278-95-5[rn] OR bromochloroacetate[tiab]) OR (“bromochloroacetic acid”[nm] OR 5589-96-8[rn] OR “bromochloroacetic acid”[tiab] OR bromochloroacetate[tiab] OR “Chlorobromoacetic acid”[tiab]) OR (Diiodoacetic-acid[tiab] OR “598-89-0”[tiab] OR Diiodoacetate[tiab]) OR (71815-43-5[rn] OR Bromoiodoacetic-acid[tiab] OR Bromoiodoacetate[tiab]) OR (Chloroiodoacetic-acid[tiab] OR “Chloro(iodo)acetic acid”[tiab] OR 53715-09-6[rn] OR “2-Chloro-2-iodoacetic acid”[tiab] OR “Acetic acid, 2-chloro-2-iodo-”[tiab] OR “chloro-iodoacetic acid”[tiab] OR Chloroiodoacetate[tiab]) OR (“Monochloroacetic acid”[tiab] OR “Monochloracetic acid”[tiab] OR “79-11-8”[rn] OR Chloroacetic-acid[tiab] OR “Chloroacetic acid”[nm] OR “Chloracetic acid”[tiab]) OR (Bromoacetic-acid[tiab] OR Bromoacetate[tiab] OR Monobromoacetic-acid[tiab] OR 79-08-3[rn]) OR (“Iodoacetic acid”[mh] OR 64-69-7[rn] OR Monoiodoacetic-acid[tiab] OR Monoiodoacetate[tiab] OR Monoiodine-acetate[tiab] OR Iodoacetate[tiab] OR Iodoacetic-acid[tiab]) NOT (trichloro-acetic-acid-peel*[tiab] OR trichloroacetic-acid-peel*[tiab] OR trichloracetic-acid-peel*[tiab] OR Trichloroacetic-Acid-solub* OR Trichloroacetic-Acid-insolub* OR Trichloroacetic-Acid-precipit* OR TCA-solub* OR TCA-insolub* OR TCA-precipit* OR anogenital-wart*[tiab] OR genital-wart*[tiab] OR “Condylomata Acuminata”[Mh] OR “Human papillomavirus”[tiab] OR “Human papillomavirus 31”[mh] OR “Sexually transmitted diseas*”[tiab])

#### A.3.1.2 Web of Science

(TS=(“Haloacetic acid*” OR “Dihaloacetic acid*” OR “Trihaloacetic acid*”)) OR (TS=(“dichloroacetic acid” OR “79-43-6” OR dichloroacetate OR “dichloroacetic acid” OR “Bichloracetic acid” OR “Dichloracetic acid” OR “Dichlorethanoic acid” OR “Dichloroethanoic acid” OR “76-03-9” OR “Trichloroacetic Acid” OR Trichloroacetate OR “Trichloracetic acid” OR “Dibromoacetic acid” OR “631-64-1” OR dibromoacetate OR “Dibromoacetic acid” OR “tribromoacetic acid” OR “75-96-7” OR tribromoacetate OR “tribromoacetic acid” OR “Dichlorobromoacetic acid” OR Bromodichloroacetate OR “bromodichloroacetic acid” OR “bromodichloroacetic-acid” OR “71133-14-7” OR “Dibromochloroacetic acid” OR “5278-95-5” OR bromochloroacetate OR “bromochloroacetic acid “OR “5589-96-8” OR “bromochloroacetic acid” OR bromochloroacetate OR “Chlorobromoacetic acid”)) OR (TS=(“Diiodoacetic acid” OR “598-89-0” OR Diiodoacetate OR “71815-43-5” OR “Bromoiodoacetic acid” OR Bromoiodoacetate OR “Chloroiodoacetic acid” OR “Chloro(iodo)acetic acid” OR “53715-09-6” OR “2-Chloro-2-iodoacetic acid” OR “chloro-iodoacetic acid” OR Chloroiodoacetate)) OR (TS=(“Monochloroacetic acid” OR “Monochloracetic acid” OR “79-11-8” OR “Chloroacetic acid” OR “Chloroacetic acid” OR “Chloracetic acid” OR “Iodoacetic acid” OR “64-69-7” OR “Monoiodoacetic acid” OR Monoiodoacetate OR “Monoiodine acetate” OR Iodoacetate OR “Bromoacetic acid” OR Bromoacetate OR “Monobromoacetic acid” OR “79-08-3”)) NOT (TS=(“trichloro-acetic acid peel*” OR “trichloroacetic acid peel*” OR “trichloracetic acid peel*” OR “Trichloroacetic-Acid solub*” OR “Trichloroacetic Acid insolub*” OR “Trichloroacetic Acid precipit*” OR “TCA solub*” OR “TCA insolub*” OR “TCA precipit*” OR “anogenital wart*” OR “genital wart*” OR “Condylomata Acuminata” OR “Human papillomavirus*” OR “Sexually transmitted diseas*”))

#### A.3.1.3 Scopus

((TITLE-ABS-KEY (“Haloacetic acid*” OR “Dihaloacetic acid*” OR “Trihaloacetic acid*”)) OR (TITLE-ABS-KEY (“dichloroacetic acid” OR “79-43-6” OR dichloroacetate OR “dichloroacetic acid” OR “Bichloracetic acid” OR “Dichloracetic acid” OR “Dichlorethanoic acid” OR “Dichloroethanoic acid” OR “76-03-9” OR “Trichloroacetic Acid” OR trichloroacetate OR “Trichloracetic acid” OR “Dibromoacetic acid” OR “631-64-1” OR dibromoacetate OR “Dibromoacetic acid” OR “tribromoacetic acid” OR “75-96-7” OR tribromoacetate OR “tribromoacetic acid” OR “Dichlorobromoacetic acid” OR bromodichloroacetate OR “bromodichloroacetic acid” OR bromodichloroacetic-acid OR “71133-14-7” OR “Dibromochloroacetic acid” OR “5278-95-5” OR bromochloroacetate OR “bromochloroacetic acid” OR “5589-96-8” OR “bromochloroacetic acid” OR bromochloroacetate OR “Chlorobromoacetic acid”)) OR (TITLE-ABS-KEY (“Diiodoacetic acid” OR “598-89-0” OR diiodoacetate OR “594-68-3” OR “71815-43-5” OR “Bromoiodoacetic acid” OR bromoiodoacetate OR “Chloroiodoacetic acid” OR “Chloro(iodo)acetic acid” OR “53715-09-6” OR “2-Chloro-2-iodoacetic acid” OR “chloro-iodoacetic acid” OR chloroiodoacetate)) OR (TITLE-ABS-KEY (“Monochloroacetic acid” OR “Monochloracetic acid” OR “79-11-8” OR “Chloroacetic acid” OR “Chloroacetic acid” OR “Chloracetic acid” OR “Iodoacetic acid” OR “64-69-7” OR “Monoiodoacetic acid” OR monoiodoacetate OR “Monoiodine acetate” OR iodoacetate OR “Bromoacetic acid” OR bromoacetate OR “Monobromoacetic acid” OR “79-08-3”))) AND NOT (TITLE-ABS-KEY(“trichloro-acetic acid peel*” OR “trichloroacetic acid peel*” OR “trichloracetic acid peel*” OR “Trichloroacetic-Acid solub*” OR “Trichloroacetic Acid insolub*” OR “Trichloroacetic Acid precipit*” OR “TCA solub*” OR “TCA insolub*” OR “TCA precipit*” OR “anogenital wart*” OR “genital wart*” OR “Condylomata Acuminata” OR “Human papillomavirus*” OR “Sexually transmitted diseas*”))

### A.3.2 RoC Cancer String

The PubMed String is the same as described in the Handbook Appendix (https://ntp.niehs.nih.gov/ntp/roc/handbook/rochandbookappendix_508.pdf), however additional options for wildcard use and truncation have allowed the same string to be shortened for WOS and Scopus. The altered strings are presented here.

#### A.3.2.1 Web of Science

(TS=(*broma OR *bromas OR *doma OR *domas OR *droma OR *dromas OR *eoma OR *eomas OR *goma OR *gomas OR *ioma OR *iomas OR *loma OR *lomas OR *moma OR *momas OR *noma OR *nomas OR *omatosis OR *phoma OR *phomas OR *poma OR *pomas OR *phroma OR *phromas OR *sarcoma OR *sarcomas OR *scoma OR *scomas OR *thecoma OR *thecomas OR *thoma OR *thomas OR *toma OR *tomas OR *uroma OR *uromas OR *xoma OR *xomas OR *yoma OR *yomas OR *kaemia OR *kaemia OR *kemia OR *kemia OR *plakia OR *plakias)) OR (TS=(“cancer” OR “cancerous” OR “cancers” OR “carcinogen” OR “carcinogenesis” OR “carcinogenic” OR “carcinogens” OR “carcinoid” OR “carcinomatosis” OR “cocarcinogenesis” OR “metaplasia” OR “anaplasia” OR “neoplasia” OR “neoplasia” OR “neoplasm” OR “neoplasms” OR “neoplastic” OR “tumor” OR “tumorgenesis” OR “tumorgenic” OR “tumorigenesis” OR “tumorigenic” OR “tumorogenesis” OR “tumorogenic” OR “tumors” OR “tumour” OR “tumours” OR “nonhodgkin” OR “nonhodgkins” OR “Hodgkin” OR “hodgkins”)) OR (TS=(“acrochordon” OR “acrochordons” OR “acrospiroma” OR “acrospiromas” OR “adenomatous” OR “adenosis” OR “Buschke-Lowenstein” OR “chloroma” OR “chloromas” OR “CIN” OR “CLL” OR “dermoid” OR “dysmyelopoiesis” OR “epidermoid” OR “essential thrombocythemia” OR “exostosis” OR “fibroid” OR “fibroids” OR “lymphoproliferation” OR “lymphoproliferations” OR “lymphoproliferative” OR “macroglobulinemia” OR “macroglobulinemias” OR “malignancies” OR “malignancy” OR “malignant” OR “mastocytosis” OR “meigs syndrome” OR “micrometastases” OR “micrometastasis” OR “mycosis fungoides” OR “myelofibrosis” OR “myeloproliferation” OR “myeloproliferations” OR “myeloproliferative” OR “NSCLC” OR “papillomata” OR “papillomatosis” OR “pilomatricoma” OR “pilomatricomas” OR “polyposis” OR “poroma” OR “poromas” OR “premalignant” OR “preneoplastic” OR “seminomatous” OR “sezary syndrome” OR “struma ovarii” OR “waldenstrom” OR “waldenstroms” OR “oncogene fusion” OR “5q syndrome” OR “aberrant crypt foci” OR “Aberrant crypt focus” OR “carney complex” OR “denys drash” OR “leukostasis” OR “zollinger ellison”)) OR ((TS=(“sentinel lymph node” NOT “biopsy”)) OR (TS=(“ASCO” NOT “fungi”)) OR (TS=(“WAGR” AND “syndrome”)))

#### A.3.2.2 Scopus

(TITLE-ABS (*broma OR *bromas OR *doma OR *domas OR *droma OR *dromas OR *eoma OR *eomas OR *goma OR *gomas OR *ioma OR *iomas OR *loma OR *lomas OR *moma OR *momas OR *noma OR *nomas OR *omatosis OR *phoma OR *phomas OR *poma OR *pomas OR *phroma OR *phromas OR *sarcoma OR *sarcomas OR *scoma OR *scomas OR *thecoma OR *thecomas OR *thoma OR *thomas OR *toma OR *tomas OR *uroma OR *uromas OR *xoma OR *xomas OR *yoma OR *yomas OR *kaemia OR *kaemia OR *kemia OR *kemia OR *plakia OR *plakias)) OR (TITLE-ABS (“cancer” OR “cancerous” OR “cancers” OR “carcinogen” OR “carcinogenesis” OR “carcinogenic” OR “carcinogens” OR “carcinoid” OR “carcinomatosis” OR “cocarcinogenesis” OR “metaplasia” OR “anaplasia” OR “neoplasia” OR “neoplasia” OR “neoplasm” OR “neoplasms” OR “neoplastic” OR “tumor” OR “tumorgenesis” OR “tumorgenic” OR “tumorigenesis” OR “tumorigenic” OR “tumorogenesis” OR “tumorogenic” OR “tumors” OR “tumour” OR “tumours” OR “nonhodgkin” OR “nonhodgkins” OR “non-hodgkin” OR “non-hodgkins” OR “Hodgkin” OR “hodgkins”)) OR (TITLE-ABS(“acrochordon” OR “acrochordons” OR “acrospiroma” OR “acrospiromas” OR “adenomatous” OR “adenosis” OR “Buschke-Lowenstein” OR “chloroma” OR “chloromas” OR “CIN” OR “CLL” OR “dermoid” OR “dysmyelopoiesis” OR “epidermoid” OR “essential thrombocythemia” OR “exostosis” OR “fibroid” OR “fibroids” OR “lymphoproliferation” OR “lymphoproliferations” OR “lymphoproliferative” OR “macroglobulinemia” OR “macroglobulinemias” OR “malignancies” OR “malignancy” OR “malignant” OR “mastocytosis” OR “meigs syndrome” OR “micrometastases” OR “micrometastasis” OR “mycosis fungoides” OR “myelofibrosis” OR “myeloproliferation” OR “myeloproliferations” OR “myeloproliferative” OR “NSCLC” OR “papillomata” OR “papillomatosis” OR pilomatricoma OR pilomatricomas OR polyposis OR poroma OR poromas OR “premalignant” OR “preneoplastic” OR “seminomatous” OR “sezary syndrome” OR “struma ovarii” OR “waldenstrom” OR “waldenstroms” OR “oncogene fusion” OR “5q syndrome” OR “aberrant crypt foci” OR “Aberrant crypt focus” OR “carney complex” OR “denys drash” OR leukostasis OR “zollinger ellison”)) OR ((TITLE-ABS (“ASCO” AND NOT “fungi”)) OR (TITLE-ABS (“WAGR” AND “syndrome”)))

## A.4 Supplementary Searches

### A.4.1 Disinfection By-products, Water Disinfection, Water Treatment

This search was used to run supplemental cancer searches to capture references for studies evaluating general categories of chemicals that could include the selected HAAs. The search was limited to the years 2011 and forward because the IARC evaluation was used as a source for earlier studies of this type.

#### A.4.1.1 PubMed

(Disinfection-ByProduct*[tiab] OR Disinfection-By-Product*[tiab]) OR water-disinfect*[tiab] OR disinfected-water[tiab]) OR (“treated water*”[tiab] OR “water treatment*”[tiab])

#### A.4.1.2 Web of Science

((TS=(“Disinfection ByProduct*” OR “Disinfection By-Product*”)) OR (TS=(water n/2 disinfect*))) OR (TS= (“treated water” OR (water NEAR/2 treatment*)))

#### A.4.1.3 Scopus

(((TITLE-ABS-KEY (“Disinfection ByProduct*” OR “Disinfection By-Product*”)) OR (TITLE-ABS-KEY (water W/2 disinfect*))) OR ((TITLE-ABS-KEY (water W/2 treatment* OR “treated water”)))

### A.4.2 Supplementary Bladder Cancer Search

While bladder cancer is represented in the RoC Cancer search string, a supplemental search was conducted to collect all bladder cancer literature, in case there were studies that discussed the relevant chemicals in the body of the paper but not in the title abstracts or keyword.

#### A.4.2.1 PubMed

As the most productive source of medical literature, a broader search was conducted in PubMed than the other two databases. Therefore the search was not limited by any haloacetic acid terms. However, the search was limited to the years 2011 and forward because the IARC evaluation was used as a source for earlier studies of this type. The other two databases included too many non-medical “bladder” concepts so the HAA terms were needed to focus the search.

(bladder[tiab] OR “Urinary Bladder”[Mh])

AND

RoC Cancer String

#### A.4.2.2 Web of Science

(TS=(bladder))

AND

13 HAAs Search (as described above)

#### A.4.2.3 Scopus

(TITLE-ABS-KEY (bladder*))

AND

AAs Search (as described above)

### A.4.3 Mechanism Special Search

A search of select terms focused on mechanistic and metabolic concepts to help identify viable justifications for grouping chemicals for read-across. The specific concepts search were pyruvate dehydrogenase (excluding dichloroacetic acid terms), Glutathione Transferase Zeta, and cell transformation. These strings were combined with the 13 HAAs string.

#### A.4.3.1 PubMed

((GAPDH[tiab] OR Glyceraldehyde-3-Phosphate-Dehydrogenas*[tiab] OR “Glyceraldehyde-3-Phosphate Dehydrogenases”[mh]) OR (tumorigenic-transformation*[tiab] OR Cell-transformation*[tiab] OR “Cell Transformation, Neoplastic”[Mh]) OR (“Glutathione Transferase*”[tiab] OR “Glutathione Transferase”[mh] OR glutathione-S-transferase*[tiab] OR GST-zeta[tiab] OR GSTz[tiab]))

#### A.4.3.2 Web of Science

((TS=(“Glyceraldehyde 3 Phosphate Dehydrogenas**” OR “GAPDH”)) OR (TS=(“tumorigenic transformation*” OR “Cell transformation*”)) OR (TS=(“Glutathione Transferase*” OR “glutathione-S-transferase*” OR “GST zeta” OR gstz)))

#### A.4.3.3 Scopus

((TITLE-ABS-KEY (“Glyceraldehyde 3 Phosphate Dehydrogenas**” OR “GAPDH”)) OR (TITLE-ABS-KEY (“tumorigenic transformation*” OR “Cell transformation*”)) OR (TITLE-ABS-KEY (“Glutathione Transferase*” OR “glutathione-S-transferase*” OR “GST zeta” OR gstz)))