# 5 Overall Cancer Hazard Evaluation and Listing Recommendation

Merkel cell polyomavirus (MCV) is known to be a human carcinogen based on sufficient evidence from studies in humans. This conclusion is based on epidemiological studies showing that it causes Merkel cell carcinoma (MCC) in humans, together with supporting evidence from mechanistic studies demonstrating the biological plausibility of its carcinogenicity in humans (Table 5-1).

Table 5-1 Summary of the Evidence for MCV and Merkel Cell Carcinoma from Human Studies

Types of Studies | Merkel Cell Carcinoma
Epidemiological Studies with positive associations or dose-response | 21 Case series (716 MCV/855 MCC cases) 3/3 Case-control studies; moderate to highly statistically significant OR; 1 nested case-control study—statistically significant; increase in risk in females but only modest nonsignificant risk in males
Molecular (human tissue) Clonality % MCV-infected tumors MCV protein expression | Monoclonal >80% of MCC Large T (LT), small T (sT) antigens
Level of evidence | Sufficient

LT = large T antigen; MCV = Merkel cell polyomavirus; MCC = Merkel cell carcinoma; OR = odds ratio; sT = small T-antigen.

Data are inadequate to evaluate the association between MCV and either chronic lymphocytic leukemia or lung carcinoma, both of which have inconsistent evidence from epidemiological studies and no available evidence from mechanistic studies.

The following table provides the level of evidence recommendation for the carcinogenicity of MCV for Merkel cell carcinoma from studies in humans, including the key data from both epidemiological and molecular studies in humans.