# 3 Human Cancer Studies

Merkel-cell polyomavirus (MCV) is a recently (2008) discovered polyomavirus that has been studied in relationship to Merkel cell carcinoma. The NTP used the body of knowledge published by IARC (2013) on MCV for studies conducted between 2008 and 2012, combined with new studies that were identified (published between 2012 and 2015) to evaluate the scientific evidence for specific cancer endpoints independently of IARC’s conclusions. Where available, IARC data tables of the effect estimates have informed the cancer hazard assessment.

IARC primarily evaluated the relationship between MCV and Merkel cell carcinoma; other cancer endpoints were discussed by IARC, but not reviewed in detail. In this section, only the Merkel cell carcinoma endpoint is evaluated in depth due to sparsely available published literature on other endpoints. MCV detection methods varied across studies, with exposure determined primarily through amplification of viral DNA and other techniques in tissue, and via multiplex-binding assays of serum.

The cancer hazard evaluation of MCV from human cancer studies is divided into three parts: the first briefly summarizes the approach for identifying and selecting the literature specific to MCV (Section 3.1); the second discusses the cancer hazard evaluation for specific cancer endpoints (Sections 3.2 to 3.4); and the last part summarizes the evaluations across endpoints (Section 3.5). The level of evidence from cancer studies in humans also considers studies of tissues from humans in addition to epidemiological studies and is provided in Section 5.

## 3.1 Selection of the Relevant Literature

A systematic literature search of major databases, citations, and other authoritative sources from 2012 to August 2015 was conducted. Details on the literature search strategy can be found in Appendix A. For the MCV review, all case-control and cohort studies, regardless of cancer endpoint, were identified. These included studies reviewed by IARC (2013) and new epidemiological studies identified in the literature search. The case-control studies may range from broadly defined, non-matched hospital- or population-based case-control designs to formal matched case-control designs. Case-series studies of five patients or more on the relationship between MCV and Merkel cell carcinoma, and published since 2012, were also included in the review. Data from the epidemiological studies included case-series studies and were considered in the overall assessment.

## 3.2 Cancer Hazard Evaluation: Merkel Cell Carcinoma

This section provides a brief background on Merkel cell carcinoma, summarizes the study findings for each study design, discusses relevant cofactors and integrates the evidence for the association between Merkel cell carcinoma and MCV across study designs. The review consists of six case-series studies, three case-control studies, and one nested case-control study on MCV and Merkel cell carcinoma.

### 3.2.1 Background Information

Merkel cell carcinoma is a rare and highly aggressive form of skin cancer, with an incidence rate of approximately 4 cases per million (Hodgson 2005). It is most common in whites, males, and those over 60 (Agelli and Clegg 2003; Schrama et al. 2012). Merkel cell carcinoma has a five-year relative survival rate of 60% to 70% (relative to stage and anatomic site at diagnosis) (IARC 2013; Schrama et al. 2012). There are several risk factors for Merkel cell carcinoma, which include age, with a mean age of onset around 75 years of age, male gender, and race, with Merkel cell carcinoma occurring primarily in Caucasians (Agelli and Clegg 2003; Schrama et al. 2012). Additionally, ultraviolet light is a potential risk factor, with Merkel cell carcinoma most often diagnosed in sun-exposed areas of the skin (Mogha et al. 2010; Spurgeon and Lambert 2013). Merkel cell carcinoma occurs most often in immunocompromised individuals, including transplant recipients (Clarke et al. 2015) and those who are HIV-1 positive (Engels et al. 2002).

### 3.2.2 Case-series Studies of MCV and Merkel Cell Carcinoma

Since its discovery in 2008, MCV has been identified in up to 80% of Merkel cell carcinoma cases (IARC 2013), with newer studies suggesting over 98% of Merkel cell carcinoma tumors contain MCV (Rodig et al. 2012). Other studies suggest that there are two varieties of Merkel cell carcinoma, one that is MCV infected, and one that is not; however, the existence of a MCV-negative subset is controversial (Moore and Chang 2014). In a meta-analysis of mixed case-series and mechanistic studies, the global prevalence of MCV in Merkel cell carcinoma cases was 79% (Santos-Juanes et al. 2015). In 21 case-series studies of 5 patients or more since 2008, MCV was detected in 716 of 885 Merkel cell carcinoma cases (see Table 2.3 in IARC (2013)). All but six of these case-series studies were reviewed by IARC (2013); the remaining studies are detailed in Table 3-1 below. In the IARC (2013) review, several of the case-series studies reviewed included a control group; however, the IARC Working Group did not consider these true case-control studies, due to convenience sampling or the lack of comparability of exposure measures. In the studies presented here, evidence of MCV infection in Merkel cell carcinoma cases ranged from 42% to 100%; however, only 23% of cytokeratin 20 (CK-20) negative Merkel cell carcinoma cases presented by Miner et al. (2015) were positive for MCV. CK-20 is an epithelial marker positive in approximately 95% of Merkel cell carcinomas. A variety of detection methods were employed in these case-series studies, which may account for the differences in the percentage of cases in which MCV was detected.

Table 3-1 Recent Case-series Studies of MCV and Merkel Cell Carcinoma Published Since the IARC (2013) Review

Author (Year) | n/N Exposed Cases | Percent Exposed to MCV | MCV Tissue Detection Method | Location/Comments
Ly et al. (2012) | 17/27 | 63.0 | IHC staining with CM2B4 anti-large T antigen | Canada
Ota et al. (2012) | 9/9 | 100.0 | Viral load calculated using digital PCR (small-T DNA primers); anti-CK20, chromogranin A, and synaptophysin IHC; anti-CM2B4 IHC and conventional PCR (6 nested primer sets) | Japan
Chun et al. (2013) | 6/7 | 85.7 | PCR and quantitative PCR, and IHC | Korea
Hourdequin et al. (2013) | 11/11 | 100.0 | Quantitative PCR assays for the detection of 4 MCV genomic targets | United States
Leitz et al. (2014) | 19/32 16/29 13/31 | 59.4 55.2 41.9 | Qualitative PCR for LT sequences Quantitative PCR for LT sequences in DNA IHC staining with CM2B4 anti-large T antigen | Germany (not all cases tested with all three methods)
Miner et al. (2015) | 3/13 | 23.0 | Quantitative PCR for LT and sT antigens | United States (CK-20-negative MCC)

CK-20 = cytokeratin 20, CM2B4 = antibody to MCV, LT = large T-antigen, IHC = immunohistochemistry, MCC = Merkel cell carcinoma, MCV = Merkel cell polyomavirus, PCR = polymerase chain reaction, sT = small T antigen.

## 3.3 Case-control Studies

Three case-control studies were identified that investigated the association between MCV and Merkel cell carcinoma. These three studies were reviewed previously by IARC (2013), and are detailed in Table 3-2. In the first study, Carter et al. (2009) investigated the association between MCV antibodies (antibodies to MCVw162 VP1) and Merkel cell carcinoma in 41 (27 male and 14 female) consecutively identified Merkel cell carcinoma cases and 76 (51 male and 25 female) hospital controls frequency matched on age and sex. They found that 36 of 41 cases carried MCV antibodies, compared with 40 of 76 controls (OR 6.6, 95% CI = 2.3 to 18.8, adjusted for age and sex).

Table 3-2 Case-control and Nested Case-control Studies of MCV and Merkel Cell Carcinoma

Author (Year) Country | Serum Detection Method | Exposure Group (MCV + cases; controls) | OR (95% CI)^a^ | Covariates | Comments
Case-control studies
Carter et al. (2009)^b^ United States | Multiplex antibody-binding assay to detect MCV VP1 antibody | MCV VPI + (36/41; 40/76) | 6.6 (2.3–18.8) | Age, sex | Controls selected from a previous case-control study, matched on age and sex
Paulson et al. (2010)^b^ United States | Multiplex antibody-binding assay to detect antibodies to MCV VP1; MCV sT; MCV LT | MCV VPI (139/530) MCV sT (50/139; 5/530) MCV LT (31/139; 9/530) | 5.5 (2.9–11.2) 63.2 (24.4–164.0) 16.9 (7.8–36.7) | Age, sex | Controls selected by RDD and frequency matched on age and sex; 66 individuals not matched and not included in analysis
Viscidi et al. (2011) Italy | VLP-based ELISA | VLP + (30/33; 25/36) | [4.4 (0.9–26.7)] | Age | Controls selected from cancer-free individuals attending screenings at a clinic
Nested case-control study
Faust et al. (2014) Sweden and Norway | Antibodies to MCV measured by neutralization assay and by IgG antibodies to MCV pseudovirions | [underlined: All participants] Any (22/13) High (1/22; 14/79) Neutralizing (10/22; 12/75) [underlined: Females] Any (12/13; 33/47) High (9/13; 10/47) Neutralizing (8/13; 8/47) [underlined: Males] Any (7/9; 24/29) High (2/9; 4/29) Neutralizing (2/9; 4/29) | [underlined: All participants] 2.6 (0.7–15.0) 4.4 (1.3–17.4) 5.3 (1.3–32.3) [underlined: Females] 6.0 (0.8–277) 7.0 (1.6–42.8) 14.3 (1.7–677) [underlined: Males] 1.0 (0.1–12.6) 1.3 (0.1–19.9) 1.3 (0.1–19.9) | Enrollment method, age, sex, county, and length of follow up | Cases and controls from two large biobank cohorts. Matched by enrollment method, age, sex, county, and length of follow up

CI = confidence interval; ELISA = enzyme-linked immunosorbent assay; IgG = immunoglobulin G; LT = large T antigen; MCC = Merkel cell carcinoma; MCV = Merkel cell polyomavirus; OR = odds ratio; PCR = polymerase chain reaction; RDD = random digit dialing; sT = small T antigen; VLP = virus-like particle; VP1 = viral capsid protein 1.

^a^ ORs in brackets were calculated by NTP.

^b^ Study populations for Carter et al. (2009) and Paulson et al. (2010) overlap to an unknown extent.

A second study by Paulson et al. (2010) included 139 Merkel cell carcinoma cases (including 79 males and 60 females) and 530 controls. Controls were identified through random-digit dialing and were frequency matched by age (within 5 years) and sex to cases. Significant associations were seen between MCV capsid, (OR = 5.5, 95% CI = 2.9 to 11.2), as well as two markers of early gene expression, large T oncoproteins (31 of 139 exposed cases; OR = 16.9, 95% CI = 7.8 to 36.7) and small T oncoproteins (51 of 139 exposed cases; OR = 63.2, 95% CI = 24.4 to 164.0) and Merkel cell carcinoma. Imprecise estimates, particularly for small T oncoproteins, were a result of few seropositive controls within the study.

In a third study (Viscidi et al. 2011), 33 Merkel cell carcinoma patients (25 males and 8 females) and 37 healthy controls were recruited from a family medicine clinic. Of 33 cases, 30 were seropositive for MCV capsid IgG, detected via VLP-based ELISA, while 25 of 36 controls were seropositive ([OR = 4.4, 95% CI = 1.10 to 17.53], p = 0.02; OR and CI were calculated by IARC (2013). After adjusting for age, this association was attenuated (p = 0.32); however, the adjusted effect estimate and confidence intervals were not reported.

### 3.3.1 Nested Case-control Study

A prospective nested case-control study (Faust et al. 2014) utilized two large biobank cohorts containing samples from over 856,000 individuals in Sweden and Norway. Cases were identified through cancer registries and linked to samples in the biobanks. A total of 22 cases with samples in the biobank were identified. Four healthy controls (alive and cancer free at the time the case was diagnosed) were matched to each case on enrollment method, age, sex, county, number of samples, and length of follow-up. The risk for future Merkel cell carcinoma was associated with both baseline presence of neutralizing MCV antibodies (10 of 22 cases exposed; OR = 5.3, 95% CI = 1.3 to 32.3) and with the presence of high levels of MCV antibodies (11 of 22 cases exposed; OR = 4.4, 95% CI = 1.3 to 17.4), along with an elevated, but non-significant risk for any level of MCV antibodies (19 of 22 cases exposed; OR = 2.6, 95% CI = 0.7 to 15.0). When stratified by gender, the risk for Merkel cell carcinoma in females was significantly associated with both the baseline presence of neutralizing MCV antibodies (8 of 13 cases exposed; OR = 14.3, 95% CI = 1.7 to 677, and the presence of high levels of MCV antibodies (9 of 13 cases exposed; OR = 7.0, 95% CI = 1.6 to 42.8). There was also an elevated, but statistically non-significant association between Merkel cell carcinoma and any level of MCV antibodies (OR = 6.0, 95% CI = 0.8 to 277). No association between Merkel cell carcinoma and MCV was seen in males, which may be related to the small sample size of males in this study. This study was described in Table 3-2.

### 3.3.2 Cofactors

There is limited and conflicting evidence as to whether co-infection with HIV-1 increases the risk of MCV infection (Tolstov et al. 2011; Wieland and Kreuter 2011). However, prior to or shortly after the discovery of MCV, several studies reported increased risks of Merkel cell carcinoma among HIV-1-positive populations (Engels et al. 2002; Izikson et al. 2011; Lanoy et al. 2009), organ transplant recipients, and other immunocompromised patients (Clarke et al. 2015; Heath et al. 2008; Lanoy and Engels 2010); see also accompanying monograph on HIV-1. To date, no studies have been identified that have measured MCV viral load in healthy tissues from Merkel cell carcinoma cases, however, and no other cofactors of the relationship between MCV and Merkel cell carcinoma have been identified to date. Additionally, no studies have been identified to date that have measured MCV among HIV-1-positive or immunocompromised Merkel cell carcinoma cases.

Ultraviolet (UV) radiation has been identified as a risk factor for Merkel cell carcinoma. UV radiation is both mutagenic and immunosuppressive and evidence that exposure to UV light is an important cofactor in Merkel cell carcinoma development includes the following: Merkel cell carcinoma incidence is higher at equatorial latitudes, more than 80% of primary tumors occur on sun-exposed skin, and Caucasians have the highest risk (Agelli et al. 2010; Amber et al. 2013; Becker et al. 2009a). An in vivo study using human volunteers showed that after UV exposure, there was induction of the sT transcript that was attributed to MCV activation and a luciferase-based in vitro study confirmed that the sT promoter was UV-inducible (Mogha et al. 2010).

These and other potential cofactors in the Merkel cell carcinoma/MCV relationship have not been evaluated in epidemiological studies.

### 3.3.3 Integration of the Evidence across Studies

MCV is present in over 80% of Merkel cell carcinoma cases. As MCV is a newly identified virus, only a handful of epidemiological studies have been conducted; however, there is credible evidence of an association between Merkel cell carcinoma and MCV. The three case-control and one nested case-control studies found statistically significant associations, with ORs ranging from 4.4 to 63.2. Nevertheless, it is noteworthy that the study populations of Carter et al. (2009) and Paulson et al. (2010) overlap to an unknown extent; although there are at least 98 unique cases in Paulson et al. (2010). Additionally, there is some evidence of an increased risk at higher levels of MCV exposure, evidenced by Faust et al. (2014), where ORs in populations with high levels of antibodies were higher than those for any MCV exposure. Faust et al. (2014) also demonstrated a temporal relationship between Merkel cell carcinoma and MCV. This study is also suggestive of an effect modification by gender, with a stronger association in females than in males; however, fewer male cases were reported in the study. The study by Paulson et al. (2010) demonstrated a strong association between MCV T antigen (both LT and sT) antibodies and virus detection in Merkel cell carcinomas. Further, antibodies to T antigens (but not to MCV capsid protein) varied greatly over time in infected patients and reflected tumor burden. Due to the paucity of studies and lack of known risk factors for MCV infection in relation to Merkel cell carcinoma, confounding cannot be ruled out. Moreover, the lack of a gold standard detection method for MCV is a limitation in each of the reviewed studies, which might lead to exposure misclassification.

## 3.4 Cancer Hazard Evaluation: Other Cancer Endpoints

A small number of case-control studies have investigated the association between MCV and other cancer endpoints, including acute lymphoblastic leukemia (Gustafsson et al. 2012), skin squamous-cell carcinoma (Rollison et al. 2012), bladder cancer (Polesel et al. 2012; Robles et al. 2013), esophageal cancer (Sitas et al. 2012), chronic lymphocytic leukemia (Robles et al. 2015; Robles et al. 2012). To date, there is insufficient evidence to fully evaluate these cancer endpoints; however, two cancer endpoints (chronic lymphocytic leukemia and lung carcinoma) are shown in Table 3-3 and discussed below. For findings on other endpoints, see IARC (2013) Table 2.2.

Table 3-3 Case-control Studies of MCV Lymphomas or Leukemia

Author (Year) | Detection Method | Cancer Endpoint | MCV+ Cases/ Total Cases (%) | MCV+ Controls/ Total Controls (%) | OR (95% CI) | Covariates
Chronic lymphocytic leukemia
Robles et al. (2015) | Bead-based multiplex serology | CLL | All cases 233/289 (80.5%) 1^st^ Tertile: 52/123 (42.6%) 2^nd^ Tertile: 41/109 (37.7%) 3^rd^ Tertile: 11/57 (19.7%) | 260/310 (83.8%) | All cases 0.79 (0.54–1.16) Reference group 0.92 (0.63–1.34) 0.46 (0.30–0.70) | –
Robles et al. (2012) | MCV VP1 VLP enzyme immunoassay | All lymphomas CLL | 400/468 (85%) 94/108 (87%) | 448/552 (81.2%) NR | 1.34 (0.95–1.88) 1.49 (0.80–2.75) | Age, sex, study center
Teras et al. (2015) ^a^ | MCV serology | CLL/SLL | All cases 42/66 (63.75%) High titer 19/42 (45.2%)^b^ | 383/557 (68.8%) Low titer 23/42 (54.8%) | All cases 0.80 (0.47–1.37) 1.0 (ref, low titer) 0.83 (0.44–1.59)^b^ | Age, sex, race, birth, blood draw date

CLL = chronic lymphocytic leukemia; MCC = Merkel cell carcinoma; MCV = Merkel cell polyomavirus; OR = odds ratio; PCR = polymerase chain reaction; SLL = small lymphocytic lymphoma; VLP = virus-like particle; VP1 = viral capsid protein 1.

^a^ Nested case control study.

^b^ Among seropositive participants only, median fluorescence intensity value for MCV antigen was used as the cutpoint.

Four case series and reports have been identified investigating the prevalence of MCV in chronic lymphocytic leukemia cases and included a total of 345 chronic lymphocytic leukemia cases. Between 4% and 74% of cases were positive for MCV, depending on the MCV detection method (Cimino et al. 2013; Imajoh et al. 2012; Peretti et al. 2014; Tolstov et al. 2010). In addition to differences in methods for measuring exposure to MCV (e.g., viral load, MCV DNA) this wide range in prevalence may be due to differences in tissues or aims of the study. For example, in the Peretti et al. (2014) study, 243/293 chronic lymphocytic leukemia cases were MCV positive when MCV was tested in the hair bulb, and 0/293 were positive in skin lesions.

Two case-control studies and one nested case-control study on the association between chronic lymphocytic leukemia and MCV were identified. Robles et al. (2015; 2012) conducted two case-control studies and found mixed results; a non-significant positive association between MCV and chronic lymphocytic leukemia (OR = 1.49, 95% CI = 0.80 to 2.75) in the first study, and non-significant negative association in the later study (OR = 0.79, 95% CI = 0.54 to 1.16). In a nested case-control study, 42/66 chronic lymphocytic leukemia cases were seropositive for MCV prior to diagnosis (OR = 0.80, 95% CI = 0.47 to 1.37) (Teras et al. 2015).

Nine case-series studies have been identified that looked at the prevalence of MCV in lung carcinomas. In five studies of small-cell lung carcinoma patients, 11% (14/129) were MCV positive (Andres et al. 2009; Helmbold et al. 2009; Joh et al. 2010b; Karimi et al. 2014; Wetzels et al. 2009). In five studies of non-small-cell lung carcinoma patients, 13% (71/529) were MCV positive. A case-series study on extrapulmonary small-cell lung carcinoma (Hourdequin et al. 2013) found 19% (3/16) of cases to be MCV positive.

## 3.5 Synthesis across Cancer Endpoints

A summary of the evidence for MCV infection and the different cancer endpoints from epidemiological studies is provided in Table 3-4. The level of evidence from cancer studies in humans also considers studies of tissues from humans in addition to epidemiological studies and is provided in Section 5.

Table 3-4 Summary of MCV Cancer Endpoints and Strength of the Epidemiological Evidence

Cancer Endpoint | Strength of Evidence
Merkel cell carcinoma | Consistent evidence seen in several epidemiological studies, including one prospective study. All studies found a positive association between MCC and MCV. MCV found in >80% of MCC tumors.
Chronic lymphocytic leukemia | Inconsistent evidence of an association in case series and epidemiological studies.
Lung carcinoma | Inconsistent evidence of an association seen in case series. No adequate epidemiological studies have been conducted.

MCC = Merkel cell carcinoma, MCV = Merkel cell polyomavirus.