# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2331-267X

DOI: https://doi.org/10.22427/ROC-MGRAPH-11

Report Series: RoC Monograph Series

Report Series Number: 11

Official citation: National Toxicology Program (NTP). 2016. Report on Carcinogens monograph on Merkel cell polyomavirus. Research Triangle Park, NC: National Toxicology Program. RoC Monograph 11.