# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Conducted technical review and evaluation and proposed the listing recommendation
  Gloria D. Jahnke, D.V.M., DABT, Project Lead
  Ruth M. Lunn, Dr.P.H., Director, Office of the Report on Carcinogens
- Integrated Laboratory Systems, Inc., Research Triangle Park, North Carolina, USA
  Contributed to the conduct and technical review of the cancer hazard evaluation
  Sanford Garner, Ph.D., Principal Investigator
  Stanley Atwood, M.S., DABT
  Andrew Ewens, Ph.D., DABT
  Alton Peters, M.S.
- Social & Scientific Systems, Inc., Durham, North Carolina, USA
  Conducted technical review and evaluation
  Whitney Arroyave, Ph.D.