# Abbreviations

  4EBP-1: 4E-binding protein 1
  AIDS: Acquired Immune Deficiency Syndrome
  ALTO: alternate frame of the large T open reading frame
  BKV: BK polyomavirus
  CDC: Centers for Disease Control and Prevention
  CI: confidence interval
  CK-20: cytokeratin 20
  CLL: chronic lymphocytic leukemia
  CM2B4: antibody to MCV
  DNA: deoxyribonucleic acid
  dsDNA: double stranded deoxyribonucleic acid
  ELISA: enzyme-linked immunoassay
  FBW7: F-box/WD repeat-containing protein 7
  FDA: Food and Drug Administration
  HIF-1: hypoxia-inducible factor
  HIV: human immunodeficiency virus
  IARC: International Agency for Research on Cancer
  IgG: immunoglobulin G
  IHC: immunohistochemistry
  JCV: JC polyomavirus
  LT: large T antigen
  MCC: Merkel cell carcinoma
  MCPyV: Merkel cell polyomavirus
  MCV: Merkel cell polyomavirus
  N: number
  NEMO: NF-κB essential modulator
  MAPK: mitogen activated protein kinase
  miRNA: microRNA
  NHANES: National Health and Nutrition Examination Survey
  NTP: National Toxicology Program
  OR: odds ratio
  PCR: polymerase chain reaction
  PDGF: platelet-derived growth factor
  pRB: retinoblastoma protein
  PTEN: phosphatase and tensin homologue
  RDD: random digit dialing
  SLL: small lymphocytic lymphoma
  sT: small T-antigen
  SV40: simian virus 40
  TLR9: Toll-like receptor 9
  USA: United States of America
  UV: ultraviolet radiation
  Vam6p: vacuolar protein-sorting gene product
  VEGF: vascular endothelial growth factor
  VL: virus-like particle
  VLP: virus-like particle
  VP1: viral capsid protein 1
  VP2: viral capsid protein 2