# Glossary

Case series: A collection of subjects (usually, patients) with common characteristics used to describe some clinical, pathophysiological, or operational aspect of a disease, treatment, exposure, or diagnostic procedure. A case series does not include a comparison group and is often based on prevalent cases and on a sample of convenience. Common selection biases and confounding severely limit their power to make causal inferences.
Case-comparison study (case-control study, case referent study): The observational epidemiological study of persons with the disease (or another outcome variable) of interest and a suitable control group of persons without the disease (comparison group, reference group). The potential relationship of a suspected risk factor or an attribute to the disease is examined by comparing the diseased and non-diseased subjects with regard to how frequently the factor or attribute is present (or, if quantitative, the levels of the attribute) in each of the groups (diseased and non-diseased).
Cellular immunity: immunity independent of antibody but dependent on the recognition of antigen by T cells and their subsequent destruction of cells bearing the antigen or on the secretion by T cells of lymphokines that enhance the ability of phagocytes to eliminate the antigen.
Convenience sample: Samples selected by easily employed but basically non-probabilistic (and probably biased) methods. “Man-in-the-street” surveys and a survey of blood pressure among volunteers who drop in at an examination booth in a public place are in this category.
Diagnostic criteria: The specific combination of signs, symptoms, and test results that a clinician uses to identify a person as representing a case of a particular disease or condition.
Familial aggregation: A tendency of some diseases to cluster in families, which may be the result of genetic and epigenetic mechanisms, shared environmental exposures (e.g., diet), or both.
Humoral response: An immune response in which antibodies produced by B cells cause the destruction of extracellular microorganisms and prevent the spread of intracellular infections.
Immunoassay: A laboratory technique that uses the binding between an antigen and its homologous antibody to identify and quantify the specific antigen or antibody in a sample.
Innate immune response: The fast-acting, non-specific immunological actions of an organism that recognize an infection and attempt to clear it from the organism. The innate immune system can be thought of an organism's front line of defense against pathogens.
Latent phase: A phase of the virus life cycle during which the virus is not replicating.
Lytic phase: A phase of the virus life cycle during which the virus replicates within the host cell, releasing a new generation of viruses when the infected cell lyses.
microRNA: small, non-coding RNA molecules approximately 22 nucleotides in length that act post translationally in a regulatory role to target messenger RNAs for cleavage or translational expression.
Polymerase chain reaction: A laboratory technique used to produce large amounts of specific DNA fragments. Polymerase chain reaction is used for genetic testing and to diagnose disease.
Titer: A laboratory measurement of the concentration of a substance in a solution (e.g., an antibody titer measures the presence and amount of antibodies in the blood).
Vertical transmission: The transmission of infection from one generation to the next (e.g., from mother to infant prenatally, during delivery, or in the postnatal period via breast milk.