# References

Adams JM, Cory S. 2007. The Bcl-2 apoptotic switch in cancer development and therapy. Oncogene. 26(9):1324–1337. 10.1038/sj.onc.1210220 17322918
Agelli M, Clegg LX. 2003. Epidemiology of primary Merkel cell carcinoma in the United States. J Am Acad Dermatol. 49(5):832–841. 10.1016/S0190-9622(03)02108-X 14576661
Agelli M, Clegg LX, Becker JC, Rollison DE. 2010. The etiology and epidemiology of Merkel cell carcinoma. Curr Probl Cancer. 34(1):14–37. 10.1016/j.currproblcancer.2010.01.001 20371072
Ahuja R, Jamal A, Nosrati N, Pandey V, Rajput P, Saxena N, Sidhu K, Kumar V. 2014. Human oncogenic viruses and cancer. Curr Sci. 107(5):768–785.
Amber K, McLeod MP, Nouri K. 2013. The Merkel cell polyomavirus and its involvement in Merkel cell carcinoma. Dermatol Surg. 39(2):232–238. 10.1111/dsu.12079 23387356
Andres C, Belloni B, Puchta U, Sander CA, Flaig MJ. 2009. Re: Clinical factors associated with Merkel cell polyomavirus infection in Merkel cell carcinoma. J Natl Cancer Inst. 101(23):1655–1656, author reply 1656–1657. 10.1093/jnci/djp370 19864638
Angermeyer S, Hesbacher S, Becker JC, Schrama D, Houben R. 2013. Merkel cell polyomavirus-positive Merkel cell carcinoma cells do not require expression of the viral small T antigen. J Invest Dermatol. 133(8):2059–2064. 10.1038/jid.2013.82 23439392
Arora R, Chang Y, Moore PS. 2012 a. MCV and Merkel cell carcinoma: A molecular success story. Curr Opin Virol. 2(4):489–498. 10.1016/j.coviro.2012.05.007 22710026
Arora R, Shuda M, Guastafierro A, Feng H, Toptan T, Tolstov Y, Normolle D, Vollmer LL, Vogt A, Domling A, et al. 2012 b. Survivin is a therapeutic target in Merkel cell carcinoma. Sci Transl Med. 4(133):133ra56. 10.1126/scitranslmed.3003713 22572880
Asioli S, Righi A, Volante M, Eusebi V, Bussolati G. 2007. p63 expression as a new prognostic marker in Merkel cell carcinoma. Cancer. 110(3):640–647. 10.1002/cncr.22828 17599745
Avdulov S, Li S, Michalek V, Burrichter D, Peterson M, Perlman DM, Manivel JC, Sonenberg N, Yee D, Bitterman PB, et al. 2004. Activation of translation complex eIF4F is essential for the genesis and maintenance of the malignant phenotype in human mammary epithelial cells. Cancer Cell. 5(6):553–563. 10.1016/j.ccr.2004.05.024 15193258
Becker JC, Schrama D, Houben R. 2009 a. Merkel cell carcinoma. Cell Mol Life Sci. 66(1):1–8. 10.1007/s00018-008-8483-6 19023519
Becker JC, Houben R, Ugurel S, Trefzer U, Pfohler C, Schrama D. 2009 b. MC polyomavirus is frequently present in Merkel cell carcinoma of European patients. J Invest Dermatol. 129(1):248–250. 10.1038/jid.2008.198 18633441
Bhatia K, Goedert JJ, Modali R, Preiss L, Ayers LW. 2010. Merkel cell carcinoma subgroups by Merkel cell polyomavirus DNA relative abundance and oncogene expression. Int J Cancer. 126(9):2240–2246. 10.1002/ijc.24676 19551862
Borchert S, Czech-Sioli M, Neumann F, Schmidt C, Wimmer P, Dobner T, Grundhoff A, Fischer N. 2014. High-affinity Rb binding, p53 inhibition, subcellular localization, and transformation by wild-type or tumor-derived shortened Merkel cell polyomavirus large T antigens. J Virol. 88(6):3144–3160. 10.1128/JVI.02916-13 24371076
Brambilla E, Negoescu A, Gazzeri S, Lantuejoul S, Moro D, Brambilla C, Coll JL. 1996. Apoptosis-related factors p53, Bcl2, and Bax in neuroendocrine lung tumors. Am J Pathol. 149(6):1941–1952. 8952529
Brunner M, Thurnher D, Pammer J, Geleff S, Heiduschka G, Reinisch CM, Petzelbauer P, Erovic BM. 2008. Expression of VEGF-A/C, VEGF-R2, PDGF-alpha/beta, c-kit, EGFR, Her-2/Neu, Mcl-1 and Bmi-1 in Merkel cell carcinoma. Mod Pathol. 21(7):876–884. 10.1038/modpathol.2008.63 18408656
Carter JJ, Daugherty MD, Qi X, Bheda-Malge A, Wipf GC, Robinson K, Roman A, Malik HS, Galloway DA. 2013. Identification of an overprinting gene in Merkel cell polyomavirus provides evolutionary insight into the birth of viral genes. Proc Natl Acad Sci USA. 110(31):12744–12749. 10.1073/pnas.1303526110 23847207
Carter JJ, Paulson KG, Wipf GC, Miranda D, Madeleine MM, Johnson LG, Lemos BD, Lee S, Warcola AH, Iyer JG, et al. 2009. Association of Merkel cell polyomavirus-specific antibodies with Merkel cell carcinoma. J Natl Cancer Inst. 101(21):1510–1522. 10.1093/jnci/djp332 19776382
Centers for Disease Control and Prevention (CDC). 2011. List of vaccines used in United States. Atlanta, GA: Centers for Disease Control and Prevention. https://www.cdc.gov/vaccines/vpd-vac/vaccines-list.htm. [Accessed: June 22, 2015]
Chang Y, Moore PS. 2012. Merkel cell carcinoma: A virus-induced human cancer. Annu Rev Pathol. 7:123–144. 10.1146/annurev-pathol-011110-130227 21942528
Chen T, Hedman L, Mattila PS, Jartti T, Ruuskanen O, Soderlund-Venermo M, Hedman K. 2011. Serological evidence of Merkel cell polyomavirus primary infections in childhood. J Clin Virol. 50(2):125–129. 10.1016/j.jcv.2010.10.015 21094082
Chen T, Tanner L, Simell V, Hedman L, Makinen M, Sadeghi M, Veijola R, Hyoty H, Ilonen J, Knip M, et al. 2014. Diagnostic methods for and clinical pictures of polyomavirus primary infections in children, Finland. Emerg Infect Dis. 20(4):689–692. 10.3201/eid2004.131015 24655410
Cheng J, Rozenblatt-Rosen O, Paulson KG, Nghiem P, DeCaprio JA. 2013. Merkel cell polyomavirus large T antigen has growth-promoting and inhibitory activities. J Virol. 87(11):6118–6126. 10.1128/JVI.00385-13 23514892
Chun SM, Yun SJ, Lee SC, Won YH, Lee JB. 2013. Merkel cell polyomavirus is frequently detected in Korean patients with Merkel cell carcinoma. Ann Dermatol. 25(2):203–207. 10.5021/ad.2013.25.2.203 23717012
Cimino PJ Jr, Bahler DW, Duncavage EJ. 2013. Detection of Merkel cell polyomavirus in chronic lymphocytic leukemia T-cells. Exp Mol Pathol. 94(1):40–44. 10.1016/j.yexmp.2012.09.019 23026399
Cimino PJ, Robirds DH, Tripp SR, Pfeifer JD, Abel HJ, Duncavage EJ. 2014. Retinoblastoma gene mutations detected by whole exome sequencing of Merkel cell carcinoma. Mod Pathol. 27(8):1073–1087. 10.1038/modpathol.2013.235 24406863
Clarke CA, Robbins HA, Tatalovich Z, Lynch CF, Pawlish KS, Finch JL, Hernandez BY, Fraumeni JF Jr, Madeleine MM, Engels EA. 2015. Risk of Merkel cell carcinoma after solid organ transplantation. J Natl Cancer Inst. 107(2). 10.1093/jnci/dju382 25575645
Coursaget P, Samimi M, Nicol JT, Gardair C, Touze A. 2013. Human Merkel cell polyomavirus: Virological background and clinical implications. APMIS. 121(8):755–769. 10.1111/apm.12122 23781869
Dalianis T, Hirsch HH. 2013. Human polyomaviruses in disease and cancer. Virology. 437(2):63–72. 10.1016/j.virol.2012.12.015 23357733
DeCaprio JA, Garcea RL. 2013. A cornucopia of human polyomaviruses. Nat Rev Microbiol. 11(4):264–276. 10.1038/nrmicro2992 23474680
Demetriou SK, Ona-Vu K, Sullivan EM, Dong TK, Hsu SW, Oh DH. 2012. Defective DNA repair and cell cycle arrest in cells expressing Merkel cell polyomavirus T antigen. Int J Cancer. 131(8):1818–1827. 10.1002/ijc.27440 22261839
Dresang LR, Guastafierro A, Arora R, Normolle D, Chang Y, Moore PS. 2013. Response of Merkel cell polyomavirus-positive merkel cell carcinoma xenografts to a survivin inhibitor. PLoS One. 8(11):e80543. 10.1371/journal.pone.0080543 24260412
Engels EA, Frisch M, Goedert JJ, Biggar RJ, Miller RW. 2002. Merkel cell carcinoma and HIV infection. Lancet. 359(9305):497–498. 10.1016/S0140-6736(02)07668-7 11853800
Erstad DJ, Cusack JC Jr. 2014. Mutational analysis of Merkel cell carcinoma. Cancers (Basel). 6(4):2116–2136. 10.3390/cancers6042116 25329450
Faust H, Andersson K, Ekstrom J, Hortlund M, Robsahm TE, Dillner J. 2014. Prospective study of Merkel cell polyomavirus and risk of Merkel cell carcinoma. Int J Cancer. 134(4):844–848. 10.1002/ijc.28419 23922031
Feinmesser M, Halpern M, Fenig E, Tsabari C, Hodak E, Sulkes J, Brenner B, Okon E. 1999. Expression of the apoptosis-related oncogenes bcl-2, bax, and p53 in Merkel cell carcinoma: Can they predict treatment response and clinical outcome? Hum Pathol. 30(11):1367–1372. 10.1016/S0046-8177(99)90070-9 10571519
Feng H, Shuda M, Chang Y, Moore PS. 2008. Clonal integration of a polyomavirus in human Merkel cell carcinoma. Science. 319(5866):1096–1100. 10.1126/science.1152586 18202256
Fernández-Figueras MT, Puig L, Musulén E, Gilaberte M, Lerma E, Serrano S, Ferrándiz C, Ariza A. 2007. Expression profiles associated with aggressive behavior in Merkel cell carcinoma. Mod Pathol. 20(1):90–101. 10.1038/modpathol.3800717 17115023
Foulongne V, Courgnaud V, Champeau W, Segondy M. 2011. Detection of Merkel cell polyomavirus on environmental surfaces. J Med Virol. 83(8):1435–1439. 10.1002/jmv.22110 21618553
Gheit T, Munoz JP, Levican J, Gonzalez C, Ampuero S, Parra B, Gaggero A, Corvalan AH, Meneses M, Tommasino M, et al. 2012. Merkel cell polyomavirus in non-small cell lung carcinomas from Chile. Exp Mol Pathol. 93(1):162–166. 10.1016/j.yexmp.2012.04.008 22537543
Gjoerup O. 2012. Polyomaviruses and cancer. Cancer Associated Viruses. New York: Springer; p. 337–375. 10.1007/978-1-4614-0016-5_14
Gomez B, He L, Tsai YC, Wu TC, Viscidi RP, Hung CF. 2013. Creation of a Merkel cell polyomavirus small T antigen-expressing murine tumor model and a DNA vaccine targeting small T antigen. Cell Biosci. 3(1):29. 10.1186/2045-3701-3-29 23856459
Griffiths DA, Abdul-Sada H, Knight LM, Jackson BR, Richards K, Prescott EL, Peach AHS, Blair GE, Macdonald A, Whitehouse A. 2013. Merkel cell polyomavirus small T antigen targets the NEMO adaptor protein to disrupt inflammatory signaling. J Virol. 87(24):13853–13867. 10.1128/JVI.02159-13 24109239
Gustafsson B, Honkaniemi E, Goh S, Giraud G, Forestier E, von Dobeln U, Allander T, Dalianis T, Bogdanovic G. 2012. KI, WU, and Merkel cell polyomavirus DNA was not detected in guthrie cards of children who later developed acute lymphoblastic leukemia. J Pediatr Hematol Oncol. 34(5):364–367. 10.1097/MPH.0b013e318241fb52 22713707
Hanahan D, Weinberg RA. 2000. The hallmarks of cancer. Cell. 100(1):57–70. 10.1016/S0092-8674(00)81683-9 10647931
Hanahan D, Weinberg RA. 2011. Hallmarks of cancer: The next generation. Cell. 144(5):646–674. 10.1016/j.cell.2011.02.013 21376230
Harms PW, Patel RM, Verhaegen ME, Giordano TJ, Nash KT, Johnson CN, Daignault S, Thomas DG, Gudjonsson JE, Elder JT, et al. 2013. Distinct gene expression profiles of viral- and nonviral-associated merkel cell carcinoma revealed by transcriptome analysis. J Invest Dermatol. 133(4):936–945. 10.1038/jid.2012.445 23223137
Hashida Y, Imajoh M, Nemoto Y, Kamioka M, Taniguchi A, Taguchi T, Kume M, Orihashi K, Daibata M. 2013. Detection of Merkel cell polyomavirus with a tumour-specific signature in non-small cell lung cancer. Br J Cancer. 108(3):629–637. 10.1038/bjc.2012.567 23322199
Heath M, Jaimes N, Lemos B, Mostaghimi A, Wang LC, Penas PF, Nghiem P. 2008. Clinical characteristics of Merkel cell carcinoma at diagnosis in 195 patients: The AEIOU features. J Am Acad Dermatol. 58(3):375–381. 10.1016/j.jaad.2007.11.020 18280333
Helmbold P, Lahtz C, Herpel E, Schnabel PA, Dammann RH. 2009. Frequent hypermethylation of RASSF1A tumour suppressor gene promoter and presence of Merkel cell polyomavirus in small cell lung cancer. Eur J Cancer. 45(12):2207–2211. 10.1016/j.ejca.2009.04.038 19473831
Higaki-Mori H, Kuwamoto S, Iwasaki T, Kato M, Murakami I, Nagata K, Sano H, Horie Y, Yoshida Y, Yamamoto O, et al. 2012. Association of Merkel cell polyomavirus infection with clinicopathological differences in Merkel cell carcinoma. Hum Pathol. 43(12):2282–2291. 10.1016/j.humpath.2012.04.002 22795182
Hill AB. 1965. The environment and disease: Association or causation? Proc R Soc Med. 58(5):295–300. 10.1177/003591576505800503 14283879
Hodgson NC. 2005. Merkel cell carcinoma: Changing incidence trends. J Surg Oncol. 89(1):1–4. 10.1002/jso.20167 15611998
Houben R, Adam C, Baeurle A, Hesbacher S, Grimm J, Angermeyer S, Henzel K, Hauser S, Elling R, Brocker EB, et al. 2012. An intact retinoblastoma protein-binding site in Merkel cell polyomavirus large T antigen is required for promoting growth of Merkel cell carcinoma cells. Int J Cancer. 130(4):847–856. 10.1002/ijc.26076 21413015
Houben R, Michel B, Vetter-Kauczok CS, Pfohler C, Laetsch B, Wolter MD, Leonard JH, Trefzer U, Ugurel S, Schrama D, et al. 2006. Absence of classical MAP kinase pathway signalling in Merkel cell carcinoma. J Invest Dermatol. 126(5):1135–1142. 10.1038/sj.jid.5700170 16498399
Houben R, Schrama D, Becker JC. 2009. Molecular pathogenesis of Merkel cell carcinoma. Exp Dermatol. 18(3):193–198. 10.1111/j.1600-0625.2009.00853.x 19400830
Houben R, Shuda M, Weinkam R, Schrama D, Feng H, Chang Y, Moore PS, Becker JC. 2010. Merkel cell polyomavirus-infected Merkel cell carcinoma cells require expression of viral T antigens. J Virol. 84(14):7064–7072. 10.1128/JVI.02400-09 20444890
Hourdequin KC, Lefferts JA, Brennick JB, Ernstoff MS, Tsongalis GJ, Pipas JM. 2013. Merkel cell polyomavirus and extrapulmonary small cell carcinoma. Oncol Lett. 6(4):1049–1052. 10.3892/ol.2013.1483 24137462
Hughes M, Gao L. 2013. Skin cancer viruses: Bench to bedside - HPV, HHV8 and Merkel cell carcinoma virus. Drug Discov Today Dis Mech. 10(3-4):e91–e94. 10.1016/j.ddmec.2013.05.001
Imajoh M, Hashida Y, Taniguchi A, Kamioka M, Daibata M. 2012. Novel human polyomaviruses, Merkel cell polyomavirus and human polyomavirus 9, in Japanese chronic lymphocytic leukemia cases. J Hematol Oncol. 5:25. 10.1186/1756-8722-5-25 22658224
International Agency for Research on Cancer (IARC). 1997. Epstein-Barr virus and Kaposi’s sarcoma herpesvirus/human herpesvirus. Chapter 8: Epstein-Barr virus. In: IARC Monographs on the Evaluation of Carcinogenic Risks to Humans vol 70. Lyon, France: International Agency for Research on Cancer. p. 47–373.
International Agency for Research on Cancer (IARC). 2013. Malaria and some polyomaviruses (SV40, BK, JC, and Merkel cell viruses). In: IARC Working Group on the Evaluation of Carcinogenic Risks to Humans vol. 104. Lyon, France: International Agency for Research on Cancer. p. 365.
Izikson L, Nornhold E, Iyer JG, Nghiem P, Zeitouni NC. 2011. Merkel cell carcinoma associated with HIV: Review of 14 patients. AIDS. 25(1):119–121. 10.1097/QAD.0b013e328340a19c 21119325
Joh J, Jenson AB, Moore GD, Rezazedeh A, Slone SP, Ghim SJ, Kloecker GH. 2010 a. Human papillomavirus (HPV) and Merkel cell polyomavirus (MCPyV) in non small cell lung cancer. Exp Mol Pathol. 89(3):222–226. 10.1016/j.yexmp.2010.08.001 20699096
Joh J, Jenson AB, Slone SS, Moore G, Ghim S, Kloecker GH. 2010 b. Merkel cell polyomavirus (MCPYV) DNA present in non small cell lung cancer (NSCLC). Ann Oncol. 21 Suppl 8:52.
Karimi S, Yousefi F, Seifi S, Khosravi A, Nadji SA. 2014. No evidence for a role of Merkel cell polyomavirus in small cell lung cancer among Iranian subjects. Pathol Res Pract. 210(12):836–839. 10.1016/j.prp.2014.08.011 25238937
Kassem A, Schopflin A, Diaz C, Weyers W, Stickeler E, Werner M, Zur Hausen A. 2008. Frequent detection of Merkel cell polyomavirus in human Merkel cell carcinomas and identification of a unique deletion in the VP1 gene. Cancer Res. 68(13):5009–5013. 10.1158/0008-5472.CAN-08-0949 18593898
Kean JM, Rao S, Wang M, Garcea RL. 2009. Seroepidemiology of human polyomaviruses. PLoS Pathog. 5(3):e1000363. 10.1371/journal.ppat.1000363 19325891
Kennedy MM, Blessing K, King G, Kerr KM. 1996. Expression of bcl-2 and p53 in Merkel cell carcinoma. An immunohistochemical study. Am J Dermatopathol. 18(3):273–277. 10.1097/00000372-199606000-00006 8806961
Kim J, McNiff JM. 2008. Nuclear expression of survivin portends a poor prognosis in Merkel cell carcinoma. Mod Pathol. 21(6):764–769. 10.1038/modpathol.2008.61 18425079
Kuwamoto S. 2011. Recent advances in the biology of Merkel cell carcinoma. Hum Pathol. 42(8):1063–1077. 10.1016/j.humpath.2011.01.020 21641014
Kwun HJ, Shuda M, Camacho CJ, Gamper AM, Thant M, Chang Y, Moore PS. 2015. Restricted protein phosphatase 2A targeting by Merkel cell polyomavirus small T antigen. J Virol. 89(8):4191–4200. 10.1128/JVI.00157-15 25631078
Kwun HJ, Shuda M, Feng H, Camacho CJ, Moore PS, Chang Y. 2013. Merkel cell polyomavirus small T antigen controls viral replication and oncoprotein expression by targeting the cellular ubiquitin ligase SCFFbw7. Cell Host Microbe. 14(2):125–135. 10.1016/j.chom.2013.06.008 23954152
Lanoy E, Dores GM, Madeleine MM, Toro JR, Fraumeni JF Jr, Engels EA. 2009. Epidemiology of nonkeratinocytic skin cancers among persons with AIDS in the United States. AIDS. 23(3):385–393. 10.1097/QAD.0b013e3283213046 19114864
Lanoy E, Engels EA. 2010. Skin cancers associated with autoimmune conditions among elderly adults. Br J Cancer. 103(1):112–114. 10.1038/sj.bjc.6605733 20551958
Lasithiotaki I, Antoniou KM, Derdas SP, Sarchianaki E, Symvoulakis EK, Psaraki A, Spandidos DA, Stathopoulos EN, Siafakas NM, Sourvinos G. 2013. The presence of Merkel cell polyomavirus is associated with deregulated expression of BRAF and Bcl-2 genes in non-small cell lung cancer. Int J Cancer. 133(3):604–611. 10.1002/ijc.28062 23355004
Lassacher A, Heitzer E, Kerl H, Wolf P. 2008. p14ARF hypermethylation is common but INK4a-ARF locus or p53 mutations are rare in Merkel cell carcinoma. J Invest Dermatol. 128(7):1788–1796. 10.1038/sj.jid.5701256 18219279
Laude HC, Jonchere B, Maubec E, Carlotti A, Marinho E, Couturaud B, Peter M, Sastre-Garau X, Avril MF, Dupin N, et al. 2010. Distinct Merkel cell polyomavirus molecular features in tumour and non tumour specimens from patients with Merkel cell carcinoma. PLoS Pathog. 6(8):e1001076. 10.1371/journal.ppat.1001076 20865165
Lazaris-Karatzas A, Montine KS, Sonenberg N. 1990. Malignant transformation by a eukaryotic initiation factor subunit that binds to mRNA 5′ cap. Nature. 345(6275):544–547. 10.1038/345544a0 2348862
Lee S, Paulson KG, Murchison EP, Afanasiev OK, Alkan C, Leonard JH, Byrd DR, Hannon GJ, Nghiem P. 2011. Identification and validation of a novel mature microRNA encoded by the Merkel cell polyomavirus in human Merkel cell carcinomas. J Clin Virol. 52(3):272–275. 10.1016/j.jcv.2011.08.012 21907614
Leitz M, Stieler K, Grundhoff A, Moll I, Brandner JM, Fischer N. 2014. Merkel cell polyomavirus detection in Merkel cell cancer tumors in Northern Germany using PCR and protein expression. J Med Virol. 86(10):1813–1819. 10.1002/jmv.23808 24307009
Li J, Wang X, Diaz J, Tsang SH, Buck CB, You J. 2013. Merkel cell polyomavirus large T antigen disrupts host genomic integrity and inhibits cellular proliferation. J Virol. 87(16):9173–9188. 10.1128/JVI.01216-13 23760247
Liu X, Hein J, Richardson SC, Basse PH, Toptan T, Moore PS, Gjoerup OV, Chang Y. 2011. Merkel cell polyomavirus large T antigen disrupts lysosome clustering by translocating human Vam6p from the cytoplasm to the nucleus. J Biol Chem. 286(19):17079–17090. 10.1074/jbc.M110.192856 21454559
Loyo M, Guerrero-Preston R, Brait M, Hoque MO, Chuang A, Kim MS, Sharma R, Liégeois NJ, Koch WM, Califano JA, et al. 2010. Quantitative detection of Merkel cell virus in human tissues and possible mode of transmission. Int J Cancer. 126(12):2991–2996. 10.1002/ijc.24737 19588496
Ly TY, Walsh NM, Pasternak S. 2012. The spectrum of Merkel cell polyomavirus expression in Merkel cell carcinoma, in a variety of cutaneous neoplasms, and in neuroendocrine carcinomas from different anatomical sites. Hum Pathol. 43(4):557–566. 10.1016/j.humpath.2011.06.005 21940035
Martel-Jantin C, Filippone C, Cassar O, Peter M, Tomasic G, Vielh P, Briere J, Petrella T, Aubriot-Lorton MH, Mortier L, et al. 2012. Genetic variability and integration of Merkel cell polyomavirus in Merkel cell carcinoma. Virology. 426(2):134–142. 10.1016/j.virol.2012.01.018 22342276
Martel-Jantin C, Filippone C, Tortevoye P, Afonso PV, Betsem E, Descorps-Declere S, Nicol JT, Touze A, Coursaget P, Crouzat M, et al. 2014. Molecular epidemiology of Merkel cell polyomavirus: Evidence for geographically related variant genotypes. J Clin Microbiol. 52(5):1687–1690. 10.1128/JCM.02348-13 24523477
Martel-Jantin C, Pedergnana V, Nicol JT, Leblond V, Tregouet DA, Tortevoye P, Plancoulaine S, Coursaget P, Touze A, Abel L, et al. 2013. Merkel cell polyomavirus infection occurs during early childhood and is transmitted between siblings. J Clin Virol. 58(1):288–291. 10.1016/j.jcv.2013.06.004 23829968
Mesri EA, Feitelson MA, Munger K. 2014. Human viral oncogenesis: A cancer hallmarks analysis. Cell Host Microbe. 15(3):266–282. 10.1016/j.chom.2014.02.011 24629334
Miner AG, Patel RM, Wilson DA, Procop GW, Minca EC, Fullen DR, Harms PW, Billings SD. 2015. Cytokeratin 20-negative Merkel cell carcinoma is infrequently associated with the Merkel cell polyomavirus. Mod Pathol. 28(4):498–504. 10.1038/modpathol.2014.148 25394777
Moens U, Rasheed K, Abdulsalam I, Sveinbjornsson B. 2015. The role of Merkel cell polyomavirus and other human polyomaviruses in emerging hallmarks of cancer. Viruses. 7(4):1871–1901. 10.3390/v7041871 25866902
Mogha A, Fautrel A, Mouchet N, Guo N, Corre S, Adamski H, Watier E, Misery L, Galibert MD. 2010. Merkel cell polyomavirus small T antigen mRNA level is increased following in vivo UV-radiation. PLoS One. 5(7):e11423. 10.1371/journal.pone.0011423 20625394
Moore PS, Chang Y. 2014. The conundrum of causality in tumor virology: The cases of KSHV and MCV. Semin Cancer Biol. 26:4–12. 10.1016/j.semcancer.2013.11.001 24304907
Moore PS, Chang YA. 2010. Why do viruses cause cancer? Highlights of the first century of human tumour virology. Nat Rev Cancer. 10(12):878–889. 10.1038/nrc2961 21102637
Mouchet N, Coquart N, Lebonvallet N, Le Gall-Ianotto C, Mogha A, Fautrel A, Boulais N, Dreno B, Martin L, Hu W, et al. 2014. Comparative transcriptional profiling of human Merkel cells and Merkel cell carcinoma. Exp Dermatol. 23(12):928–930. 10.1111/exd.12546 25236165
National Toxicology Program (NTP). 2015. Handbook for preparing the report on carcinogens monographs. Research Triangle Park, NC: National Toxicology Program. https://ntp.niehs.nih.gov/ntp/roc/handbook/roc_handbook_508.pdf.
Niller HH, Wolf H, Minarovits J. 2011. Viral hit and run-oncogenesis: Genetic and epigenetic scenarios. Cancer Lett. 305(2):200–217. 10.1016/j.canlet.2010.08.007 20813452
Ota S, Ishikawa S, Takazawa Y, Goto A, Fujii T, Ohashi K, Fukayama M. 2012. Quantitative analysis of viral load per haploid genome revealed the different biological features of Merkel cell polyomavirus infection in skin tumor. PLoS One. 7(6):e39954. 10.1371/journal.pone.0039954 22768181
Pastrana DV, Tolstov YL, Becker JC, Moore PS, Chang Y, Buck CB. 2009. Quantitation of human seroresponsiveness to Merkel cell polyomavirus. PLoS Pathog. 5(9):e1000578. 10.1371/journal.ppat.1000578 19750217
Pastrana DV, Wieland U, Silling S, Buck CB, Pfister H. 2012. Positive correlation between Merkel cell polyomavirus viral load and capsid-specific antibody titer. Med Microbiol Immunol (Berl). 201(1):17–23. 10.1007/s00430-011-0200-7 21614514
Paulson KG, Carter JJ, Johnson LG, Cahill KW, Iyer JG, Schrama D, Becker JC, Madeleine MM, Nghiem P, Galloway DA. 2010. Antibodies to Merkel cell polyomavirus T antigen oncoproteins reflect tumor burden in Merkel cell carcinoma patients. Cancer Res. 70(21):8388–8397. 10.1158/0008-5472.CAN-10-2128 20959478
Peretti A, Borgogna C, Rossi D, De Paoli L, Bawadekar M, Zavattaro E, Boldorini R, De Andrea M, Gaidano G, Gariglio M. 2014. Analysis of human β-papillomavirus and Merkel cell polyomavirus infection in skin lesions and eyebrow hair bulbs from a cohort of patients with chronic lymphocytic leukaemia. Br J Dermatol. 171(6):1525–1528. 10.1111/bjd.13215 24976446
Polesel J, Gheit T, Talamini R, Shahzad N, Lenardon O, Sylla B, La Vecchia C, Serraino D, Tommasino M, Franceschi S. 2012. Urinary human polyomavirus and papillomavirus infection and bladder cancer risk. Br J Cancer. 106(1):222–226. 10.1038/bjc.2011.519 22116302
Popp S, Waltering S, Herbst C, Moll I, Boukamp P. 2002. UV-B-type mutations and chromosomal imbalances indicate common pathways for the development of Merkel and skin squamous cell carcinomas. Int J Cancer. 99(3):352–360. 10.1002/ijc.10321 11992403
Robles C, Casabonne D, Benavente Y, Costas L, Gonzalez-Barca E, Aymerich M, Campo E, Tardon A, Jiménez-Moleón JJ, Castaño-Vinyals G, et al. 2015. Seroreactivity against Merkel cell polyomavirus and other polyomaviruses in chronic lymphocytic leukaemia, the MCC-Spain study. J Gen Virol. 96(8):2286–2292. 10.1099/vir.0.000167 25920529
Robles C, Poloczek A, Casabonne D, Gonzalez-Barca E, Bosch R, Benavente Y, Viscidi RP, de Sanjose S. 2012. Antibody response to Merkel cell polyomavirus associated with incident lymphoma in the Epilymph case-control study in Spain. Cancer Epidemiol Biomarkers Prev. 21(9):1592–1598. 10.1158/1055-9965.EPI-11-1140 22781028
Robles C, Viscidi R, Malats N, Silverman DT, Tardon A, Garcia-Closas R, Serra C, Carrato A, Herranz J, Lloreta J, et al. 2013. Bladder cancer and seroreactivity to BK, JC and Merkel cell polyomaviruses: The Spanish Bladder Cancer Study. Int J Cancer. 133(3):597–603. 10.1002/ijc.28053 23355322
Rodig SJ, Cheng J, Wardzala J, DoRosario A, Scanlon JJ, Laga AC, Martinez-Fernandez A, Barletta JA, Bellizzi AM, Sadasivam S, et al. 2012. Improved detection suggests all Merkel cell carcinomas harbor Merkel polyomavirus. J Clin Invest. 122(12):4645–4653. 10.1172/JCI64116 23114601
Rollison DE, Giuliano AR, Messina JL, Fenske NA, Cherpelis BS, Sondak VK, Roetzheim RG, Iannacone MR, Michael KM, Gheit T, et al. 2012. Case-control study of Merkel cell polyomavirus infection and cutaneous squamous cell carcinoma. Cancer Epidemiol Biomarkers Prev. 21(1):74–81. 10.1158/1055-9965.EPI-11-0764 22016472
Rothman KJ, Greenland S. 2005. Causation and causal inference in epidemiology. Am J Public Health. 95 Suppl 1:S144–S150. 10.2105/AJPH.2004.059204 16030331
Sahi H, Koljonen V, Kavola H, Haglund C, Tukiainen E, Sihto H, Bohling T. 2012. Bcl-2 expression indicates better prognosis of Merkel cell carcinoma regardless of the presence of Merkel cell polyomavirus. Virchows Arch. 461(5):553–559. 10.1007/s00428-012-1310-3 22976527
Sahi H, Savola S, Sihto H, Koljonen V, Bohling T, Knuutila S. 2014. RB1 gene in Merkel cell carcinoma: Hypermethylation in all tumors and concurrent heterozygous deletions in the polyomavirus-negative subgroup. APMIS. 122(12):1157–1166. 10.1111/apm.12274 24735260
Samimi M, Gardair C, Nicol JT, Arnold F, Touze A, Coursaget P. 2015. Merkel cell polyomavirus in Merkel cell carcinoma: Clinical and therapeutic perspectives. Semin Oncol. 42(2):347–358. 10.1053/j.seminoncol.2014.12.021 25843739
Santos-Juanes J, Fernandez-Vega I, Fuentes N, Galache C, Coto-Segura P, Vivanco B, Astudillo A, Martinez-Camblor P. 2015. Merkel cell carcinoma and Merkel cell polyomavirus: A systematic review and meta-analysis. Br J Dermatol. 173(1):42–49. 10.1111/bjd.13870 25919492
Schlagbauer-Wadl H, Klosner G, Heere-Ress E, Waltering S, Moll I, Wolff K, Pehamberger H, Jansen B. 2000. Bcl-2 antisense oligonucleotides (G3139) inhibit Merkel cell carcinoma growth in SCID mice. J Invest Dermatol. 114(4):725–730. 10.1046/j.1523-1747.2000.00937.x 10733680
Schmitt M, Wieland U, Kreuter A, Pawlita M. 2012. C-terminal deletions of Merkel cell polyomavirus large T-antigen, a highly specific surrogate marker for virally induced malignancy. Int J Cancer. 131(12):2863–2868. 10.1002/ijc.27607 22674148
Schowalter RM, Pastrana DV, Pumphrey KA, Moyer AL, Buck CB. 2010. Merkel cell polyomavirus and two previously unknown polyomaviruses are chronically shed from human skin. Cell Host Microbe. 7(6):509–515. 10.1016/j.chom.2010.05.006 20542254
Schrama D, Ugurel S, Becker JC. 2012. Merkel cell carcinoma: Recent insights and new treatment options. Curr Opin Oncol. 24(2):141–149. 10.1097/CCO.0b013e32834fc9fe 22234254
Seo GJ, Chen CJ, Sullivan CS. 2009. Merkel cell polyomavirus encodes a microRNA with the ability to autoregulate viral gene expression. Virology. 383(2):183–187. 10.1016/j.virol.2008.11.001 19046593
Shahzad N, Shuda M, Gheit T, Kwun HJ, Cornet I, Saidj D, Zannetti C, Hasan U, Chang Y, Moore PS, et al. 2013. The T antigen locus of Merkel cell polyomavirus downregulates human Toll-like receptor 9 expression. J Virol. 87(23):13009–13019. 10.1128/JVI.01786-13 24067965
Shuda M, Arora R, Kwun HJ, Feng H, Sarid R, Fernandez-Figueras MT, Tolstov Y, Gjoerup O, Mansukhani MM, Swerdlow SH, et al. 2009. Human Merkel cell polyomavirus infection I. MCV T antigen expression in Merkel cell carcinoma, lymphoid tissues and lymphoid tumors. Int J Cancer. 125(6):1243–1249. 10.1002/ijc.24510 19499546
Shuda M, Feng H, Kwun HJ, Rosen ST, Gjoerup O, Moore PS, Chang Y. 2008. T antigen mutations are a human tumor-specific signature for Merkel cell polyomavirus. Proc Natl Acad Sci USA. 105(42):16272–16277. 10.1073/pnas.0806526105 18812503
Shuda M, Kwun HJ, Feng H, Chang Y, Moore PS. 2011. Human Merkel cell polyomavirus small T antigen is an oncoprotein targeting the 4E-BP1 translation regulator. J Clin Invest. 121(9):3623–3634. 10.1172/JCI46323 21841310
Shuda M, Velasquez C, Cheng E, Cordek DG, Kwun HJ, Chang Y, Moore PS. 2015. CDK1 substitutes for mTOR kinase to activate mitotic cap-dependent protein translation. Proc Natl Acad Sci USA. 112(19):5875–5882. 10.1073/pnas.1505787112 25883264
Sihto H, Kukko H, Koljonen V, Sankila R, Bohling T, Joensuu H. 2009. Clinical factors associated with Merkel cell polyomavirus infection in Merkel cell carcinoma. J Natl Cancer Inst. 101(13):938–945. 10.1093/jnci/djp139 19535775
Sihto H, Kukko H, Koljonen V, Sankila R, Bohling T, Joensuu H. 2011. Merkel cell polyomavirus infection, large T antigen, retinoblastoma protein and outcome in Merkel cell carcinoma. Clin Cancer Res. 17(14):4806–4813. 10.1158/1078-0432.CCR-10-3363 21642382
Sitas F, Egger S, Urban MI, Taylor PR, Abnet CC, Boffetta P, O’Connell DL, Whiteman DC, Brennan P, Malekzadeh R, et al. 2012. InterSCOPE study: Associations between esophageal squamous cell carcinoma and human papillomavirus serological markers. J Natl Cancer Inst. 104(2):147–158. 10.1093/jnci/djr499 22228147
Spurgeon ME, Cheng J, Bronson RT, Lambert PF, DeCaprio JA. 2015. Tumorigenic activity of Merkel cell polyomavirus T antigens expressed in the stratified epithelium of mice. Cancer Res. 75(6):1068–1079. 10.1158/0008-5472.CAN-14-2425 25596282
Spurgeon ME, Lambert PF. 2013. Merkel cell polyomavirus: A newly discovered human virus with oncogenic potential. Virology. 435(1):118–130. 10.1016/j.virol.2012.09.029 23217622
Stakaitytė G, Wood JJ, Knight LM, Abdul-Sada H, Adzahar NS, Nwogu N, Macdonald A, Whitehouse A. 2014. Merkel cell polyomavirus: Molecular insights into the most recently discovered human tumour virus. Cancers (Basel). 6(3):1267–1297. 10.3390/cancers6031267 24978434
Swick BL, Ravdel L, Fitzpatrick JE, Robinson WA. 2008. Platelet-derived growth factor receptor alpha mutational status and immunohistochemical expression in Merkel cell carcinoma: Implications for treatment with imatinib mesylate. J Cutan Pathol. 35(2):197–202. 18190445
Teman CJ, Tripp SR, Perkins SL, Duncavage EJ. 2011. Merkel cell polyomavirus (MCPyV) in chronic lymphocytic leukemia/small lymphocytic lymphoma. Leuk Res. 35(5):689–692. 10.1016/j.leukres.2011.01.032 21414663
Teras LR, Rollison DE, Pawlita M, Michel A, Blase JL, Willhauck-Fleckenstein M, Gapstur SM. 2015. Prediagnostic circulating polyomavirus antibody levels and risk of non-Hodgkin lymphoma. Cancer Epidemiol Biomarkers Prev. 24(2):477–480. 10.1158/1055-9965.EPI-14-1125 25488906
Tolstov YL, Arora R, Scudiere SC, Busam K, Chaudhary PM, Chang Y, Moore PS. 2010. Lack of evidence for direct involvement of Merkel cell polyomavirus (MCV) in chronic lymphocytic leukemia (CLL). Blood. 115(23):4973–4974. 10.1182/blood-2010-03-273177 20538816
Tolstov YL, Knauer A, Chen JG, Kensler TW, Kingsley LA, Moore PS, Chang Y. 2011. Asymptomatic primary Merkel cell polyomavirus infection among adults. Emerg Infect Dis. 17(8):1371–1380. 10.3201/eid1708.110079 21801612
Tolstov YL, Pastrana DV, Feng H, Becker JC, Jenkins FJ, Moschos S, Chang Y, Buck CB, Moore PS. 2009. Human Merkel cell polyomavirus infection II. MCV is a common human infection that can be detected by conformational capsid epitope immunoassays. Int J Cancer. 125(6):1250–1256. 10.1002/ijc.24509 19499548
U.S. Food and Drug Administration (FDA). 2015. Complete list of vaccines licensed for immunization and distribution in the US. U.S. Food and Drug Administration. https://www.fda.gov/BiologicsBloodVaccines/Vaccines/ApprovedProducts/ucm093833.htm. [Accessed on 6/22/15]
Van Gele M, Kaghad M, Leonard JH, Van Roy N, Naeyaert JM, Geerts ML, Van Belle S, Cocquyt V, Bridge J, Sciot R, et al. 2000. Mutation analysis of P73 and TP53 in Merkel cell carcinoma. Br J Cancer. 82(4):823–826. 10.1054/bjoc.1999.1006 10732753
Van Gele M, Leonard JH, Van Roy N, Cook AL, De Paepe A, Speleman F. 2001. Frequent allelic loss at 10q23 but low incidence of PTEN mutations in Merkel cell carcinoma. Int J Cancer. 92(3):409–413. 10.1002/ijc.1209 11291079
Van Gele M, Speleman F, Vandesompele J, Van Roy N, Leonard JH. 1998. Characteristic pattern of chromosomal gains and losses in Merkel cell carcinoma detected by comparative genomic hybridization. Cancer Res. 58(7):1503–1508. 9537255
Verhaegen ME, Mangelberger D, Harms PW, Vozheiko TD, Weick JW, Wilbert DM, Saunders TL, Ermilov AN, Bichakjian CK, Johnson TM, et al. 2015. Merkel cell polyomavirus small T antigen is oncogenic in transgenic mice. J Invest Dermatol. 135(5):1415–1424. 10.1038/jid.2014.446 25313532
Viscidi RP, Rollison DE, Sondak VK, Silver B, Messina JL, Giuliano AR, Fulp W, Ajidahun A, Rivanera D. 2011. Age-specific seroprevalence of Merkel cell polyomavirus, BK virus, and JC virus. Clin Vaccine Immunol. 18(10):1737–1743. 10.1128/CVI.05175-11 21880855
Wetzels CT, Hoefnagel JG, Bakkers JM, Dijkman HB, Blokx WA, Melchers WJ. 2009. Ultrastructural proof of polyomavirus in Merkel cell carcinoma tumour cells and its absence in small cell carcinoma of the lung. PLoS One. 4(3):e4958. 10.1371/journal.pone.0004958 19305499
White MK, Pagano JS, Khalili K. 2014. Viruses and human cancers: A long road of discovery of molecular paradigms. Clin Microbiol Rev. 27(3):463–481. 10.1128/CMR.00124-13 24982317
Wieland U, Kreuter A. 2011. Merkel cell polyomavirus infection and Merkel cell carcinoma in HIV-positive individuals. Curr Opin Oncol. 23(5):488–493. 10.1097/CCO.0b013e3283495a5b 21734578
Xie H, Lee L, Caramuta S, Hoog A, Browaldh N, Bjornhagen V, Larsson C, Lui WO. 2014. MicroRNA expression patterns related to merkel cell polyomavirus infection in human Merkel cell carcinoma. J Invest Dermatol. 134(2):507–517. 10.1038/jid.2013.355 23962809
Xu GJ, Kula T, Xu Q, Li MZ, Vernon SD, Ndung'u T, Ruxrungtham K, Sanchez J, Brander C, Chung RT et al. 2015. Viral immunology. Comprehensive serological profiling of human populations using a synthetic human virome. Science. 348(6239):aaa0698. 10.1126/science.aaa0698 26045439
Yamasaki L. 2003. Role of the RB tumor suppressor in cancer. Cancer Treat Res. 115:209–239. 10.1007/0-306-48158-8_9
Zeng Q, Gomez BP, Viscidi RP, Peng S, He L, Ma B, Wu TC, Hung CF. 2012. Development of a DNA vaccine targeting Merkel cell polyomavirus. Vaccine. 30(7):1322–1329. 10.1016/j.vaccine.2011.12.072 22210138
Zhang C, Liu F, He Z, Deng Q, Pan Y, Liu Y, Zhang C, Ning T, Guo C, Liang Y, et al. 2014. Seroprevalence of Merkel cell polyomavirus in the general rural population of Anyang, China. PLoS One. 9(9):e106430. 10.1371/journal.pone.0106430 25184447
zur Hausen H. 1994. Molecular pathogenesis of cancer of the cervix and its causation by specific human papillomavirus types. Curr Top Microbiol Immunol. 186:131–156. 10.1007/978-3-642-78487-3_8 8205839
zur Hausen H. 2001. Oncogenic DNA viruses. Oncogene. 20(54):7820–7823. 10.1038/sj.onc.1204958 11753664
zur Hausen H, de Villiers EM. 2014. Cancer “causation” by infections—individual contributions and synergistic networks. Semin Oncol. 41(6):860–875. 10.1053/j.seminoncol.2014.10.003 25499643