# Appendix A Literature Search Strategy

The objective of the literature search approach is to identify published literature that is relevant for evaluating the potential carcinogenicity of the Merkel cell polyomavirus (MCV). As discussed in the Viruses Concept Document (https://ntp.niehs.nih.gov/ntp/roc/concept_docs/2014/virusesconcept_508.pdf), the monograph relies on the IARC monograph and studies published since the monograph (new studies). The literature search strategy was used to identify new human cancer studies and recent reviews of mechanistic data.

## A.1 General Approach

Database searching encompasses selecting databases and search terms and conducting the searches. Searches of several citation databases are generally conducted using search terms for the individual viruses of interest, combined with search terms for cancer and/or specific topics, including epidemiological and mechanistic studies. A critical step in the process involves consultation with an information specialist to develop relevant search terms. These terms are used to search bibliographic databases. IARC used literature found by searching PubMed for MCV through 2012. Because the body of literature for this virus was small, PubMed, Web of Science and Scopus were searched for any information about MCV without date limitations up to August 2015. Table A-1 highlights the general concepts searched with selected example terms. To review all the terms used, please refer to the full search strings below.

Table A-1 Major Topics Searched

Topics | Example Terms
Merkel cell polyomavirus | Merkel cell polyomavirus, Merkel cell virus, Merkel cell carcinoma

The literature for MCV was searched without using narrowing terms within the bibliographic databases. The results were then processed in EndNote to remove duplicates before being transferred to DistillerSR for screening.

Figure A-1

Literature Processing Flow

The bibliographic database search results (1869) were processed in Endnote then imported into DistillerSR for first and second tier screening. Relevant studies found through the citations of review articles and other secondary searched were also included. Tagging in DistillerSR categorized the useful articles into Human Epidemiologic literature (119) or Mechanistic literature (199).

## A.2 Search Strings for MCV Searches

[underlined: PubMed, Scopus and WOS]

“Merkel cell polyomavirus” OR “Merkel cell virus” OR “Merkel cell carcinoma” AND (polyomavirus OR virus)