# 5 Overall Cancer Hazard Evaluation and Listing Recommendation

Kaposi sarcoma-associated virus (KSHV) is known to be a human carcinogen based on sufficient evidence from studies in humans. This conclusion is based on epidemiological and molecular studies showing that it causes Kaposi sarcoma (Table 5-1) primary effusion lymphoma (Table 5-2), and a plasmablastic variant of multicentric Castleman disease (Table 5-3) in humans, together with supporting evidence from mechanistic studies demonstrating the biological plausibility of its carcinogenicity in humans.

Table 5-1 Summary of the evidence for KSHV and Kaposi sarcoma from human studies

Types of Studies | Kaposi Sarcoma
Epidemiological
Positive associations | 39/39^a^ case-control studies (all ORs > 1.0) and all 16^a^ cohort/nested case-control studies; ORs/RRs for all studies are mostly statistically significant and some very high (10 to >100-fold) Elevated RR in both HIV-1-negative and HIV-1-positive populations and in all types of Kaposi sarcoma Dose response in several studies
Molecular (human tissue)
Clonality | Mono- or oligoclonal
% KSHV-infected tumors | >99% (~1 copy/cell)
KSHV protein expression^b^
Latent | LANA, vCyclin, vFLIP, kaposin A and B
Lytic | RTA, K1, vIRFs, vIL-6, vGPCR, vCCLs, K15
Level of evidence | Sufficient

HIV-1 = human immunodeficiency virus type 1; K1 = unique KSHV protein 1; K15 = unique KSHV protein 15; KSHV = Kaposi sarcoma-associated herpes virus; LANA = latency-associated nuclear antigen; OR = odds ratio; RR = risk ratio; RTA = replication and transactivation protein; vCCLs = viral-encoded chemokines; vFLIP = viral FLICE-inhibitory protein; vGPCR = viral G protein-coupled receptor; vIL-6 = viral homolog of interleukin-6; vIRF = viral interferon regulatory factors.

^a^ The number of studies is based on those reporting risk estimates.

^b^ See Section 4.1.2 for more details.

Table 5-2 Summary of the Evidence for KSHV and Primary Effusion Lymphoma from Human Studies

Types of Studies | Primary Effusion Lymphoma (PEL)
Epidemiological
Positive associations | Found in over 115 cases; at least 95 individual case reports and case-series studies and 21 cases in one comparison study PEL is a single distinct pathological entity Found in both HIV-1-negative and -positive cases and in transplant patients Approximately 50% cases also have Kaposi sarcoma; some PEL cases found in geographical regions associated with endemic or classic Kaposi sarcoma
Molecular (human tissue)
Clonality | Monoclonal
% KSHV-infected tumors | 100% (high copy number); cell lines established from PEL tumors retain a stable latent viral genome
KSHV protein expression | Similar to Kaposi sarcoma
Other | KSHV is part of diagnostic criteria Expression of KSHV viral genes was required for survival of PEL cells in culture
Level of evidence | Sufficient

HIV-1 = human immunodeficiency virus type 1; KSHV = Kaposi sarcoma-associated herpesvirus; PEL = primary effusion lymphoma.

Table 5-3 Summary of the Evidence for KSHV and Multicentric Castleman Disease from Human Studies

Types of Studies | Multicentric Castleman Disease (MCD)
Epidemiological
Positive associations | Found in most cases of MCD (plasmablastic variant) in several case series studies; 4/4 case comparison studies; very high ORs or no cases of KSHV among controls
Molecular (human tissue)
Clonality | Typically polyclonal^b^
% KSHV-infected tumors | 100% of cancerous lymph nodes KSHV+ with HIV-1+ and 50% KSHV+ with HIV-1-
KSHV protein expression^a^ | LANA, vIL-6
Level of evidence | Sufficient (plasmablastic variant)

HIV-1 = human immunodeficiency virus type 1; KSHV = Kaposi sarcoma-associated herpesvirus; LANA = latency-associated nuclear antigen; OR = odds ratio; vIL-6 = viral homolog of interleukin-6.

^a^ Multicentric Castleman disease is associated with lytic infection.

^b^ Monoclonal B-cell expansion have been reported.

Data are inadequate to evaluate the association between KSHV and multiple myeloma, which has inconsistent evidence from epidemiological studies and no available evidence from mechanistic studies.

The following tables provide the level of evidence recommendations for the carcinogenicity of KSHV for each endpoint from studies in humans, including the key data from both epidemiological and molecular studies in humans.