# 4 Mechanistic and Other Relevant Data

KSHV-associated oncogenesis is a complex process that involves interactions among various viral, host, and environmental cofactors (Fukumoto et al. 2011; Mesri et al. 2014). Although many of the mechanisms by which KSHV is able to establish and maintain infection are known, and many KSHV-encoded proteins and their functions have been characterized in vitro, some aspects of infection and transformation are still not well understood (Fukumoto et al. 2011; Giffin and Damania 2014). This section reviews the characteristics of KSHV-associated neoplasms and risk factors (Section 4.1), evaluates the mode of action and evidence that KSHV is an oncogenic virus (Section 4.2), and provides a synthesis of the information (Section 4.3).

As discussed in Section 3, three neoplasms have been associated with KSHV in humans, although the level of evidence for each endpoint varies: (1) Kaposi sarcoma, (2) primary effusion lymphoma, and (3) a plasmablastic variant of multicentric Castleman disease. These cancers occur most frequently in the context of immunosuppression and are the focus of this section (Giffin and Damania 2014; Mesri et al. 2014). Although other lymphohematopoietic neoplasms and several solid tumor sites (see Section 3) have been investigated, the available data were insufficient to establish a causal relationship with KSHV and are not discussed in this section.

## 4.1 Characteristics and Risk Factors

Some basic characteristics of the neoplasms associated with KSHV are shown in Table 4-1. The epidemiological data reviewed in Section 3 indicated that human immunodeficiency virus type 1 infection and immunosuppression are important host-related cofactors that increase the risk of developing KSHV-associated neoplasms. However, it is also clear that not all host and environmental cofactors have been identified. Further, KSHV latent and lytic transcripts include genes and non-coding RNAs that promote acquisition of various cancer hallmarks (e.g., insensitivity to antigrowth signals, avoiding cell-cycle arrest, immune evasion, genetic instability, cell proliferation, resisting apoptosis, and angiogenesis) (Mesri et al. 2014). This section reviews the role of immunosuppression, viral proteins, and non-coding RNAs, and other possible cofactors in KSHV-induced neoplasms.

Table 4-1 Characteristics of KSHV-associated Neoplasms

Neoplasm | Presentation | Lineage and Primary Tumor Cell | Clonality | KSHV Genomes
KS | Highly angiogenic lesions found on skin, visceral organs, or mucosal surfaces; leaky vasculature | Endothelial cell origin; tumor cells are spindle cells with mixed blood and lymphatic endothelial cell markers | Oligoclonal or monoclonal | >99% of tumor cells contain single copy of KSHV genome
PEL | Non-Hodgkin lymphoma; B-cell expansion (usually serous effusion without detectable tumor masses) in body cavity | B cells; CD20−; markers resemble partially differentiated plasma cells | Monoclonal | Tumor cells contain 50 to 100 copies of KSHV genome
MCD | Plasmablastic variant; disseminated lymphadenopathy | B cell; IgM γ-restricted plasmablasts | Typically polyclonal | Unknown, detected in most HIV-1+ MCD cases

Source: Adapted from Giffin and Damania (2014).

KS = Kaposi sarcoma; MCD = multicentric Castleman disease; PEL = primary effusion lymphoma.

### 4.1.1 Human Immunodeficiency Virus Type 1 and Immunosuppression

Although KSHV encodes oncogenic genes that could potentially induce all Kaposi sarcoma phenotypes, the risk of malignancy is greatly enhanced in the presence of cofactors, particularly immunosuppression by human immunodeficiency virus type 1 or iatrogenically during organ transplantation (Mesri et al. 2010). The importance of human immunodeficiency virus type 1 infection as a potent cofactor for KSHV oncogenesis is demonstrated by the dramatic increase in Kaposi sarcoma incidence in human immunodeficiency virus type 1-infected individuals (see Section 3). The risk for developing Kaposi sarcoma is strongly associated with defects in both cellular and humoral immunity. Decreasing CD4 cell counts are associated with an increasing risk of Kaposi sarcoma in both AIDS-associated and classic Kaposi sarcoma cases; however, human immunodeficiency virus type 1-infected individuals with higher CD4 counts are also developing Kaposi sarcoma as they age (Krown et al. 2008). Decreased CD19 cell counts are also associated with an increased risk of Kaposi sarcoma in human immunodeficiency virus type 1-positive and human immunodeficiency virus type 1-negative individuals (Uldrick and Whitby 2011). Iatrogenic immunosuppression also is associated with an increased risk (primarily in kidney allograft patients), but it is not nearly as great as that seen with human immunodeficiency virus type 1 infection (Mesri et al. 2010). This also may reflect differences in KSHV infection rates rather than human immunodeficiency virus type 1-specific causes, or differences in immune dysfunction. Further, human immunodeficiency virus type 1 infection causes changes in cytokine profiles and produces several viral proteins (human immunodeficiency virus type 1 transactivating protein [tat], human immunodeficiency virus type 1 negative factor protein [Nef]) that may be potent cofactors that can activate KSHV lytic replication and influence pathogenesis (Mesri et al. 2014; Purushothaman et al. 2015; Zhu et al. 2014). The biological basis for the role of immunosuppression in KSHV oncogenesis also involves the interactions of latent and lytic infection and is discussed in the following sections.

### 4.1.2 KSHV Transcripts

The KSHV genome contains 87 open reading frames including many genes found in other herpesviruses, several unique open reading frames (designated K1 to K15) not found in other herpesviruses, and at least 14 viral genes that are homologues of human cellular genes (Mesri et al. 2010; Wen and Damania 2010). Viral transcripts dysregulate several cellular signaling pathways including those involved in cell-cycle progression (e.g., vCyclin, LANA), angiogenesis (e.g., LANA, K1, vCCL, vGPCR, vIL6), apoptosis (e.g., LANA, K1, vFLIP, vBCL-2), immune modulation/evasion (e.g., vFLIP, K3, K5, vIRFs), signal transduction (e.g., K1, K15), and antiviral responses (IARC 2012; Mesri et al. 2010; Wen and Damania 2010). While latent infection is dominant in KSHV-infected cells in vivo and in vitro, both latent and lytic genes contribute to the malignant phenotype (Fukumoto et al. 2011; Mesri et al. 2010). Viral transcription profiling identified significant differences in the degree of KSHV transcription in human immunodeficiency virus type 1-infected Kaposi sarcoma patients that had not received antiviral treatment and/or chemotherapy (Hosseinipour et al. 2014). Two primary subtypes of Kaposi sarcoma transcriptional signatures were identified: (1) lesions that displayed only a latent transcription pattern (i.e., LANA, vCyclin, vFLIP, miRNAs), and (2) lesions that exhibited extended but incomplete viral RNA transcription (e.g., vIRFs, K1, K15, Orf21/thymidine kinase, Orf36/protein kinase, and others). Only one sample exhibited a complete lytic transcription profile. The data demonstrate multiple subtypes of Kaposi sarcoma lesions and is consistent with other studies reporting similar “extended” KSHV transcripts under conditions of incomplete or abortive replication (discussed below).

A large portion of the KSHV genome is devoted toward evading the innate immune response of the host (e.g., interferon production, interferon regulatory factor activation, NK cell activity, complement activation, inflammasome activation, and chemokine activity), thus facilitating life-long infection (Fukumoto et al. 2011; Giffin and Damania 2014). In addition, KSHV evades adaptive immune responses by repressing viral antigen presentation, T-cell activation, BCR-mediated B-cell activation and B-cell differentiation (Giffin and Damania 2014). Professional antigen-presenting cells, including B cells, dendritic cells, and macrophages, are primary targets for KSHV infection (Campbell et al. 2014a; Knowlton et al. 2013). Cytokine profiles, surface expression of major histocompatibility complex (MHC) molecules, and T-cell activation are altered in infected antigen-presenting cells. This likely explains why T-cell responses to KSHV antigens are not very robust. Both complete and abortive virus replication cycles in antigen-presenting cells (APCs) can affect viral pathogenesis and progression to Kaposi sarcoma and B-cell cancers. Host cell transformation and oncogenesis are thought to result inadvertently from the survival mechanisms used by KSHV and other oncogenic viruses (Wen and Damania 2010).

In an immune-compromised host, lytic infected cells escape immunosurveillance and are able to express the full oncogenic repertoire, including genes that induce angiogenesis and inflammation (Cavallin et al. 2014; Mesri et al. 2014). In addition, some latently infected cells also express some of the early lytic genes but do not complete the lytic cycle. These cells may become progressively transformed and acquire oncogenic alterations that allow them to switch back to a less immunogenic latent form. Latent proteins and miRNAs play an important role in KSHV-associated neoplasms through inhibition of apoptosis and maintenance of latency while KSHV lytic proteins mimic or disrupt host cytokine signals, resulting in microenvironments that promote tumor growth through mechanisms called “paracrine neoplasia” (Cavallin et al. 2014; Fukumoto et al. 2011; Mesri et al. 2010). This section briefly reviews the role of latent proteins, lytic proteins, non-coding RNAs, and their interactions in KSHV pathogenesis.

#### Latent Proteins

Latent KSHV infection is characterized by a circularized, extra-chromosomal viral genome (episome) that is tethered to the host chromosomes by latency-associated nuclear antigen (LANA) (Giffin and Damania 2014). All KSHV-infected cells express LANA, and antibody-based detection methods are the most powerful tool for diagnosis of pathological samples of KSHV infection (Fukumoto et al. 2011). Only a small portion of the viral genome is actively transcribed during latency and no functional or infectious viral particles are produced (Giffin and Damania 2014). LANA is the most consistently detected viral protein in KSHV-associated tumor cells and is necessary for replicating the episomal viral DNA (IARC 2012). In addition to LANA, latent transcripts include vCyclin, viral FLICE-inhibitory protein (vFLIP), kaposin A and B, viral interferon regulatory factor 3 (vIRF-3, also known as LANA-2) (expressed in primary effusion lymphoma and multicentric Castleman disease cells but not in Kaposi sarcoma) and viral miRNAs. Although the primary function of LANA is to maintain the viral episome, it also interferes with several anti-tumorigenic pathways, including p53 and anti-proliferative transforming growth factor-β (TGFβ), and might contribute to angiogenesis by stabilizing hypoxia-inducible factor-1α (HIF-1α) and by targeting von Hippel Lindau for degradation (Mesri et al. 2010). Recent evidence also suggests that caspase cleavage sites in LANA have an important role in delaying apoptosis and blunting the caspase-1-mediated inflammasome, thus inhibiting key cellular defense mechanisms (Davis et al. 2015). vCyclin is a constitutive activator of cyclin-dependent kinase 6 (CDK6), a gene that is overexpressed in lymphomas and leukemias, induces cytokinesis defects and polyploidy, and promotes viral replication (Kollmann et al. 2013; Mesri et al. 2010). vFLIP and kaposin A and B contribute to the inflammatory microenvironment. Thus, these transcripts are associated with growth and proliferative signals, evasion of apoptosis, angiogenic and inflammatory signals, and a limitless replicative potential that support tumor growth and progression (Mesri et al. 2010). Transgenic mice expressing some or all of the KSHV latency genes develop phenotypes characteristic of KSHV malignancies (e.g., B-cell hyperplasia and lymphoma) (Fakhari et al. 2006; Sin and Dittmer 2013). Some biochemical and biological properties, including their role in carcinogenesis, of KSHV latent proteins are shown in Table 4-2.

Table 4-2 Biochemical and Biological Properties of Latent KSHV Proteins

KSHV Gene/Protein | Function in Viral Life Cycle | Homology to Human Protein | Biochemical Properties | Role in Carcinogenesis
ORF 73/LANA | Replication and maintenance of latent viral episome; partition of episomes to daughter cells | None | Interacts with histones, pRB, BET proteins, GSK-3β and others; inactivates p53-dependent transcriptional activation; induces S-phase entry and activates hTERT transcription; recruits origin-binding proteins | Anti-apoptotic activity, cell survival, deregulation of cell cycle, enhances ras-mediated transforming properties in vitro, tumorigenic in transgenic mice
ORF 71, K13/ vFLIP | Viral persistence; spindle cell formation and lymphomagenesis; inhibition of lytic viral replication | FLICE (caspase-8)-inhibitory proteins | Activates NF-κB; inhibits CD95/Fas-induced apoptosis, anoikis, superoxide-induced cell death; modulates MHC-1 expression | Anti-apoptotic activity, cell survival, immune evasion
ORF 72/vCYC | Viral cyclin; strongly activates CDK6 protein kinase activity | D-type cyclin | Phosphorylates H1, pRB, BCL-2, p27^KIP1^ in tandem with CDK6 | Deregulation of cell cycle
K12/Kaposin A^a^, Kaposin B^a^ | Modulation of cytokine mRNAs regulated by the p38 pathway | None | Interacts with cytohesin-1 Modulates p38/MK2 | Transforming properties in cultured cells
K10.5/vIRF3, LANA-2^b^ | Modulates viral interferon response | Interferon regulatory factor | Modulates p53 function; activates IRF-3, IRF-7, c-myc; inhibits IRF-5 | Anti-apoptotic activity, immune evasion, cell survival
K15/K15 protein^b^ | Recruits endothelial cells to infected cells | None | Activates NF-κB, MEK/Erk; induces inflammatory cytokines; interacts with proteins involved in signal transduction, with members of src family of PTK, and with an apoptotic regulatory protein HAX-1 | Possible anti-apoptotic and angiogenic activity

Source: IARC (2012).

BET = bromodomain and extra-terminal; CDK6 = cyclin-dependent kinase 6; FLICE = FADD-like interleukin-1 beta-converting enzyme; HAX-1 = HS1-associated protein X1; hTERT = human telomerase reverse transcriptase; IRF = interferon regulatory factor; LANA = latency associated nuclear antigen; MHC = major histocompatibility complex; NF- κB = nuclear factor kappa-light-chain-enhancer of activated B cells; pRB = retinoblastoma protein; PTK = protein tyrosine kinase; vCYC = viral cyclin; vIRF3 = viral interferon regulatory factor-3.

^a^ Expression increases after activation of the lytic cycle.

^b^ Lytic in endothelial cells; latent in B cells.

#### Lytic KSHV Proteins

The lytic cycle is characterized by expression of all viral transcripts in an orchestrated temporal order, replication of the viral genome, viral assembly, and viral egress (Wen and Damania 2010). Lytic reactivation requires expression of the replication and transcription activator (RTA) protein and is under epigenetic control (Giffin and Damania 2014; Li et al. 2014; Pantry and Medveczky 2009). RTA plays an important role as both an initiator and controller of KSHV lytic DNA replication (Purushothaman et al. 2015). Many of the lytic viral proteins, including K1, viral interferon response factors (vIRFs), vIL-6, viral-encoded chemokines (vCCLs), viral G protein-coupled receptor (vGPCR) and K15 contribute to the angiogenic and inflammatory phenotype of oncogenic lesions (Purushothaman et al. 2015; Sodhi et al. 2000). However, lytic infection generally results in cellular lysis and is unlikely to have a direct role in endothelial cell growth, transformation, or immortalization (Mesri et al. 2010). Two hypotheses (paracrine oncogenesis and abortive lytic replication) have been proposed to explain how the interactions between latent and lytic KSHV-infected cells contribute to a malignant phenotype (Bais et al. 2003; Cavallin et al. 2014; Mesri et al. 2010).

The paracrine hypothesis recognizes that host and viral growth factors can enhance latent genes and cytokines supplied by a minority of lytically infected cells or latently infected cells expressing early lytic genes (Cavallin et al. 2014; Mesri et al. 2010). Lytic genes induce a number of paracrine-acting factors such as vascular endothelial growth factor (VEGF), platelet-derived growth factor (PDGF), IL-6, angiopoietin 2 (ANGP2), and others that could drive latently infected cell proliferation, angiogenesis, and inflammation and support immune escape and survival. Experimental evidence supporting the role of lytic infection in oncogenesis include the following: (1) lytic viral proteins are expressed and virions are present in a minority of cells within Kaposi sarcoma lesions, (2) immunosuppression increases KSHV re-activation and lytic replication, (3) interruption of lytic replication by immune reconstitution or anti-lytic herpes anti-virals inhibits or prevents tumor development, (4) lytic infection is necessary to support viral episomal maintenance by recruitment of new cells to latency, and (5) endothelial cells expressing latent genes were tumorigenic in nude mice when co-injected with a few vGPCR-expressing cells (at a ratio that approximated the proportion of vGPCR-expressing and latent gene-expressing tumor cells found in human Kaposi sarcoma) but lost their tumorigenic potential in the absence of paracrine secretions from vGPCR-expressing cells (Mesri et al. 2010; Montaner et al. 2006). In addition, controlling KSHV lytic infection decreases the risk of developing Kaposi sarcoma in patients with AIDS (Uldrick and Whitby 2011) and transgenic mice expressing vGPCR develop angiogenic lesions that resemble Kaposi sarcoma (Guo et al. 2003; Yang et al. 2000).

The abortive lytic hypothesis recognizes that not all cells undergoing lytic reactivation complete the lytic cycle (i.e., abortive lytic replication). Such cells express only the oncogenic early lytic genes and can be transformed by genetic or epigenetic alterations, including vGPCR-mediated immortalization, and switch back to a less immunogenic latent status (Bais et al. 2003; Cavallin et al. 2014). Lytically infected cells can stimulate these cells through paracrine mechanisms.

Biochemical and biological properties of some KSHV lytic proteins are shown in Table 4-3.

Table 4-3 Lytic KSHV Proteins and Their Role in Carcinogenesis

KSHV Gene/Protein | Function in Viral Lifecycle | Homology to Human Protein | Biochemical Properties | Role in Carcinogenesis
K1/VIP | May increase/decrease viral reactivation | None | Activates intracellular signaling cascades; induces angiogenic cytokines; blocks intracellular transport of BCR-complexes to cell surface | Transforming properties, angiogenesis, anti-apoptotic activity
ORF 74/vGPCR | Stimulates cellular proliferation | G-protein-coupled receptor | Activates Akt, MEK/Erk, JNK, p38; induces secretion of proinflammatory cytokines and angiogenic growth factors | Transforming properties in cells, tumorigenicity in mice, angiogenesis, anti-apoptotic activity
K2/vIL6 | Viral IL6 | Interleukin-6 | Induces proliferation of PEL cell lines; induces VEGF and STAT3 phosphorylation | Tumor cell survival, angiogenesis, hematopoiesis
K3/miR-1, ZMP-B | Down modulates HLA, ICAM-1, B7-2 | None | E3 ubiquitin ligase | Immune evasion
K5/miR-2 | Down modulates HLA-A, HLA-B, ICAM-1, CD86, CD1d | Part of a family of membrane-bound-E3-ubiquitin ligases | E3 ubiquitin ligase | Immune evasion
K6/vCCL-1, vMIP-I | Viral chemokine | Chemokine homologue related to MIP-1α | CCR8 agonist; induces monocyte chemotaxis (VEGF production) | Angiogenic properties, anti-apoptotic activity
K4/vCCL-2, vMIP-II | Viral chemokine | Chemokine homologue related to macrophage inflammatory protein (MIP)-1α | CCR3, CCR5, CCR8 agonist; induces monocyte chemotaxis | Angiogenic properties
K4.1/vCCL-3, vMIP-III | Viral chemokine | Some homology to chemokines TARC and eotaxin | CCR4, XCR1 agonist | Angiogenic properties
K7/vIAP | Apoptosis inhibitor | Structurally related to a splice variant of survivin | Binds to and inhibits several proteins involved in apoptosis; induces degradation of IkB, p53, vGCR | Anti-apoptotic activity
ORF 16/vBCL-2 | Viral Bcl-2 | Bcl-2 | Heterodimerizes with human Bcl-2 | Anti-apoptotic activity
ORF 45/ORF 45 | Virion protein important for lytic replication; inhibits virus-mediated induction of type 1 interferon | None | Binds to and inhibits phosphorylation of IRF-7 | Virion infectivity, immune evasion
ORF 50/K-RTA | Immediate-early transactivator; ubiquitin E3 ligase | None | Binds to and activates several lytic viral promoters directly or by interacting with RBPJk; promotes ubiquitination and degradation of IRF-7; represses p53 | Reactivation of lytic viral replication from latency, immune evasion, anti-apoptotic activity
K8/K-bZIP | Modulates cell cycle and lytic reactivation | None | EBV Zta homologue; binds to lytic replication origin; binds to, antagonizes, and recruits p53 to ND10/PML bodies; inhibits G1/S transition; co-regulator of K-RTA | Deregulation of cell cycle
K9/vIRF-1 | Modulates viral interferon responses | Interferon regulatory factor | Prevents IRF-3-mediated transcription; inhibits p53-transcriptional activity and prevents p53-dependent apoptosis | Transformation of rodent fibroblasts, immune evasion, anti-apoptotic activity
K11/vIRF-2 | Modulates viral interferon responses | Interferon regulatory factor | Inhibits interferon induction; inhibits induction of CD95L | Immune evasion, anti-apoptotic activity
K10.5/vIRF3, LANA-2^a^ | Modulates viral interferon responses | Interferon regulatory factor | Modulates p53 function; activates IRF-3, IRF-7, c-myc; inhibits IRF-5 | Anti-apoptotic activity, immune evasion, cell survival
K15/K15 protein^a^ | Recruits endothelial cells to infected cells | None | Activates NF-κB, MEK/Erk; induces inflammatory cytokines; interacts with proteins involved in signal transduction, with members of src family of protein tyrosine kinases, and with an apoptotic regulatory protein HAX-1 | Possible anti-apoptotic and angiogenic activity

Sources: IARC (2012); Purushothaman et al. (2015).

^a^ Lytic in endothelial cells; latent in B cells.

#### Non-coding RNAs

KSHV-encoded miRNAs are expressed in latently infected cells and are involved with suppressing lytic reactivation by activating NF-κB, endothelial cell differentiation, and angiogenesis (Mesri et al. 2010; Moody et al. 2013). KSHV infection also induces cellular miRNAs, particularly miR-132. miR-132 inhibits anti-viral innate immune responses and induces abnormal endothelial cell proliferation, thus, linking viral immune escape with angiogenesis, two important features of Kaposi sarcoma. Moody et al. (2013) demonstrated that KSHV miRNAs mediated cellular transformation and tumorigenesis using a KSHV-induced cellular transformation system of primary rat mesenchymal precursor cells. A mutant virus with a cluster of precursor miRNAs deleted failed to transform primary cells and caused cell-cycle arrest and apoptosis. The oncogenicity of the mutant virus was restored by complementation with the miRNA cluster or several individual precursor miRNAs. Qin et al. (2010) also demonstrated that KSHV miRNAs induce IL-6 and IL-10 secretion in murine macrophages and human myelomonocytic cells and support a role in programming macrophage cytokine responses that favor KSHV-associated tumor progression. Transgenic mice expressing KSHV miRNAs as well as multiple viral latent proteins (e.g., LANA, vFLIP, vCYC) recapitulated the precancerous latent state of KSHV infection (i.e., chronic activation of mature B cells, increased plasma cell frequency, marginal zone B-cell hyperplasia, and hyperglobulinemia) (Sin and Dittmer 2013). A subsequent study that crossed these KSHV latency locus transgenic mice with Myc transgenic mice demonstrated that the KSHV latency locus cooperates with the deregulated Myc pathways to induce lymphoma at a higher rate than in single latency or Myc transgenic mice (Sin et al. 2015).

In addition to the miRNAs, KSHV also encodes a long, non-coding RNA known as polyadenylated nuclear (PAN) RNA during the early lytic stage (Campbell et al. 2014b). PAN RNA has been implicated in KSHV gene expression, replication, and immune modulation and is required for optimal expression of all KSHV lytic genes. It also facilitates LANA-episomal dissociation during lytic replication.

### 4.1.3 Other Possible Cofactors

It is likely that other cofactors are involved in KSHV-associated neoplasms as evidenced by the geographic variation in incidence before the human immunodeficiency virus type 1 epidemic (see Section 3.3.1). Co-infection with other human herpesviruses (e.g., Epstein-Barr virus; see monograph on Epstein-Barr virus), or human cytomegalovirus can activate KSHV lytic replication and influence its pathogenesis (Purushothaman et al. 2015). While other cofactors have been proposed (see Section 3), their mode of action and role as risk factors for specific cancers have not been established.

## 4.2 Mode of Action and Evidence for Cancer Causation

As discussed in the Overview and Introduction Section, it is often difficult to apply stringent criteria, such as Koch’s postulates or Hill’s considerations, for determining that a human tumor virus is oncogenic (Moore and Chang 2010; zur Hausen 2001). Therefore, in addition to the usual criteria used by epidemiologists to determine causality, other factors should be considered as proposed by IARC (1997b) and zur Hausen (1994; 2001). Unlike other oncogenic viruses, Hill’s epidemiological considerations for causality are met for KSHV and Kaposi sarcoma (Moore and Chang 2010). Thus, application of various criteria applicable to oncogenic viruses and mechanistic data provide strong evidence that KSHV is oncogenic in humans and are briefly reviewed below by tumor type.

### 4.2.1 Kaposi Sarcoma

Chang et al. (1994) was the first to report KSHV in Kaposi sarcoma tissues obtained from AIDS patients. There is now substantial evidence that KSHV is the etiological agent of Kaposi sarcoma. KSHV is present in the vast majority of Kaposi sarcoma tumor cells, thus meeting Hill’s consideration for strength and consistency (each cell contains one copy of the KSHV genome and its seroprevalence was correlated with the global incidence of the disease) (Fukumoto et al. 2011; Mesri et al. 2010). In addition, the most difficult of the Hill considerations, experimental epidemiological evidence in a randomized clinical trial, was fulfilled when AIDS patients who were treated with an antiherpesvirus drug were protected from new occurrences of Kaposi sarcoma but not against established tumors (Moore and Chang 2010). Other lines of evidence linking KSHV and Kaposi sarcoma include the following (Cavallin et al. 2014):

- KSHV is associated with all four clinical forms of the disease,
- KSHV is found in spindle cells,
- KSHV infection precedes the onset of Kaposi sarcoma,
- KSHV seroprevalence is highest in areas of high Kaposi sarcoma incidence,
- KSHV encodes many viral oncogenes, and
- KSHV transforms and induces tumorigenesis in endothelial cells.
- Monoclonal expansion of KSHV tumors supports an etiologic role for the virus (Duprez et al. 2007; Judde et al. 2000).

In addition, in vitro models and animal models have been developed that accurately reproduce many features observed in KSHV-associated neoplasms (An et al. 2006; Ashlock et al. 2014; Dittmer et al. 2015; Mesri and Cesarman 2011; Mutlu et al. 2007).

### 4.2.2 Primary Effusion Lymphoma

Primary effusion lymphoma is rare. It occurs most frequently in human immunodeficiency virus type 1-infected homosexual males; however, it has been described in association with post-transplant immunosuppression, and in human immunodeficiency virus type 1-negative elderly patients of Eastern European/Mediterranean and Jewish descent (two populations with high seropositivity for KSHV and elevated incidence of classic Kaposi sarcoma) (Dourmishev et al. 2003; Fukumoto et al. 2011; IARC 2012). Because of inadequate pathology and public health infrastructures, the rates of primary effusion lymphoma in the areas of highest KSHV prevalence (i.e., sub-Saharan Africa) are currently unknown.

KSHV DNA sequences were first identified in eight body-cavity-based lymphomas (later identified as primary effusion lymphoma) taken from patients with AIDS, but they were not detected in 185 other lymphomas examined from patients with or without AIDS (Cesarman et al. 1995). Asou et al. (2000) reported similar findings—KSHV was present in 21 of 21 primary effusion lymphoma patients but was not detected in 139 patients with other AIDS- and non-AIDS-related lymphomas. KSHV infection in primary effusion lymphoma cells is predominantly latent with only a small subpopulation of cells that stain for markers of lytic reactivation (Fukumoto et al. 2011). vIL-6 is the most frequently detected lytic protein and induces VEGF expression and cytokine signals in a broad range of cell types (Aoki et al. 2001; Fukumoto et al. 2011). Further evidence that supports KSHV infection as a causal agent in primary effusion lymphoma is as follows:

- Primary effusion lymphoma neoplasms always carry KSHV and are commonly co-infected with Epstein-Barr virus (Cesarman et al. 1995; Fukumoto et al. 2011);
- KSHV has been incorporated as a diagnostic criterion for primary effusion lymphoma (IARC 2012);
- About half of primary effusion lymphoma patients also have Kaposi sarcoma, and a previous Kaposi sarcoma diagnosis confers an increased risk of primary effusion lymphoma relative to all other AIDS-associated non-Hodgkin lymphomas (Dourmishev et al. 2003; Fukumoto et al. 2011);
- Primary effusion lymphoma cells contain 50 to 100 copies per cell of KSHV DNA, and the expression pattern of KSHV-encoded proteins is almost identical in primary effusion lymphoma and Kaposi sarcoma (Fukumoto et al. 2011; Giffin and Damania 2014; IARC 2012);
- Several KSHV-infected cell lines have been established from primary effusion lymphoma cells that retain a stable latent viral genome including a KSHV+/EBV− cell line established from KSHV+ and Epstein-Barr virus+ primary effusion lymphoma cases, suggesting that KSHV plays an essential role in primary effusion lymphoma pathogenesis (Fukumoto et al. 2011; Katano et al. 1999); and
- Expression of several KSHV viral genes was required for survival of primary effusion lymphoma cells in culture (IARC 2012).

### 4.2.3 Multicentric Castleman Disease

Castleman disease is an uncommon lymphoproliferative disorder with several histological variants (hyaline vascular, plasma cell, mixed, and plasmablastic types) and two clinical forms; unicentric (or localized) and multicentric (Al-Maghrabi 2011; Bonekamp et al. 2011; El-Osta and Kurzrock 2011; Fajgenbaum et al. 2014). The plasmablastic form of multicentric Castleman disease has been specifically associated with KSHV in both human immunodeficiency virus type 1-positive and human immunodeficiency virus type 1-negative cases (Dupin et al. 2000). Thus, KSHV-associated multicentric Castleman disease is now recognized as a distinct entity from other forms of multicentric Castleman disease and is classified by WHO as “large B-cell lymphoma arising in HHV8-associated multicentric Castleman disease” (IARC 2008). This plasmablastic variant of diffuse large B cell lymphoma has KSHV expression of lytic antigens, cytoplasmic IgM with light chain restriction, and viral interleukin 6 expression and is characterized by severe inflammatory symptoms (attributed primarily to elevated levels of IL-6), an aggressive course, and a poor prognosis (Bonekamp et al. 2011; Fajgenbaum et al. 2014; Polizzotto et al. 2012; Venkataraman et al. 2013). Dysregulated IL-6 levels are thought to contribute to multicentric Castleman disease development (Cai et al. 2010). Fewer studies have investigated the association of multicentric Castleman disease and KSHV compared to Kaposi sarcoma or primary effusion lymphoma; however, additional supporting evidence is as follows:

- Several case-control, case-comparison or case series studies have reported an association between KSHV and multicentric Castleman disease (see Section 3 and Table 3-4);
- Cases of Kaposi sarcoma and multicentric Castleman disease frequently occur together in the human immunodeficiency virus type 1-positive population (Cronin and Warnke 2009; Reddy and Mitsuyasu 2011);
- The level of KSHV in peripheral blood monocytes or plasma corresponds with symptoms during multicentric Castleman disease flares in human immunodeficiency virus type 1-positive individuals (Reddy and Mitsuyasu 2011);
- KSHV-positive multicentric Castleman disease cases are associated with KSHV lytic infection, and high levels of vIL-6 have been detected in infected B cells and sera and likely are associated with B-cell proliferation seen in multicentric Castleman disease (Aoki et al. 2001; Fukumoto et al. 2011; IARC 2012);
- vIL-6, a frequently detected lytic protein, enhances cytokine signaling, increases human IL-6 and induces VEGF expression, and likely exacerbates inflammation and disease progression and may be a mechanism leading to multicentric Castleman disease (Al-Maghrabi 2011; Fukumoto et al. 2011; Giffin and Damania 2014); and
- Treatment of multicentric Castleman disease cases with an inhibitor of KSHV infection has shown some success (Casper et al. 2004).

## 4.3 Synthesis

Human viral oncogenesis is a complex process that involves interactions among many viral, host, and environmental factors. Immunosuppression is an important cofactor based on the dramatic increase in Kaposi sarcoma incidence among human immunodeficiency virus type 1-infected individuals. KSHV infection has been clearly linked with all clinical forms of Kaposi sarcoma, as well as primary effusion lymphoma and a plasmablastic variant of multicentric Castleman disease, and biologically plausible modes-of-action have been described. One or more KSHV transcripts are expressed in all KSHV-associated tumors and are required for survival of tumor cells in culture. Latent transcripts drive viral persistence and replication, promote host cell proliferation, and prevent apoptosis while lytic transcripts dysregulate cell signaling pathways that contribute to the angiogenic and inflammatory phenotype of oncogenic lesions via paracrine mechanisms.