# 3 Human Cancer Studies

## 3.1 Introduction

The majority of human epidemiological studies for KSHV have focused on Kaposi sarcoma, which was first described by Dr. Mori Kaposi in 1872 (IARC 1997b), prior to the discovery of the virus in 1994 (Chang et al. 1994). Since 1994, a number of other cancer endpoints have been evaluated, the major ones are certain B-cell non-Hodgkin lymphomas, in particular rare forms of primary effusion lymphoma, multicentric Castleman disease, multiple myeloma, and other lymphohematopoietic cancers. The evidence for these endpoints, which were identified by IARC (1997b; 2012), is assessed in this section. A limited number of studies of solid tumor endpoints (including prostate, bladder, head and neck, angiosarcoma, skin, hepatocellular, and vulvar cancers, and childhood inflammatory myofibroblastoma) have also been conducted, but only in single or small studies for most endpoints, and thus are only reviewed briefly.

One of the key issues in the cancer hazard evaluation is the extent to which observed associations between KSHV and specific cancer endpoints can be explained by cofactors, including host genetic factors, co-infection with other viruses, or other environmental and/or other risk factors, as distinct from confounding factors. However, while a substantial number of studies have investigated KSHV cancer risk in association with human immunodeficiency virus type 1 infection, relatively few studies have clearly identified other cofactors, in particular the presence of other oncoviruses (e.g., Epstein-Barr virus) and non-viral cofactors.

In the majority of studies, KSHV exposure is detected based on DNA in the peripheral blood mononuclear cells, tumor, normal tissue, semen, saliva, and other biological samples or via serological measures usually measuring antibodies to lytic or latent viral antigens. Earlier studies included in this evaluation primarily used serological measurements, while later studies generally used more sensitive and specific seroprevalence measures or detected KSHV DNA.

This evaluation of the human cancer hazard associated with KSHV is divided into three major parts. First, a summary of the approach for selection of the studies is provided (Section 3.2). Next, the cancer evaluation for each endpoint is presented (Sections 3.3 to 3.5), and lastly, a summary of the evaluation across cancer endpoints is provided (Section 3.6). The level of evidence from cancer studies in humans also considers molecular studies of tissues from humans in addition to epidemiological studies and is provided in Section 5.

The NTP used the body of knowledge published in the IARC (1997b; 2012) monographs on KSHV as the resource for studies conducted up to and including 2008. The key human studies identified in these monographs, together with new human studies identified from 2008 to 2015, are considered in the RoC monograph and used to evaluate the scientific evidence for specific cancer endpoints independently of IARC’s conclusions. Where available, IARC data tables of the effect estimates have informed the cancer hazard assessment.

## 3.2 Selection of the Literature

A literature search of major databases, citations, and other authoritative sources for literature from 2008 to August 2015 was conducted. The literature search strategy (including the databases and search terms, and other sources for identifying literature), procedures for selecting the literature (systematic screening procedures and inclusion/exclusion criteria), and the results of the literature search are described in Appendix A. Cross-sectional or prospective cohort studies, and case-control studies, which may range from broadly defined, non-matched hospital or population case-comparison designs to formal age-, sex-, and race-matched case-control designs, as well as summaries of multiple case reports or case-series studies are included in the review.

## 3.3 Cancer Evaluation: Kaposi Sarcoma

### 3.3.1 Background Information

Studies of Kaposi sarcoma incidence or prevalence have been conducted among four main epidemiological types. Although Kaposi sarcoma is histologically indistinguishable in these four types, the age at diagnosis, clinical features, and progression of the disease vary considerably by type.

- “Epidemic” or “human immunodeficiency virus type 1/AIDS-related” Kaposi sarcoma occurs among human immunodeficiency virus type 1-positive, typically immunocompromised individuals;
- “Iatrogenic,” “transplant,” or “immunosuppressive” Kaposi sarcoma occurs primarily among organ recipients, mostly renal and liver transplant patients, generally in the presence of immune suppression, and also among other patients with immune suppression (e.g., hemodialysis patients (Jalilvand et al. 2011));
- “Classic,” “sporadic,” or “indolent” Kaposi sarcoma is rare, less aggressive in its course than human immunodeficiency virus type 1-related Kaposi sarcoma (Hiatt et al. 2008), predominantly affects the lower extremities, and occurs mostly among older males 50 to 70 years of age in specific populations, e.g., in some Mediterranean countries such as southern Italy, or among East Europeans of Jewish descent with higher (e.g., 10% to 20%) KSHV prevalence rates (IARC 1997b; 2012);
- “Endemic” Kaposi sarcoma also occurs mostly among men, but among younger groups than classic Kaposi sarcoma, including children, in regions of sub-Saharan Africa with relatively high KSHV seroprevalence rates, e.g., of 25% to over 50% (IARC 2012). The course of Kaposi sarcoma in children tends to be much more aggressive than that observed in adults (Senba et al. 2011). Since the advent of the human immunodeficiency virus type 1 epidemic, the ratio of Kaposi sarcoma in men to women has decreased from 7:1 to 2:1 in South Africa (Sitas and Newton 2001), despite little evidence that the male to female ratio of KSHV infection differs or has changed over the past two decades (Dedicoat and Newton 2003).

Kaposi sarcoma appears to be rare in immunocompetent individuals among populations with the epidemic type of the cancer, and the expression and course of the cancer may also be affected by compromised immune status in populations with classic or endemic types of Kaposi sarcoma. In the United States, Kaposi sarcoma occurred in <1 per 100,000 individuals prior to the human immunodeficiency virus type 1/AIDS epidemic starting in the early 1980s, peaking at approximately 5 to 6 per 100,000 in the U.S. population by the early 1990s, prior to the advent of highly active antiretroviral therapy (HAART) (NCI 2014).

Approximately 12,000 patients were diagnosed with Kaposi sarcoma between 1975 and 2005, according to SEER registry statistics (Armstrong et al. 2013). In Europe, the Surveillance of Rare Cancers in Europe (RARECARE) project (Stiller et al. 2014) reported 2,667 incident cases of Kaposi sarcoma between 1995 and 2002, an age-standardized rate of 0.3 per 100,000 across the entire European Union. In the subgroup of southern European countries, where predominantly classic cases have been identified, the average incidence was 0.8 per 100,000; the incidence rates for other areas in Europe ranged from 0.02 to 0.25. The Kaposi sarcoma incidence rate among U.S. men (approximately 3.3/100,000) (Rouhani et al. 2008) is higher than that among European men (0.5/10,000) but comparable among women in the United States and Europe (approximately 0.1/100,000; see Stiller et al. (2014)).

### 3.3.2 Descriptive Epidemiological Studies

A number of case series, descriptive epidemiological, or surveillance studies of Kaposi sarcoma from multiple countries, conducted from 2008 to 2015, were identified (Hiatt et al. 2008 [United States]; Jalilvand et al. 2011 [Iran]; Jalilvand et al. 2012 [Iran]; Kanno et al. 2010 [Japan]; Koski et al. 2014 [Tanzania]; Lanternier et al. 2008 [Tanzania]; Magri et al. 2009 [Brazil]; Mousavi et al. 2014 [immigrants to Sweden]; Mwakigonja et al. 2008 [Tanzania]; Nsubuga et al. 2008 [Uganda]; Ogoina et al. 2011 [Nigeria]; Senba et al. 2011 [Kenya]; Stiller et al. 2014 [European cancer surveillance registry]; Tiussi et al. 2012 [Brazil]). As supported by studies reviewed by IARC (2012), descriptive studies that report KSHV seroprevalence (typically LANA) or KSHV-DNA among cases of Kaposi sarcoma indicate ranges from approximately 88% to 98%, irrespective of whether these are human immunodeficiency virus type 1 positive, human immunodeficiency virus type 1 negative, endemic, or classic Kaposi sarcoma cases (Hiatt et al. 2008; IARC 2012; Kanno et al. 2010; Lanternier et al. 2008; Magri et al. 2009; Mwakigonja et al. 2008; Nsubuga et al. 2008; Ogoina et al. 2011). However, relatively few case studies of KSHV seroprevalence have been reported among human immunodeficiency virus type 1-negative populations in regions with endemic or classic Kaposi sarcoma.

### 3.3.3 Cohort and Nested Case-control Studies

Table 3-1 summarizes findings from 13 cohort or nested case-control studies conducted prior to 2009 and reviewed by IARC (2012) and from two prospective cohort and one nested case-control studies identified since the IARC review (Labo et al. 2015; Nawar et al. 2008; Wakeham et al. 2015) that reported risk estimates for KSHV seroprevalence or DNA and Kaposi sarcoma. Most of the cohort studies were of immunosuppressed populations either human immunodeficiency virus type 1-positive or transplant recipients and were conducted among U.S., Canadian, or European-based populations; two cohorts were of southern Mediterranean populations who have a high prevalence of classic Kaposi sarcoma (Parravicini et al. 1997; Rezza et al. 1999) and the nested case-control study was in Uganda, a country with a high prevalence of endemic Kaposi sarcoma (Labo et al. 2015).

Table 3-1 Summary of Cohort and Nested Case-control Studies of Risk of Kaposi Sarcoma among KSHV-Seropositive vs. KSHV-Negative Participants

Reference | Detection Methods | Cohort (Comparison Group) and Cases and Controls | RR
HIV-1-positive/AIDS populations
Cohort studies
Grulich et al. (1999) (USA) | Latent and lytic antigens | AIDS+ MSM | 4.4*
O'Brien et al. (1999) (USA) | Latent nuclear antigen | HIV-1+ MSM | 3.6*
Jacobson et al. (2000) (USA)^a^ | Lytic antigens | HIV-1+ MSM (seroconversion to KSHV after HIV-1 infection vs. before HIV-1 infection) | 2.6*
Rezza et al. (1999) (Italy) | Latent nuclear antigen | HIV-1+ (various exposures) | 29.6*
Nawar et al. (2008) (USA) | Lytic antigens | KSHV and HIV-1 concurrent infections; MSM KSHV infection prior to HIV-1 infection; MSM | 1.8* 1.1 (NS)
Labo et al. (2015) (USA, Puerto Rico) | Latent and lytic antigens | HIV-1+ men and women | 9.5*
Range | | | 1.8–29.6
Nested case-control studies
Moore et al. (1996) Parry and Moore (1997) (USA) | PCR | KS cases: AIDS+ MSM Controls: HIV-1+ MSM | 11.6*
Gao et al. (1996) (USA) | Latent nuclear antigen | KS cases: AIDS+ MSM Controls: HIV-1+ MSM | [16.3]*
Engels et al. (2003) (USA) | Lytic antigens PBMC DNA | KS cases: HIV-1+ MSM Controls: HIV-1+ MSM | 11.7*
Quinlivan et al. (2001)^b^ (Switzerland) | Latent nuclear antigen | KS cases: HIV-1+ M or F Controls: HIV-1+ M or F | 3.0
Newton et al. (2006) (UK) | Latent and lytic antigens | KS cases: HIV-1+ M or F Controls: HIV-1+ M or F Titer (latent antigens) - Min Med Max P_trend_ | 4.4* 3.5* 4.1* 8.7* <0.001
Whitby et al. (1995) (UK) | PCR | KS cases: AIDS+ M or F Controls: HIV-1+ M or F | 12.7*
Wakeham et al. (2015) (Uganda) | Latent and lytic antigens | KS cases: HIV-1+ M or F Controls: HIV-1+ M or F K8.1 LANA | 4.1* 2.2*
Range | | | 2.2–16.3
Organ transplant recipients
Cohort study
Cattani et al. (2001) (Italy) | Latent and lytic antigens | Transplant recipients tested for KSHV before transplant, follow-up 10 years | 34.4*
Nested case-control studies
Parravicini et al. (1997) (Italy) | Latent and lytic antigens | Transplant recipients tested for KSHV before transplant | 75.0*
Rabkin et al. (1999) (Canada) | Latent antigens, whole virus assay | Transplant recipients tested for KSHV before transplant | 2.5 (NS)

* Lower 95% confidence interval (CI) > 1.0.

Source: IARC (2012) (with reported or calculated risk estimate), Table 2.2, Nawar et al. (2008), Labo et al. (2015), Wakeham et al. (2015). IARC also described seven other nested case-control or cohort studies that reported the number of KSHV-positive or -negative Kaposi sarcoma, but did not report or provide enough information to calculate a risk estimate

[ ] = RR or OR calculated by NTP

AIDS = acquired immunodeficiency syndrome; HIV-1 = human immunodeficiency virus type 1; KS = Kaposi sarcoma; KSHV = Kaposi sarcoma-associated herpesvirus; LANA = latent antinuclear antigen; MSM = men who have sex with men; PBMC = peripheral blood mononuclear cells; PCR = polymerase chain reaction; RR = relative risk; NS = lower 95% confidence interval (CI) < 1.0.

^a^ KSHV- and HIV-1-positive MSM with detectable KSHV viral load 1 year prior to diagnosis vs. KSHV- and HIV-1-positive MSM with no detectable viral load.

^b^ Note that membrane antigen RR = 1.7 (95% CI = 0.5 to 6.7) and lytic antigen RR = 0.9 (95% CI = 0.2 to 6.8).

Among the studies reviewed by IARC (2012), all of the relative risks were statistically significant, ranging from 2.5 to 75; elevated risks were observed in both human immunodeficiency virus type 1-positive and organ transplant populations, which provide support for KSHV causing Kaposi sarcoma independently of human immunodeficiency virus type 1 infection. Moreover, Newton et al. (2006) found that risk of Kaposi sarcoma increased with increasing anti-KSHV titers. The two prospective cohort studies conducted in the United States (Labo et al. 2015; Nawar et al. 2008), and the small nested case-control study conducted in Uganda (Wakeham et al. 2015), published after the IARC review, are consistent with these findings and reported risk estimates ranging between 1.8 to 9.5. One cohort study, the multi-city U.S. cohort study of 1,354 men who have sex with men (Nawar et al. 2008), found that acquiring human immunodeficiency virus type 1 infection prior to KSHV infection was associated with an increase in Kaposi sarcoma risk vs. co-prevalent infection (hazard ratio [HR] = 1.81, 95% CI = 1.32 to 2.48), whereas acquiring KSHV infection prior to human immunodeficiency virus type 1 did not increase risk in comparison with co-prevalent infection (HR = 1.05, 95% CI = 0.59 to 1.87). The nested case-control study calculated risks for both lytic and latent antigens; relative risks were somewhat higher for antibody titers to K8.1 lytic antigen (RR = 4.14, 95% CI = 3.34 to 4.94) than latent antigen (LANA) (RR = 2.2, 95% CI = 1.16 to 3.25) (Wakeham et al. 2015). It is not possible to draw conclusions as to whether risk varies among different countries due to the limited number of studies (and few studies reported in detail on the racial or ethnic composition of their cohorts).

IARC (2012) also reported on seven cohort studies of human immunodeficiency virus type 1-positive populations or organ transplant recipients (Chatlynne et al. 1998; Francès et al. 1999; Francès et al. 2000; García-Astudillo and Leyva-Cobian 2006; Marcelin et al. 2004; Melbye et al. 1998; Regamey et al. 1998) that did not calculate risk estimates, primarily due to small numbers; three of these publications reported that KSHV infection was significantly higher in Kaposi sarcoma cases than controls with P-values ranging from <0.001 (Francès et al. 2000; García-Astudillo and Leyva-Cobian 2006) to <0.0001 (Francès et al. 1999).

### 3.3.4 Case-control Studies

IARC (2012) reviewed 80 case-control studies of Kaposi sarcoma; 68 studies included AIDS cases, 7 included human immunodeficiency virus type 1-positive or “non-AIDS” cases, and 10 studies included human immunodeficiency virus type 1-negative cases (plus 4 studies in which human immunodeficiency virus type 1 status was unclear or not specified); 27 included classic cases, 14 included endemic cases, and 9 included transplant cases (some studies had more than one group). Table 3-2 summarizes data from 39 case-control studies in which risk estimates for KSHV were reported. One new case-control study of classic cases in a Sicilian population [Amodio et al. (2011b); based on an earlier study by Goedert et al. 2002] was identified after the IARC (2012) review. (Further studies among KSHV-positive patients in this population were conducted by Pelser et al. (2010) and Anderson et al. (2008) and are discussed under cofactors in Section 3.3.5, below.) Cases that fall into more than one category of Kaposi sarcoma were sometimes combined by study authors for analysis. Comparison groups may be human immunodeficiency virus type 1-positive or AIDS patients, or blood donors, oncology patients, or patients with other skin diseases or other non-cancer conditions, or combinations of such comparison groups from which a single risk estimate was calculated by authors or IARC working groups.

Table 3-2 Summary of Case-control Studies of Kaposi Sarcoma and Kaposi Sarcoma-Associated Herpesvirus (KSHV)

Reference | Detection Method | OR^a^ | Comments
HIV-1-positive/AIDS populations
Chang et al. (1994) (USA) | PCR | 68.8 | –
Whitby et al. (1995) (UK) | PCR | 29.0 | –
Monini et al. (1996a); Monini et al. (1996b) (Italy) | PCR | 1.7^a^ | –
Parry and Moore (1997) (USA) | PCR | 7.3 MSM 21.8 hemophiliacs | –
Humphrey et al. (1996) (USA) | PCR | 2.3 | –
Decker et al. (1996) (USA) | PCR | 1.1^b^ | –
Gao et al. (1996) (USA) | LANA, WB | 18.9 | –
Lefrère et al. (1996) (France) | PCR | 285.0 | –
Miller et al. (1996) (USA) | WB, IFA | 13.4 (WB)/12.2 (IFA) | –
Noel (1995) (Belgium) | PCR | 42.2 | –
Howard et al. (1997) (UK) | PCR | 10.1 | –
Sitas et al. (1999) (South Africa) | LANA, IFA | 10.8–1,683 | Sig. ↑ inc. KSHV titer
Min and Katzenstein (1999) (USA) | PCR | 16.3 | –
Boivin et al. (1999) (Canada) | PCR | 6.7 | –
Greenblatt et al. (2001) (USA) | PCR | 148.0 | –
Keller et al. (2001) (Brazil) | PCR | 7.4–17.0 | –
Cannon et al. (2003) (USA) | PCR | 8.6 | –
Newton et al. (2003a) (Uganda) | LANA, IFA | 4.1–0.8 | Sig. ↑ inc. KSHV titer
Alagiozoglou et al. (2003) (South Africa) | LANA, IFA, PCR | 15.4–25.1 | –
Albrecht et al. (2004) (Germany) | IFA | 1.04–23.2 | Sig. ↑ inc. KSHV titer
Szalai et al. (2005) (Hungary) | LANA, IFA, ELISA | 2.3^b^–23.1 | –
van der Kuyl et al. (2005) (Netherlands) | PCR | 6.3 | –
Martró et al. (2007) (Spain) | IFA | 4.8 | –
Widmer et al. (2006) (Switzerland) | PCR | 1.2^b^ | –
Laney et al. (2007) (USA) | PCR | 1.6^b^–3.4 | –
Zago et al. (2000) (Brazil) | PCR | 23.4–104.8 | –
HIV-1-negative populations
Sitas et al. (1999) (South Africa) | LANA, IFA | 1.5–12.0 | Endemic—sign. trend with ↑ KSHV titer
Newton et al. (2003a); Newton et al. (2003b) (Uganda) | LANA, IFA | 2.3–7.1 | Endemic—sign. trend with ↑ KSHV titer
Cattani et al. (2001) (Italy) | IFA | 34.4 | Transplant patients
Amodio et al. (2011a) (Sicily) | LANA, lytic (K8.1) | 5.13^b^ | Classic
Grouped populations | | | Case groups
Moore and Chang (1995) (USA) | PCR | 400 (19–17,300) [210 (12–3,712)] [∞] [∞] | Total (HIV-1+ men, HIV-1-neg. MSM, Classic HIV-1+ HIV-1-neg. MSM Classic
Chang et al. (1996) (USA) | PCR | 49.4 (9.0–328.0) [66 (5.1–857.7)] [36 (5.3–253.6)] | HIV-1+, endemic HIV-1+ Endemic
Luppi et al. (1996) (Italy) | PCR | 41.6 (7.0–327.1) [∞] [∞] | HIV-1+, classic HIV-1+ Classic
Albini et al. (1996) (Italy) | PCR | 924.3 (125–10,194) [∞] [∞] [∞] [198 (10.8–3,617)] | Total: HIV-1+, endemic, classic, transplant AIDS vs. HIV-1+ Endemic vs. HIV-1+ Classic vs. HIV-1+ Transplant vs. HIV-1 neg.
Herman et al. (1998) (USA) | PCR | 336 (14.9–47,561) | HIV-1+, classic (vs. HIV-1+ and HIV-1 neg. controls combined)
Cattani et al. (1998) (Italy) | PCR | 7.4 (2.4–23.8) [5.9 (1.8–19.2)] [20.0 (1.7–238.6)] | Classic, transplant Classic Transplant
Kazakov et al. (2002) (Switzerland) | PCR | 543 (52–14,041) [600 (34.2–10,541.2)] [150 (11.1–2,025)] 1,275 (75.9–21,420)] | Total: HIV-1+, transplant, classic HIV-1+ Transplant Classic
Lager et al. (2003) (South Africa) | PCR | 572 (26–79,693) | HIV-1 status unknown
Massambu et al. (2003) (Tanzania) | PCR | 3.8 (0.3–60.9) | HIV-1+, endemic

Source: IARC (2012), Table 2.1, Amodio et al. (2011a).

[ ] = OR calculated by NTP

CI = 95% confidence interval; ELISA = enzyme-linked immunosorbent assay; HIV-1 = human immunodeficiency virus type 1; IFA = immunofluorescence assay; KS = Kaposi sarcoma; KSHV = Kaposi sarcoma-associated herpesvirus; LANA = latent antinuclear antigen; MSM = men who have sex with men; OR = odds ratio; PCR = polymerase chain reaction; WB = Western blot assay.

^a^ Lower 95% CI = 0.0.

^b^ Lower 95% CI < 1.0.

Among the studies of patients with human immunodeficiency virus type 1 (some of which had AIDS), odds ratios (ORs), almost all statistically significant, ranged from 1.0 to 1,683 (Table 3-2). The two studies of human immunodeficiency virus type 1-negative cases and controls, both conducted in African populations with, as noted above, high endemic KSHV prevalence rates, reported ORs of 1.5 to 12.0, depending on the level of KSHV titer (Newton et al. 2003a; Sitas et al. 1999). The studies designated as grouped populations consist of combinations of human immunodeficiency virus type 1-positive, human immunodeficiency virus type 1-negative or undetermined, endemic, classic, or transplant-related Kaposi sarcoma patients in comparison with similar Kaposi sarcoma-negative groups, as noted in Table 3-2, and for which only single risk estimates were reported, ORs ranging from 3.8 to 924 were observed. ORs could also be calculated for some constituent groups within these studies, although in some instances, only a single combined control group was used and/or no formal matching of controls was conducted, so that such risk estimates must be interpreted with caution. Nevertheless, for both classic and endemic Kaposi sarcoma, KSHV was observed in >80% to 100% of cases (Table 3-2). Among the few studies that included transplant patients with Kaposi sarcoma, KSHV was observed in approximately 66% to 100% of cases.

Three studies reviewed by IARC (2012) reported on dose-response relationships between titers of KSHV exposure and risk for Kaposi sarcoma. Sitas et al. (1999) and Newton et al. (2003a) observed statistically significant trends (P < 0.001) among both human immunodeficiency virus type 1-positive and human immunodeficiency virus type 1-negative groups with a higher prevalence of endemic Kaposi sarcoma in Africa; Albrecht et al. (2004) reported a similar trend among human immunodeficiency virus type 1-positive AIDS patients in Germany.

### 3.3.5 Cofactors for Kaposi Sarcoma

KSHV has been identified in over 90% (including all four types) of Kaposi sarcoma lesions (Dedicoat and Newton 2003; IARC 2012; Mesri et al. 2010; Moore and Chang 1998). The principal cofactor identified for Kaposi sarcoma in the presence of KSHV infection is human immunodeficiency virus type 1 infection via immune suppression, among populations in both the United States and Europe (“epidemic” Kaposi sarcoma) and those with an increased prevalence of “classic” or “endemic” Kaposi sarcoma (Table 3-1 and Table 3-2). Prospective studies, largely among men who have sex with men and infrequently among human immunodeficiency virus type 1-positive intravenous drug users or women, suggest that human immunodeficiency virus type 1 infection significantly increases the risk of Kaposi sarcoma development in the presence of KSHV in a range of geographical populations, particularly among AIDS patients. There is additional evidence that infection with human immunodeficiency virus type 1 prior to infection with KSHV may increase the risk of Kaposi sarcoma by up to 2.6-fold compared with those infected with KSHV before human immunodeficiency virus type 1, and increasing duration of human immunodeficiency virus type 1 infection, and decreasing CD4 counts are associated with a more rapid course of development of the cancer (Jacobson et al. 2000; Nawar et al. 2008; Renwick et al. 1998). (See also accompanying human immunodeficiency virus type 1 monograph.)

Immune suppression among organ recipients, primarily renal and liver transplant patients, has also been identified as a major cofactor among patients who were KSHV positive prior to transplantation or who acquired KSHV during organ transplantation (see Table 3-1). In a review of 38 case-series studies by Hosseini-Moghaddam et al. (2012), approximately 13% of previously KSHV-seropositive patients reportedly developed Kaposi sarcoma after renal transplantation; approximately 5% of the patients developed the cancer as a result of primary KSHV (donor KSHV positive, recipient KSHV negative) infection.

Few studies have investigated the role of recreational drugs with immunomodulatory properties. In one prospective study, prior use of marijuana, amyl nitrate “poppers,” cocaine, or amphetamines was weakly associated with Kaposi sarcoma risk among co-KSHV and human immunodeficiency virus type 1-infected men who have sex with men, although a clear dose-response relationship was lacking (Chao et al. 2009).

The role of co-factors is less clear for the endemic and classic forms of Kaposi sarcoma. Never smoking, diabetes, and the use of oral corticosteroids have all been identified as potential risk factors for classic Kaposi sarcoma among KSHV-positive individuals in the absence of human immunodeficiency virus type 1 infection or iatrogenic or other causes of immune suppression in a well-conducted case-control study of a population in Sicily (Amodio et al. 2011a; Anderson et al. 2008; Goedert et al. 2002). While this study provides limited evidence that these factors increase the risk of Kaposi sarcoma among KSHV-positive individuals, few other data in other populations include examination of these risk factors and no firm conclusions can be drawn about their role, or that of other risk factors.

With respect to co-infection with other viruses, the role of Epstein-Barr virus is uncertain. It appears that the prevalence of Epstein-Barr virus infection is similar in Kaposi sarcoma and non-Kaposi sarcoma patients and does not appear to play a direct role in the development of the sarcoma, at least according to one well-conducted case-control study among classic cases of Kaposi sarcoma (Table 3-3) (Pelser et al. 2010). Other viruses, such as herpes simplex type 2, human cytomegalovirus, human herpesvirus-6 and 7, and human papillomavirus have also been implicated in the activating lytic replication of KSHV and thus in Kaposi sarcoma pathogenesis (reviewed by Purushothaman et al. 2015). However, no cohort or case-control studies specifically addressing the risk of Kaposi sarcoma in the presence of these viruses as cofactors among KSHV-positive populations have been identified to date.

Table 3-3 Case-control Study of Co-factors for the Development of Classic Kaposi Sarcoma among a KSHV-positive Population in Sicily

Reference | Cofactor | # KS Cases//KSHV+Controls | OR (95% CI) for KS
Anderson et al. (2008) | Diabetes Never smoking Oral corticosteroid use | Cases (45/142) Controls (15/123) Cases (23/142) Controls (12/123) Cases (53/142) Controls (26/123) | 4.02 (1.73–9.37) 2.66 (1.06–6.64) 2.25 (1.16–4.38)
Pelser et al. (2010) | EBV | Cases (low EBNA-1) (43/119) Controls (low EBNA-1) (34/105) Cases (high EBV VCA) (45/119) Controls (high EBV VCA) (45/105) | 0.97 (0.52–1.82)^a^ 0.87 (0.45–1.69)^a^

CI = confidence interval; EBNA = Epstein-Barr virus nuclear antigen; EBV = Epstein-Barr virus; EBV VCA = EBV viral capsid antigen; KS = Kaposi sarcoma; KSHV = Kaposi sarcoma-associated herpesvirus; OR = odds ratio.

^a^ Adjusted for age, sex, smoking, diabetes, and oral corticosteroid use.

Among populations with high rates of endemic Kaposi sarcoma, particularly prior to the global human immunodeficiency virus type 1 epidemic, other potential cofactors, including malaria (see e.g., Nalwoga et al. 2015), other parasitic infections, soil types causing immunosuppression, or oncogenic plants have been suggested as increasing the risk of KSHV infection and/or reactivation (Dedicoat and Newton 2003; IARC 2012). Tuberculosis has been reported as exacerbating the severity of endemic cases (e.g., in Tanzania, (Koski et al. 2014)) but it is not clear if it is a risk factor for the initial development of the sarcoma. Finally, prior to the human immunodeficiency virus type 1 epidemic, Kaposi sarcoma was more prevalent among men than women in, e.g., populations with endemic cases, despite similar KSHV seroprevalence in both sexes, suggesting that cofactors not yet clearly established might play a role in the development of the cancer (Dedicoat and Newton 2003).

### 3.3.6 Integration across Studies of Kaposi Sarcoma

At least 25 cohort or nested case-control studies and 81 case-control studies conducted in populations differing by race or ethnicity and in various geographical locations have demonstrated that KSHV infection causes Kaposi sarcoma. KSHV has been identified in over 80% of cases by serology and in virtually all Kaposi sarcoma tumors and is considered to be the diagnostic prerequisite for a diagnosis of Kaposi sarcoma. The histopathology of all four epidemiological types of Kaposi sarcoma (epidemic, iatrogenic, classic, and endemic) is identical. Case-control studies conducted among populations exhibiting the different types showed statistically significant increased risks for Kaposi sarcoma generally exceeding 10 and up to 300 or more (using serology and/or DNA in the tumor to identify KSHV infection). Most cohort studies report risks from approximately 2 to 16 although a few studies, primarily among transplant patients, have reported risks up to 75. In addition, statistically significant dose-response relationships for measures of KSHV infection and Kaposi sarcoma risk among both human immunodeficiency virus type 1-positive and/or human immunodeficiency virus type 1-negative populations have been reported (Albrecht et al. 2004; Newton et al. 2006; Newton et al. 2003a; Newton et al. 2003b; Sitas et al. 1999).

The heterogeneity in risk observed particularly in case-control studies may be at least partly due to methodological limitations. A majority of the case-control or case-comparison studies have small numbers of cases and lack formal methods of selection or matching of controls or have inadequate reporting. In addition, temporality (evidence that KSHV infection preceded the development of Kaposi sarcoma) cannot generally be clearly established in these studies. The majority of cohort or nested case-control studies have somewhat limited statistical power, and the sensitivity and specificity of KSHV detection methods in earlier studies is generally more limited than in later studies. However, several prospective cohort studies and nested case-control studies (e.g., Gao et al. 1996; Labo et al. 2015; Moore et al. 1996; Nawar et al. 2008; Wakeham et al. 2015; Whitby et al. 1995) provide evidence of temporality. Overall, confounding by other factors can be ruled out with confidence because of the findings of highly statistically significant increased risks across studies with different designs and conducted in different populations, and evidence of dose-response relationships.

With respect to cofactors, immune suppression—primarily resulting from human immunodeficiency virus type 1 infection or iatrogenically in, for example, transplant cases—is the principal cofactor. human immunodeficiency virus type 1 infection prior to KSHV infection may increase the risk of epidemic Kaposi sarcoma between 50% and 100% compared with human immunodeficiency virus type 1 infection during or after KSHV infection. While a recent, well-conducted case-control study in Sicily (Anderson et al. 2008) provides limited evidence that diabetes, corticosteroid use, and never smoking increase the risk of Kaposi sarcoma among KSHV-positive individuals, few other data in other populations have included examination of these risk factors and no firm conclusions can be drawn. Clear evidence for a modulatory role of other specific cofactors, such as genetic factors, malaria, hypoxic stress, or environmental and dietary factors, particularly among endemic and classic cases, is lacking. Co-infection with other viruses, such as Epstein-Barr virus, cannot be completely ruled out as cofactors in the development of Kaposi sarcoma in KSHV-infected individuals; although one case-control study (Pelser et al. 2010) suggests no association with co-infection with Epstein-Barr virus, there are few other data to evaluate the role of this or other viruses.

## 3.4 Lymphohematopoietic Cancers

### 3.4.1 Primary Effusion Lymphoma

#### Background Information

Primary effusion lymphoma, a monoclonal lymphoproliferative disorder also called body cavity-based B-cell lymphoma, is a rare type of B-cell non-Hodgkin lymphoma that presents primarily as pleural, peritoneal, or pericardial lymphomatous effusions and makes up approximately 2% to 4% of human immunodeficiency virus type 1-related non-Hodgkin lymphomas (Simonelli et al. 2003; Sullivan et al. 2008). In addition to lymphomatous effusions, diagnosis of primary effusion lymphoma includes KSHV infection; large-cell immunoblastic or anaplastic large-cell lymphomas; expression of CD45, clonal immunoglobulin gene rearrangements; and lack of c-myc, bcl-2, ras, and p53 gene alterations (Ablashi et al. 2002; Nador et al. 1996). Primary effusion lymphomas are thought to arise from post-germinal center B cells because they have mutations in their immunoglobulin genes. Because a large number of cases of primary effusion lymphoma identified in association with KSHV have distinctive morphological, immunophenotypical, and molecular genetic characteristics, they have been grouped as a single distinct pathological entity (IARC 1997b; 2012). Such entities should be distinguished from other large body cavity-based B-cell lymphomas or lymphoproliferative disorders observed in KSHV-negative patients and may also have a different prognosis (see e.g., Chen et al. 2009; Kishimoto et al. 2009; Xiao et al. 2013).

#### Epidemiological Studies

Epidemiological evidence of an association between primary effusion lymphoma and KSHV relies primarily on a large number of case reports, case-series, and case-comparison studies rather than formal case-control or cohort studies, due to the rarity of the condition, and the fact that the presence of KSHV is a diagnostic criterion for the specific pathological entity that constitutes primary effusion lymphoma. KSHV-positive cases of primary effusion lymphoma have been identified in both human immunodeficiency virus type 1-positive and human immunodeficiency virus type 1-negative individuals; approximately half of the cases have Kaposi sarcoma. Primary effusion lymphoma among human immunodeficiency virus type 1-positive patients exhibits a rapid progression with short survival times, whereas in human immunodeficiency virus type 1-negative and immunocompetent patients, progression appears to be much slower (IARC 1997b). The large majority of primary effusion lymphoma cases occur among men, irrespective of human immunodeficiency virus type 1 or Kaposi sarcoma status, presumably reflecting a higher prevalence of KSHV infection among men (IARC 2012).

IARC ((2012), Table 2.5) reviewed 97 individual cases reported in the literature to be primary effusion lymphoma; 44 cases were reported as both KSHV and human immunodeficiency virus type 1 positive, 31 cases were KSHV positive but human immunodeficiency virus type 1 negative, and three case were uncertain as to KSHV (N = 2)) or human immunodeficiency virus type 1 status (N = 1). The remaining 19 cases were KSHV-negative and human immunodeficiency virus type 1-negative and associated with genetic or other pre-existing conditions and/or observed among patients 67 years of age or older; however, IARC noted that the KSHV-negative cases probably represented another form of non-Hodgkin lymphoma because they do not meet the diagnostic criteria for primary effusion lymphoma. Several small case-series studies (Aoki et al. 2001; Judde et al. 2000; Oksenhendler et al. 2002; Parravicini et al. 2000) were identified that reported a total of 12 additional (i.e., not included in the 97 cases reviewed by IARC) KSHV-positive cases of primary effusion lymphoma, 10 of which were from human immunodeficiency virus type 1-positive/AIDS patients.

KSHV-positive, human immunodeficiency virus type 1-negative cases (11 of the 31 cases reported by IARC and one additional case) have been observed among organ transplant patients (Boulanger et al. 2008; Dotti et al. 1999; IARC 2012; Testa et al. 2010) and among populations (including approximately 14 reviewed by IARC and 8 additional cases) that are known to have a high risk of endemic or classic epidemiological Kaposi sarcoma, leading to the proposition that a “classic” form of primary effusion lymphoma can be identified (Yiakoumis et al. (2010), reviewed by Ascoli et al. (2002)).

Among 47 KSHV-positive cases of primary effusion lymphoma with known human immunodeficiency virus type 1 status (reported by IARC), approximately half of the cases in both human immunodeficiency virus type 1-positive (14/30) and human immunodeficiency virus type 1-negative patients (8/17) also had Kaposi sarcoma; some also presented with multicentric Castleman disease (reviewed below).

In a large case-comparison study of 191 patients with a range of lymphoproliferative disorders (Asou et al. 2000), 21 patients were identified with primary effusion lymphoma, all of whom were KSHV DNA positive, in contrast to 1 of 170 patients with AIDS-related non-Hodgkin lymphoma or with non-AIDS-related lymphomas (Castleman disease, reactive lymphoadenopathy, mucosa-associated lymphoid tissue lymphoma, and non-AIDS non-Hodgkin lymphoma). (In this study, the human immunodeficiency virus type 1 status of primary effusion lymphoma cases is unclear.) No additional cohort or case-control studies have been identified (see review by Zhang et al. 2010).

#### Cofactors for Primary Effusion Lymphoma

Immune suppression resulting from human immunodeficiency virus type 1 infection is a cofactor for primary effusion lymphoma development among KSHV-positive cases. Due in part to its rarity, there are few data on primary effusion lymphoma cases among other immunosuppressed groups although one study reviewed by IARC (2012), Kapelushnik et al. (2001), reported a case in a KSHV-positive renal transplant patient, However, no other case studies were identified for the current review. A substantial proportion (50%) of KSHV-related primary effusion lymphoma cases also have evidence of Epstein-Barr virus infection (IARC 1997b; 2012), which has also been postulated as a cofactor (Boulanger et al. 2005; Bryant-Greenwood et al. 2003; Gloghini et al. 2013).

### 3.4.2 Multicentric Castleman Disease

#### Background and Epidemiological Evidence

Multicentric Castleman disease is a subset (20%) (Talat and Schulte 2011) of Castleman disease, first identified by Castleman et al. (1956) and characterized inflammatory symptoms, plasmacytic lymphadenopathy, splenomegaly, and cytopenia with polyclonal hyperimmunoglobulinemia and high serum levels of IL-6 (Fukumoto et al. 2011; Oksenhendler et al. 2013), and has an aggressive course and poor prognosis (IARC 1997b).

Evidence of a positive association between multicentric Castleman disease and KSHV has been reported in several early case reports and case series (Barozzi et al. 1996; Corbellino et al. 1996; Gessain et al. 1996; Soulier et al. 1995); and in four case-comparison studies (63 cases of multicentric Castleman disease and 213 controls) (Asou et al. 2000; Bélec et al. 1999; Parravicini et al. 1997; Soulier et al. 1995) reviewed by IARC (2012). These studies reported a higher frequency of KSHV, primarily in human immunodeficiency virus type 1-positive but infrequently in human immunodeficiency virus type 1-negative groups, in comparison with controls (Table 3-4). Several histological variants of multicentric Castleman disease exist (hyaline vascular, plasma cell, mixed, and plasmablastic) but KSHV in individuals with and without human immunodeficiency virus type 1 infection, is almost always associated with the plasmablastic variant and rarely in the hyaline vascular form of the disease (Ascoli et al. 1999; Damania 2010; Dupin et al. 2000; Dupin et al. 1999; Fukumoto et al. 2011; Parravicini et al. 2000). Dupin et al. (2000) reported that KSHV was specifically associated with a plasmablastic variant of multicentric Castleman disease in which KSHV-positive plasmablasts showing γ light-chain restriction localized in the mantle zone of B-cell follicles (Dupin et al. 2000). In some cases, these plasmablasts coalesce to form foci of microlymphoma. These plasmablasts are not present in KSHV-negative multicentric Castleman disease (see Section 3.5 for a discussion of the two different forms of multicentric Castleman disease). Findings described in Table 3-4 illustrate the preponderance of plasmablastic types.

Table 3-4 Summary of Case-series and Case-control/Comparison Studies of KSHV and Multicentric Castleman Disease

Reference | KSHV Detection Method | HIV-1 Status of MCD Cases/Controls | KSHV-exposed Cases/Total Cases or OR (95% CI)^a^ Exposed Cases vs. Exposed Controls/
Case reports and case series
Corbellino et al. (1996) | PCR, Southern blot | HIV-1 negative | 4/6 (4/4 with plasma cell type)
Barozzi et al. (1996) | PCR | HIV-1 negative | 1/16 (1/1 is hyaline vascular type)
Gessain et al. (1996) | PCR | HIV-1 positive HIV-1 negative | 3/4 (mixed cell type)^c^ 1/6 (plasma cell type)
Soulier et al. (1995) | PCR, Southern blot | HIV-1 positive HIV-1 negative | 14/14 (6/14 plasma type) 7/17 (3/7 plasma type)
Ascoli et al. (1999) | PCR | HIV-1 positive HIV-1 negative | 1/1 (type not mentioned) 1/1 (type not mentioned)
Gopal et al. (2014) | LANA/viral load | HIV-1 positive | 1/1 (plasmablastic variant)
Parravicini et al. (2000) | Immuno-histochemistry | HIV-1 positive HIV-1 negative | 4/4 (plasma cell type) 6/6 (plasma cell type)
Dupin et al. (1999) | Immuno-histochemistry | HIV-1 positive HIV-1 negative | 5/5 (plasmablastic) 0/1^b^
Dupin et al. (2000) | PCR | HIV-1 positive HIV-1 negative | 8/8 (plasmablastic) 2/2 (plasmablastic)
Case-comparison studies
Bélec et al. (1999) (France) | IFA antibodies | 8 cases, 15 controls | [∞ (6/8 vs. 0/15)]^b^
Parravicini et al. (1997) (Italy) | PCR | All HIV-1 negative | [∞ (6/14 vs. 0/25)]^c^
Soulier et al. (1995) (France) | PCR | HIV-1 positive HIV-1 negative Total | 14/14 vs. 1/34 7/17 [30.2.(3.8–237.9)][23.0 (2.9–181.5) (21/31 vs. 1/34)^c,d^
Asou et al. (2000) (Japan) | PCR | Unclear | [∞ (1/10 vs. 0/139)]^b^

Source: IARC (2012), Table 2.6 and Table 2.7.

CI = confidence interval; IFA = immunofluorescence assay; HIV-1 = human immunodeficiency virus type 1; OR = odds ratio; PCR = polymerase chain reaction.

^a^ [ ] ORs calculated by NTP.

^b^ Cell type not specified.

^c^ Plasma cell or mixed type.

^d^ RoC calculation based on 2×2 table.

While rare, the incidence and prevalence of KSHV-multicentric Castleman disease across populations are uncertain, as it is not tracked in cancer registries and is likely to be under-diagnosed due to its irregular course. Among 32 cases of MCD followed at the NIH Clinical Center in Bethesda, MD, five were in recent African immigrants (Uldrick et al. 2012); Gopal et al. (2014) reported a single KSHV-multicentric Castleman disease case in Malawi.

#### Cofactors for Multicentric Castleman Disease

Human immunodeficiency virus type 1 co-infection substantially increases the risk of multicentric Castleman disease among KSHV-positive patients (Table 3-5; also see Section 4), and KSHV appears to be found in almost all cases of human immunodeficiency virus type 1-related multicentric Castleman disease and approximately half of human immunodeficiency virus type 1-negative cases (Oksenhendler et al. 2002; Oksenhendler et al. 2013; Parravicini et al. 1997).

Table 3-5 Summary of Five Case-control/Comparison and Nested Case-control Studies of KSHV and Multiple Myeloma^a^

Reference Study Type | KSHV Detection Method | HIV-1 Status | OR or RR (95% CI) (KSHV-exposed Cases vs. Exposed Controls)
Schönrich et al. (1998) (Germany) Case-comparison | IFA lytic KS-1 | HIV-1 negative | [1.39 (0.15–13.3)] (4/99 cases vs. 1/34 healthy controls^b^)
Sitas et al. (1999) (S. Africa) Combined 2 case-control studies | IFA latent Titer 1:100 1:>20,000 | Not specified | Adjusted prevalence rate^c^ (108 cases and 108 controls) 24% cases vs. 32% blood-donor controls 1.5% cases vs. 3% blood-donor controls
Tedeschi et al. (2001) (Finland) Nested case-control study | IFA lytic Latent (LANA) Western blot (ORF 65, 73, or K8.1A) | Not specified | 2.02 (0.94–4.33) (13/47 cases vs. 36/224 controls) 10.0 (0.91–110.3) (2/47 cases vs. 1/224 controls) 0.89 (0.25–3.25) (3/47 cases vs. 16/224 controls)
Tedeschi et al. (2005) (Scandinavia) 5 cohorts, nested case-control studies | IFA lytic IFA latent | Not specified | 1.08 (0.5–1.1) (39/329 cases vs. 238/1,393 controls^d^) 0.6 (0.1–2.7) (2/329 cases vs. 16/1,615 controls^d^)
Benavente et al. (2011) (Europe) EpiLymph multisite case-control study | Latent (ORF 73 antigen) Lytic (K8.1) | Not specified | 0.31 (0.11–0.85) (4/254 cases; NR controls^e^) 0.43 (0.15–1.2) (4 cases; NR controls^e^)

Source: IARC ((2012), Table 2.8 and Table 2.9) except for Benavente et al. (2011).

[ ] = OR calculated by NTP

CI = confidence interval; IFA = immunofluorescence assay; LANA = latent nuclear antigen; KS = Kaposi sarcoma; KSHV = Kaposi sarcoma-associated herpesvirus; MM = multiple myeloma; NR = not reported; OR = odds ratio; RR = relative risk.

^a^ Studies with unclear selection of cases or controls or no adjustment for age or other variables were excluded.

^b^ Age- and sex-matched controls.

^c^ Adjusted for age, sex, and education and sex partner.

^d^ Age-, sex-, and area-matched controls; OR adjusted for age.

^e^ Age-, sex-, sampling date-, length of follow-up- and area-matched controls.

Based on 24 cases of human immunodeficiency virus type 1-associated MCD, Powles et al. (2009) measured the incidence of MCD as 4.3 per 10,000 patient-years (95% CI = 2.7 to 6.4). The incidence increased significantly from 2.3 (95% CI = 0.02 to 4.2) in the pre-HAART era to 8.3 (95% CI = 4.6 to 12.6) in the post-HAART era. A nadir CD4 count >200/mm^3^ increased age, no previous HAART exposure and non-Caucasian ethnicity were all associated with an increased risk of multicentric Castleman disease. In a U.K. study of 41 human immunodeficiency virus type 1-positive patients with KSHV-related Kaposi sarcoma or multicentric Castleman disease, Westrop et al. (2012) reported that KSHV-infected human immunodeficiency virus type 1-positive people of African ancestry were significantly more likely to develop multicentric Castleman disease than their European counterparts (relative risk [RR] = 2.42, 95% CI = 1.28 to 4.55). An analysis of the frequency of A299G, a toll-like receptor 4 (TLR4) single nucleotide polymorphism associated with increased multicentric Castleman disease incidence, showed the polymorphism to be three-fold higher in patients of native African descent compared to those of European descent. Finally, the role of Epstein-Barr virus in KSHV-associated multicentric Castleman disease has not been extensively investigated, but the mantle zone plasmablastic cells predominantly infected with KSHV do not appear to be co-infected with Epstein-Barr virus (Dupin et al. 2000; Oksenhendler et al. 2002).

### 3.4.3 Multiple Myeloma

Multiple myeloma is a comparatively rare type of lymphohematopoietic cancer, making up <2% of incident cancers in the United States. The annual (2008 to 2011) U.S. incidence and death rate has been stable at approximately 6.3 per 100,000 in men and 3.3 per 100,000 in women with an approximately 47% 5-year survival rate (SEER 2015).

Twenty hospital-based case-control/comparison studies and two nested case-control studies of the association between multiple myeloma and KSHV were reviewed by IARC (2012). One large case-control study, including 254 cases of multiple myeloma, has been identified since 2008 (Benavente et al. 2011), together with two case series of multiple myeloma patients that reported a higher frequency of KSHV in bone marrow tissue (Ismail et al. 2011; Sadeghian et al. 2008) than among healthy controls. Excluding five studies using a case-control or case-comparison design (Benavente et al. 2011; Schönrich et al. 1998; Sitas et al. 1999) or nested case-control design (Tedeschi et al. 2001; Tedeschi et al. 2005) with age-matched controls (see Table 3-5), the majority of studies were clinic based and did not report methods for the selection of cases and controls or comparison groups and few appear to have controlled for age, sex, or other variables. Among these lower quality studies, a total of 118 cases of multiple myeloma were associated with KSHV (22%) compared with 233 of 1,524 patients without multiple myeloma (23%) in 17 of 18 studies where rates among controls were reported. The five case-control or nested case-control studies also do not support a positive association between KSHV infection and multiple myeloma risk (Table 3-5). In the nested case-control studies (Tedeschi et al. 2001; Tedeschi et al. 2005), increased risks were observed for KSHV detected by latent antibodies; however, IARC (2012) reported that after stratifying by detection method, no statistically significant differences in KSHV positivity between cases and controls were observed by the Working Group.

### 3.4.4 Other Lymphohematopoietic Cancers

Several case-series and case-control studies have been conducted of other lymphohematopoietic cancers, including other lymphomas. An increased incidence of non-Hodgkin lymphoma has been reported in association with KSHV-related multicentric Castleman disease or primary effusion lymphoma in some patients (Oksenhendler et al. 2002; Oksenhendler et al. 2013). Pan et al. (2012) recently described a rare KSHV-associated large B-cell lymphoma in lymph nodes or extranodal sites that do not exhibit lymphomatous effusions and appear to have a different immunological profile, but which may form a continuum with classic primary effusion lymphoma. Deloose et al. (2005) also reported that 38% of human immunodeficiency virus type 1-positive cases of solid immunoblastic/non-Hodgkin lymphoma were KSHV positive among 99 cases of non-Hodgkin lymphoma without evidence of primary effusion lymphoma or multicentric Castleman disease. Burbelo et al. (2012) also reported a higher frequency of KSHV among a small series of human immunodeficiency virus type 1-positive non-Hodgkin lymphoma cases than among healthy controls, but no differences in KSHV frequency were reported in a series of human immunodeficiency virus type 1-positive non-Hodgkin lymphoma cases compared according to duration of human immunodeficiency virus type 1 immunosuppression (Gérard et al. 2009).

A nested case-control study of 155 incident cases of non-Hodgkin lymphoma among human immunodeficiency virus type 1-positive men who have sex with men vs. 155 non-cancer controls (Beachler et al. 2011) did not detect a difference in serum KSHV after adjustment for age and CD4 status. The multisite EpiLymph study in Europe (Benavente et al. 2011), comprising 2,083 cases of lymphoma and 2,048 age-, sex-, and country-matched controls with KSHV serotyping, also reported no associations between KSHV seropositivity and B-cell lymphoma, T-cell lymphoma or Hodgkin lymphoma. Positive associations for splenic marginal zone lymphoma (OR = 4.1, 95% CI = 1.57 to 10.83; 6 cases, using the lytic K8.1 antigen) and mantle-cell lymphoma (OR = 2.63, 95% CI = 0.88 to 7.86; 4 cases, using lytic K8.1 antigen). Although this was a large study, exposure prevalence was low resulting in few exposed cases for some subtypes of B-cell lymphomas, T-cell lymphoma, and Hodgkin lymphoma. KSHV-related non-Hodgkin lymphoma is uncommon in sub-Saharan African populations despite a high prevalence of endemic KSHV (Engels et al. 2007b).

### 3.4.5 Integration across Studies

Over 115 KSHV-positive cases of primary effusion lymphoma have been reported in the literature, primarily in case reports or case series, and have demonstrated a form of KSHV-related primary effusion lymphoma with distinguishing clinical, morphological, and immunophenotypic features that are uniquely associated with KSHV infection; cases occur in both human immunodeficiency virus type 1-positive and human immunodeficiency virus type 1 negative patients (IARC 2012). KSHV has also been associated with the plasmablastic variant of multicentric Castleman disease (see also Section 4). A majority of KSHV-related cases occur in human immunodeficiency virus type 1-positive patients (IARC 2012). To date, it is unclear if other viruses, including Epstein-Barr virus, or other cofactors, play a role in the development of these conditions, although their rarity has precluded large-scale studies of these factors. No association of multiple myeloma with KSHV infection was found in several studies. Data are insufficient to evaluate other lymphomas.

## 3.5 Other Tumor Sites

Few studies have been conducted on other tumor sites, with the partial exception of prostate cancer. Case-control or nested case-control studies of prostate cancer identified since 2008 have reported no or small increases in risk in association with KSHV (Huang et al. 2008; McDonald et al. 2011; Sutcliffe et al. 2015). In the most recent nested case-control study within a prospective clinical cancer prevention trial, Sutcliffe et al. (2015) reported no difference in KSHV-positive serostatus (11.6% in cases, 11.1% in controls, P = 0.81). These findings are consistent with those reported in earlier studies and reviewed by IARC (2012). IARC (1997b) reviewed six case-series studies of angiosarcoma, four of which were reported as showing no association with KSHV; five case studies of skin cancer were reviewed, four of which showed no association with KSHV (IARC 1997b). In addition, IARC (1997b) reviewed approximately 28 case-series and small case-control studies comparing KSHV DNA in skin and other tissue samples from patients with Kaposi sarcoma lesions with patients with other skin tumors or tissue lesions resembling Kaposi sarcoma and found, overall, only 3% of non-Kaposi sarcoma tissues contained KSHV DNA.

Since 2008, single studies have been identified for KSHV and hepatocellular (Su et al. 2014), vulvar (Simbiri et al. 2014), bladder cancers (Panagiotakis et al. 2013), laryngeal cancer (Güvenc et al. 2008; Mohamadian Roshan et al. 2014), head and neck squamous-cell carcinoma (McLemore et al. 2010), and childhood inflammatory myofibroblastoma (Alaggio et al. 2010). The number of studies on specific solid tumors is insufficient to evaluate these endpoints, with the possible exception of prostate cancer, for which no associations with KSHV serostatus have been reported to date.

## 3.6 Synthesis across Cancer Endpoints

A summary of the evidence for KSHV infection and the different cancer endpoints from epidemiological studies is provided in Table 3-6. The level of evidence from cancer studies in human also considers studies of tissues from humans in addition to epidemiological studies and is provided in Section 5.

Table 3-6 Summary of KSHV Cancer Endpoints and Strength of the Epidemiological Evidence

Cancer Endpoint | Strength of Evidence
Kaposi sarcoma | • Consistent evidence of highly increased, statistically significant risk in many prospective cohort and case-control studies. • KSHV found in >90% of Kaposi sarcoma tumors in biopsies from Kaposi sarcoma case series. • Dose-response relationships observed in several studies.
Primary effusion lymphoma | • Consistent evidence of KSHV seropositivity or KSHV DNA in over 115 cases (individual case reports, case-series, case-comparison studies; morphologically and immunophenotypically distinct primary effusion lymphoma
Multicentric Castleman disease | • Consistent evidence of KSHV seropositivity in MCD. KSHV is found in more than 99% of the plasmablastic variant of MCD Molecular studies support the association with this specific form. • Most cases observed in HIV-1-positive individuals.
Multiple myeloma | • Inconsistent evidence, the majority with no or non-significant modest positive associations, from several case-control or case-comparison studies.
Other lymphohematopoietic cancers and solid tumor sites | • Inconsistent evidence for prostate cancer risk based on few studies. • Inadequate number of epidemiological studies to evaluate other endpoints.

KSHV = Kaposi sarcoma-associated herpesvirus; MCD = multicentric Castleman disease.