# 2 Human Exposure

This section describes prevalence and transmission (Section 2.1), and non-cancer diseases, prevention, and treatment of Kaposi sarcoma-associated herpesvirus (KSHV) (Section 2.2). The material presented in Sections 2.1 and 2.2 is summarized in Section 2.3.

## 2.1 Prevalence and Transmission

Serological tests for detecting the multiple antigens encoded by KSHV vary in sensitivity and specificity and are poorly standardized, resulting in uncertainty in prevalence estimates and complicating comparison of KSHV in different populations (IARC 2012). Considering this caveat, KSHV prevalence rates appear to vary widely in different populations; high-level endemic areas (adult general public seroprevalences between 30% and 70%) are found in many parts of Africa (Martin 2007); intermediate-level endemic areas (general public seroprevalences between 10% and 25%) are found primarily in the Mediterranean area (Whitby et al. 1998); and non-endemic areas (general public seroprevalences <10%) include North America, Central America, South America, northern Europe, and Asia. However, in non-endemic areas, certain population groups exhibit seroprevalences comparable to those in high- and intermediate-level endemic areas (e.g., between 30% and 60% of human immunodeficiency virus type 1-infected men who have sex with men and between 20% and 30% of human immunodeficiency virus type 1-uninfected men who have sex with men are infected with KSHV (Martin et al. 1998; O'Brien et al. 1999).

The first systematic evaluation of KSHV epidemiology in the general public in the United States (based on enzyme immunoassays conducted on serum samples from National Health and Nutrition Examination Survey [NHANES] III data collection) reported that overall KSHV seroprevalence is approximately 7% and is similar among men and women (Engels et al. 2007a). These seroprevalence data indicate that a significant number of people in the United States are exposed to KSHV. A previous study of 1,000 U.S. blood donors (collected in 1994 and 1995) tested by six independent laboratories, using various serological tests ranging from single immunofluorescence assays to decision trees based on results of several individual assays, reported KSHV seropositivity estimates ranging from 0.5% to 5% (IARC 2012; Pellett et al. 2003). KSHV seropositivity has been found to be lower among human immunodeficiency virus type 1-infected women than in human immunodeficiency virus type 1-infected men who have sex with men, including bisexual men (Kedes et al. 1997). Global KSHV seroprevalence has been shown to mirror the geographical distribution of classic or endemic (i.e., non- human immunodeficiency virus type 1-associated) forms of classic Kaposi sarcoma, e.g., high (15% to 60%) in African and southern Mediterranean regions, and low (1% to 5%) in the United States and northern Europe (Ganem 2010; Minhas and Wood 2014).

Transmission of KSHV appears to be primarily via saliva (IARC 2012). The presence of KSHV in peripheral blood suggests that transmission via blood is also possible, and transmission among some intravenous drug users, transfusion recipients, and from transplant donor to transplant recipient has been reported (Barozzi et al. 2003; IARC 2012). In populations with high endemic KSHV prevalence, both horizontal and vertical transmission appear to occur, primarily in childhood between the ages of 6 and 10 years (particularly if the mother is infected) and infection rates increase with age.

Risk factors for infection may include contact with, e.g., infected family members, sources of water, and, in particular, human immunodeficiency virus type 1 infection (IARC 2012), so factors that increase the risk of human immunodeficiency virus type 1 infection (e.g., number of sexual partners) also increase the risk of infection with KSHV. Further, higher KSHV infection rates in human immunodeficiency virus type 1-positive cohorts other than those acquiring human immunodeficiency virus type 1 via parenteral infection were found to reflect sexual activity, for which human immunodeficiency virus type 1 seropositivity serves as a marker (Kedes et al. 1996). Men who have sex with men may have a higher risk of KSHV transmission than heterosexual sex partners even in the absence of human immunodeficiency virus type 1 infection (Giuliani et al. 2007), and orogenital sex has been shown to be significantly correlated with KSHV seroconversion in men who have sex with men (Dukers et al. 2000). The possibility of insect bites facilitating the transmission of KSHV via human saliva (i.e., application of virus-carrying saliva at the bite site to relieve itching and reduce scratching (Amodio et al. 2011b; Coluzzi et al. 2003) has also been reported.

KSHV is generally not associated with sexual risk factors in heterosexuals (Engels et al. 2007a; IARC 2012; Smith et al. 1999). However, there is some evidence for spouse-to spouse transmission among heterosexual couples, which appears to be more efficient for female-to-male than for male-to-female transmission (Dupuy et al. 2009). This is based on a study that found higher KSHV seroprevalence among heterosexual spouses of Kaposi sarcoma patients than among spouses of controls without cancer. Overall, KSHV prevalence was higher among male spouses than female spouses.

## 2.2 Diseases, Prevention, and Treatment

Most individuals who are otherwise healthy and infected with KSHV are asymptomatic (ACS 2014; DHHS 2013; NCI 2014). There are very few reports of primary infection with KSHV, but reported symptoms associated with initial KSHV infection include a febrile maculopapular skin rash (as observed in immunocompetent children in Egypt) (Andreoni et al. 2002), as well as diarrhea, fatigue, localized rash, and lymphadenopathy (in men who have sex with men without human immunodeficiency virus type 1 infection) (Wang et al. 2001). Other symptoms include fever, splenomegaly, cytopenia, and bone marrow failure with plasmacytosis (in renal transplant recipients) (Luppi et al. 2000a). Active KSHV infection may be associated with fever, cutaneous rash, and hepatitis in autologous peripheral blood stem cell infusion recipients (Luppi et al. 2000b).

A limited number of studies have suggested associations between KSHV infection and some non-cancer endpoints, including proliferative and nonproliferative skin diseases such as pemphigus vulgaris and pemphigus foliaceus, and actinic keratosis, but other studies have failed to confirm these associations (Ablashi et al. 2002). In addition, KSHV has been found in inflammatory cells in isolated cases of interstitial pneumonitis, in sarcoid tissue, and in histocytic necrotic lymphadenitis, indicating lymph node infiltration, but an etiologic role of KSHV in these diseases has not been established (Ablashi et al. 2002).

Because KSHV transmission is associated with KSHV shedding in saliva and occasional shedding in genital secretions, avoiding salivary exposure and following safe sex practices should theoretically prevent transmission (Chang-Moore 2009; DHHS 2013; 2014)

Some drugs have been reported to reduce or inhibit KSHV shedding (e.g., see Casper et al. 2008; Cattamanchi et al. 2011); however, currently there are no FDA-approved drugs for treatment of KSHV infection. Currently, there is no vaccine against KSHV; however, limited efforts to develop a vaccine are ongoing (ACS 2014; Wu et al. 2012).

## 2.3 Summary

U.S. seroprevalence study data indicate that a significant number of people living in the United States are exposed to KSHV. Most individuals who are otherwise healthy and infected with KSHV are asymptomatic. Transmission appears to be primarily via saliva. Transmission via blood is also possible, and transmission among some intravenous drug users, transfusion recipients and from transplant donor to transplant recipient has been reported. Both horizontal and vertical transmission appears to occur, primarily in childhood (between the ages of 6 and 10 years, with infection rates increasing with age) in populations with high endemic KSHV prevalence, particularly if the mother is infected. Risk factors for infection may include contact with infected family members, sources of water, and particularly human immunodeficiency virus type 1 infection, so factors that increase the risk of human immunodeficiency virus type 1 infection also increase the risk of infection with KSHV. Men who have sex with men may have a higher risk of KSHV transmission than heterosexual sex partners even in the absence of human immunodeficiency virus type 1 infection. A limited number of studies have suggested associations between infection with KSHV and some non-cancer endpoints (e.g., pemphigus vulgaris, pemphigus foliaceus, and actinic keratosis), but other studies have failed to confirm these associations. There is currently no vaccine against KSHV, although limited vaccine development efforts are ongoing.