# 1 Properties and Detection

This section reviews the biological properties (Section 1.1) and detection methods (Section 1.2) of the Kaposi sarcoma-associated herpesvirus (KSHV). The information in this section is summarized in Section 1.3.

## 1.1 Biological Properties

### 1.1.1 Family and Type

KSHV, also designated as human herpesvirus 8 (HHV8), was the first member of the gamma-2 herpesviruses identified in humans in 1994 in association with acquired immunodeficiency syndrome (AIDS) (Chang et al. 1994; Fukumoto et al. 2011; IARC 1997b). Rhadinoviruses also include herpesviruses that infect New World monkeys, macaque Old World monkeys, cattle, and rodents (IARC 1997b).

KSHV consists of linear double-stranded DNA (dsDNA) wrapped around a core protein within a protein capsid, surrounded by a membrane envelope containing glycoproteins (Edelman 2005; Fukumoto et al. 2011; Giffin and Damania 2014; IARC 1997b; 2012) (see Figure 1-1). The capsid is made up of five major capsid proteins forming hexamer and pentamer proteins and a minor capsid protein that binds to the edges of the hexamer and pentamer junctions (Giffin and Damania 2014; IARC 2012). Between the capsid and the membrane envelope are six tegument proteins and 11 viral RNA strands (Fukumoto et al. 2011; Giffin and Damania 2014).

Figure 1-1

Kaposi Sarcoma-Associated Herpes Virus Particle

Source: Los Alamos National Laboratory.

### 1.1.2 Genome

The KSHV genome, with an overall size of 165 kbp, consists of two main sections, (1) the long unique region, which contains over 80 open reading frames (ORF) for protein and microRNA (miRNA) genes, is 140 kbp long and (2) two flanking terminal repeat regions composed of a variable number of repeating units (see Figure 1-2) (Fukumoto et al. 2011; IARC 1997b; 2012). The terminal repeats do not contain open reading frames, but function by providing the origin of replication, location of genome circularization, and binding sites to tether the viral genome to host chromosomes.

Figure 1-2

Genome Schematic

LANA = latency-associated nuclear antigen.

Most of the genes are conserved among herpesviruses and are named after the genes of the closest related virus, Herpesvirus saimiri, which infects non-human primates (IARC 1997b; 2012). These genes are designated by the number identifier of their open reading frame, e.g., ORF 16, and are numbered consecutively from left to right across the genome (Giffin and Damania 2014). Other genes originated from host cellular genes during viral evolution and are designated by their cellular homologue, preceded by “v-” denoting a viral origin, e.g., v-Bcl-2 (IARC 1997b; 2012). Some genes are unique to KSHV and are designated by the letter “K” in their open reading frame, e.g., ORF K12. MiRNAs are designated by “miR” and a number identifier, e.g., miR-K5.

### 1.1.3 Infection and Replication

Like other herpesviruses, the KSHV replication cycle includes a latent phase and a lytic phase, which allow the virus to transition between a quiescent infection and active replication (see Figure 1-3). KSHV has been detected in endothelial cells, epithelial cells, B lymphocytes, and monocytes in vivo, while a wider variety of cells can be infected in vitro (Giffin and Damania 2014). CD19^+^ B lymphocytes are a long-term latency reservoir for the virus. KSHV glycoproteins on the capsid surface mediate fusion with several target cell receptors, and the replication cycle starts as KSHV enters a cell by a receptor-mediated endocytosis or macropinocytosis process (Campbell et al. 2014a; Giffin and Damania 2014). The viral capsid then enters the nucleus and releases dsDNA. Inside the virus particle, the genome is linear, but within the host cell nucleus it circularizes, joining the terminal repeat ends together and attaching to host cell chromosomes (Campbell et al. 2014a; Fukumoto et al. 2011; IARC 1997b). In the latent phase, the viral episome persists and is replicated by host machinery to daughter cells with each cell division. No infectious virus particles are produced during latency and only a small number of genes located in the latency locus are expressed. Only a low copy number of the viral genome is present in a latently infected cell, while a high copy number is produced during a lytic infection.

Figure 1-3

KSHV Infection and Replication Cycle

Most of the time, KSHV will remain in the latent phase but cell stressors, such as phorbol esters, sodium butyrate, some signaling cytokines, cell differentiation, reactive oxygen species, and innate immune signaling by Toll-like receptors, can initiate the lytic phase (Giffin and Damania 2014). At the start of the lytic phase the viral lytic transactivator protein, RTA, causes the expression of many viral genes, beginning with those involved in controlling viral gene expression. The next viral genes expressed are those involved in DNA replication and immunomodulation. Viral DNA replication occurs at multiple origins within the terminal repeat region of the circular genome to produce linear copies of newly formed genomes. The viral capsid is then enveloped by the lipid bilayer membrane as it buds off of the nuclear membrane into the cytoplasm and progeny virions are released from the cell. See Section 4.1.2 for a detailed description of latent and lytic genes.

## 1.2 Detection Methods

KSHV infections can be detected by measuring viral protein antigens or viral DNA in tissues and antibodies against the virus in blood (see Table 1-1). The level of KSHV antibodies in the blood only suggests that a viral infection has occurred, as both the specificity and sensitivity of the test methods are low (Fukumoto et al. 2011; IARC 2012; Xu et al. 2015). KSHV DNA or antibodies against KSHV-specific antigens in the blood can be used to measure viral load. The nature of the antigens recognized by the antibodies, i.e., either latent or lytic, can help to determine the predominant nature of the infection, but this test alone is not conclusive because of variations in development of antibody responses among individuals (IARC 2012). Both latent and lytic viral infections are associated with carcinogenesis (IARC 2012). In cases of Kaposi sarcoma or primary effusion lymphoma, KSHV latently infects almost all tumor cells while lytic infection is frequently seen in the plasmablastic variant of multicentric Castleman disease (see Mechanisms and Other Relevant Data, Section 4) (Damania 2010; Dupin et al. 2000). Antibodies against two main viral proteins have been measured in humans to detect KSHV, though other protein-specific antibodies can be detected as well (see Mechanisms and Other Relevant Data, Section 4) (Fukumoto et al. 2011; IARC 1997b; 2012). These include the latent phase protein, latency-associated nuclear antigen (LANA), (ORF 73), and the lytic phase protein, K8.1.

Table 1-1 Detection Methods

Analyte | Method | Lytic Marker | Latent Marker
Fluids
Antibodies | Immunohistochemistry – infected primary effusion lymphoma cells | Nuclear and cytoplasmic staining^a^ | Only nuclear staining
| ELISA | High levels – Suggestive | Low levels – Suggestive
DNA | PCR | Genome detection - Not phase specific | –
Cells
Antigen | Immunohistochemistry – tissue | Nuclear and cytoplasm staining | Only nuclear staining
DNA | PCR | Genome detection - Not phase specific | –

^a^ Phorbol esters are used to induce the lytic phase in primary effusion lymphoma cells.

### 1.2.1 Detection in Fluids

#### Antibodies

The level of antibody response varies depending on the phase of the infection (IARC 2012). Antibody responses are low in latently infected individuals and higher in patients with lytic infections or in patients with Kaposi sarcoma (IARC 2012). Latently infected cell lines can be used to immunohistochemically detect anti-KSHV antibodies, which stain in the nucleus only. Infected cell lines can be stimulated with phorbol esters or sodium butyrate to increase the number of cells in the lytic phase and to detect antibodies against lytic antigens, which stain the cytoplasm as well as the nucleus (Fukumoto et al. 2011; IARC 1997b). Recombinant viral proteins and peptides have also been used in ELISA tests for KSHV antibodies (IARC 2012). Polymerase chain reaction (PCR) techniques can detect viral DNA in saliva and to a lesser extent in vaginal secretions and semen (Campbell et al. 2014a); however, these techniques are not used clinically.

### 1.2.2 Detection in Cells

#### Antigens

KSHV can infect many different cell types including B cells, dendritic cells, monocytes, prostate cells, keratinocytes, fibroblasts, endothelial cells, and epithelial cells, as detected by immunohistochemical staining for KSHV antigens (Campbell et al. 2014a; Fukumoto et al. 2011; Giffin and Damania 2014; IARC 1997b; 2012). KSHV encodes a viral homolog of interleukin-6 (vIL-6), which can be detected in the affected cells and blood of patients with multicentric Castleman disease, primary effusion lymphoma, and Kaposi sarcoma (Aoki et al. 2001; Bhutani et al. 2015; Fukumoto et al. 2011; Mesri et al. 2010; Parravicini et al. 2000; Parravicini et al. 1997). vIL-6 is thought to play a role in multicentric Castleman disease pathogenesis by stimulating the proliferation of plasma cells.

#### DNA

Viral DNA detected in tissues by PCR can indicate KSHV infections in those tissues (Fukumoto et al. 2011; IARC 1997b; 2012). KSHV DNA can be detected in peripheral blood mononuclear cells, but not all KSHV-infected patients will give positive results (Campbell et al. 2014a; Fukumoto et al. 2011; IARC 1997b). KSHV infection can occur without Kaposi sarcoma or multicentric Castleman disease, so detecting KSHV DNA in peripheral blood mononuclear cells does not necessarily indicate the presence of these diseases. However, those with Kaposi sarcoma or multicentric Castleman disease tend to have higher viral loads in peripheral blood mononuclear cells.

## 1.3 Summary

Kaposi sarcoma-associated herpesvirus (KSHV) is an enveloped DNA virus found in Kaposi sarcomas, primary effusion lymphoma, and some cases of multicentric Castleman disease. The genome circularizes and attaches to the host chromosome but does not integrate into the host genome. There are over 80 genes and 17 mRNAs, which include some genes that originated from host cell genes during the evolution of KSHV. The virus can reproduce lytically or can remain latent, tethered to the host chromosome. The lytic phase can be initiated by innate immune signaling, cytokine signaling, or cell differentiation or by exposure to phorbol esters, sodium butyrate, or reactive oxygen. KSHV can be detected by anti-KSHV antibodies, intracellular viral antigens, and DNA.