# Peer Review

Peer review of the Draft RoC Monograph on Kaposi Sarcoma-Associated Herpesvirus (KSHV) was conducted by an ad hoc expert panel at a public meeting held December 17, 2015, in the Rodbell Auditorium at the National Institute of Environmental Health Sciences, David P. Rall Building, Research Triangle Park, NC (see http://ntp.niehs.nih.gov/go/38854) for materials, minutes, and panel recommendations from the peer-review meeting). The selection of panel members and conduct of the peer review were performed in accordance with the Federal Advisory Committee Act and federal policies and regulations. The panel members served as independent scientists, not as representatives of any institution, company, or governmental agency.

The charge to the Peer-Review Panel was as follows:

1. Comment on the draft cancer evaluation component for KSHV, specifically, whether it was technically correct and clearly stated, whether the NTP has objectively presented and assessed the scientific evidence, and whether the scientific evidence is adequate for applying the RoC listing criteria,
2. Comment on the draft substance profile for KSHV, specifically, whether the scientific justification presented in the substance profile supports the NTP’s preliminary policy decision on the RoC listing status of the substance (available in the 14th edition of the Report on Carcinogens).

The Panel was asked to vote on the following questions:

1. Whether the scientific evidence supports the NTP’s preliminary conclusion on the level of evidence for carcinogenicity for the specific types of cancer from cancer studies in humans.
2. Whether the scientific evidence supports the NTP’s preliminary listing decision for KSHV in the RoC.

This RoC monograph on KSHV has been revised based on NTP’s review of the Panel’s peer-review comments. The Peer-Review Panel Report, which captures the Panel recommendations for listing status of KSHV in the RoC and their scientific comments, and the NTP Response to the Peer-Review Report are available on the Peer-Review Meeting webpage for Kaposi sarcoma-associated herpesvirus (https://ntp.niehs.nih.gov/go/38854).

## Peer Reviewers

- Andrew F. Olshan, Ph.D. (Chair)
  Distinguished Professor and Chair
  Department of Epidemiology
  University of North Carolina
  Chapel Hill, North Carolina, USA
- Blossom Damania, Ph.D.
  Assistant Dean of Research and Professor
  School of Medicine
  University of North Carolina
  Chapel Hill, North Carolina, USA
- Paul F. Lambert, Ph.D.
  Professor and Chair of Oncology
  Director, McArdle Laboratory for Cancer Research
  University of Wisconsin School of Medicine and Public Health
  Wisconsin Institutes for Medical Research
  Madison, Wisconsin, USA
- Margaret Madeleine, Ph.D.
  Associate Member
  Program in Epidemiology
  Fred Hutchinson Cancer Research Center
  Seattle, Washington, USA
- Edward L. Murphy, Jr., M.D.,
  Professor
  Departments of Laboratory Medicine and Epidemiology/Biostatistics
  University of California, San Francisco
  San Francisco, California, USA
- Charles S. Rabkin, M.D.,
  Senior Investigator
  Infections and Immunoepidemiology Branch
  Division of Cancer Epidemiology and Genetics
  National Cancer Institute
  Bethesda, Maryland, USA
- Rosemary Rochford, Ph.D.
  Professor, Immunology and Microbiology
  Professor, Environmental and Occupational Health
  University of Colorado School of Medicine
  Aurora, Colorado, USA