# Abbreviations

  AIDS: Acquired Immune Deficiency Syndrome
  ANGP2: angiopoietin 2
  APC: antigen-presenting cell
  BET: bromodomain and extra-terminal
  CDC: Centers for Disease Control and Prevention
  CDK6: cyclin-dependent kinase 6
  CI: confidence interval
  DNA: deoxyribonucleic acid
  DOT: Department of Transportation
  dsDNA: double-stranded DNA
  EBNA: Epstein-Barr virus nuclear antigen
  EBV: Epstein-Barr virus
  EBV VCA: EPV viral capsid antigen
  ELISA: enzyme-linked immunosorbent assays
  F: female
  FDA: Food and Drug Administration
  FLICE: FADD-like interleukin-1 beta-converting enzyme
  HAART: highly active antiretroviral therapy
  HAX-1: HS1-associated protein X1
  HHV8: human herpesvirus 8
  HIF-1α: hypoxia-inducible factor-1α
  HIV: human immunodeficiency virus
  HR: hazard ratio
  hTERT: human telomerase reverse transcriptase
  IARC: International Agency for Research on Cancer
  IFA: immunofluorescence assay
  HHV8: human herpesvirus 8
  IFA: immunofluorescence assay
  K1: unique KSHV protein 1
  K15: unique KSHV protein 15
  KS: Kaposi sarcoma
  KSHV: Kaposi sarcoma-associated herpesvirus
  LANA: latency-associated nuclear antigen
  MHC: major histocompatibility complex
  miRNA: microRNA
  M: male
  Max: maximum
  MCD: multicentric Castleman disease
  Med: median
  Min: minimum
  MM: multiple myeloma
  MSM: men who have sex with men
  Nef: negative factor protein
  NF-κB: nuclear factor kappa-light-chain enhancer of activated B cells
  NHANES: National Health and Nutrition Examination Survey
  NR: not reported
  NS: not significant
  NTP: National Toxicology Program
  OR: odds ratio
  ORF: open reading frames
  OSHA: Occupational Safety and Health Administration
  PAN: polyadenylated nuclear
  PBMC: peripheral blood mononuclear cells
  PCR: polymerase chain reaction
  PDGF: platelet-derived growth factor
  PEL: primary effusion lymphoma
  pRB: retinoblastoma protein
  PTK: protein tyrosine kinase
  RARECARE: Surveillance of Rare Cancers in Europe
  RNA: ribonucleic acid
  RR: relative risk
  RTA: replication and transcription activator
  SEER: Surveillance, Epidemiology, and End Results Program
  TGFBeta: transforming growth factor-β
  TLR4: toll-like receptor 4
  U.K.: United Kingdom
  U.S.: United States
  U.S.A.: United States of America
  vCCL: viral-encoded chemokines
  VEGF: vascular endothelial growth factor
  vFLIP: viral FLICE-inhibitory protein
  vGPCR: viral G protein-coupled receptor
  vIL-6: interleukin-6
  vIRF: viral interferon regulatory factors
  WB: western blot assay