# Glossary

Case report: Detailed descriptions of a few patients or clinical cases (frequently, just one sick person) with an unusual disease or complication, uncommon combinations of diseases, an unusual or misleading semiology, cause, or outcome (maybe a surprising recovery). They often are preliminary observations that are later refuted. They cannot estimate disease frequency or risk (e.g., for lack of a valid denominator).
Case series: A collection of subjects (usually, patients) with common characteristics used to describe some clinical, pathophysiological, or operational aspect of a disease, treatment, exposure, or diagnostic procedure. A case series does not include a comparison group and is often based on prevalent cases and on a sample of convenience. Common selection biases and confounding severely limit their power to make causal inferences.
Case-comparison study (case-control study, case referent study): The observational epidemiological study of persons with the disease (or another outcome variable) of interest and a suitable control group of persons without the disease (comparison group, reference group). The potential relationship of a suspected risk factor or an attribute to the disease is examined by comparing the diseased and non-diseased subjects with regard to how frequently the factor or attribute is present (or, if quantitative, the levels of the attribute) in each of the groups (diseased and non-diseased).
Cellular immunity: Immunity independent of antibody but dependent on the recognition of antigen by T cells and their subsequent destruction of cells bearing the antigen or on the secretion by T cells of lymphokines that enhance the ability of phagocytes to eliminate the antigen.
Cofactor: A factor that activates or enhances the action of another entity such as a disease-causing agent. Cofactors may influence the progression of a disease or the likelihood of becoming ill.
Diagnostic criteria: The specific combination of signs, symptoms, and test results that a clinician uses to identify a person as representing a case of a particular disease or condition.
Enzyme immunoassay: An assay that uses an enzyme-bound antibody to detect antigen. The enzyme catalyzes a color reaction when exposed to substrate.
Highly active antiretroviral therapy: Treatment regimens that stop or slow the HIV virus from reproducing and keep HIV disease from progressing. The usual HAART regimen combines 3 or more HIV drugs from at least 2 different classes.
Horizontal transmission: The spread of an infectious agent from one individual to another, usually through contact with bodily excretions or fluids, such as sputum or blood, which contains the agent.
Humoral immunity: The component of the immune system involving antibodies that are secreted by B-cells and circulate as soluble proteins in blood.
Immunohistochemical staining: A method to detect specific antigens in cells based on an antigen-antibody reaction, which can be recognized at the light microscopic level.
Latent phase: A phase of the virus life cycle during which the virus is not replicating.
Lytic phase: A phase of the virus life cycle during which the virus replicates within the host cell, releasing a new generation of viruses when the infected cell lyses.
Lytic reactivation: The biological events beginning with emergence of a virus from latency and ending with lysis of the host cell and release of progeny virions.
microRNA: Small, non-coding RNA molecules approximately 22 nucleotides in length that act post translationally in a regulatory role to target messenger RNAs for cleavage or translational expression.
Monoclonal: Pertaining to or designating a group of identical cells or organisms derived from a single cell or organism.
Non-coding RNAs: Functional RNA molecules that are transcribed from DNA but are not translated into proteins.
Oligoclonal: A few different clones, or the product of a few different clones.
Paracrine neoplasia: A process whereby KSHV-infected cells induce neighboring uninfected cells to produce cytokines and growth factors that are necessary as autocrine and paracrine factors for driving tumor production.
Parenteral: By some other means than through the gastrointestinal tract; the parenteral route of infection involves breaks in the skin such as cuts and scrapes, puncture wounds, bites, and burns.
Peripheral blood monocytes: Circulating precursors of macrophages and dendritic cells that migrate from the blood stream across vascular endothelium for immunological surveillance, as well as respond to inflammation.
Polyclonal: Pertaining to or designating a group of cells or organisms derived from several cells.
Polymerase chain reaction: A laboratory technique used to produce large amounts of specific DNA fragments. Polymerase chain reaction is used for genetic testing and to diagnose disease.
Professional antigen-presenting cells (APCs): Specialized white blood cells that express MHC class II and are able to activate a helper T-cell that has never encountered its antigen before. The three main types of professional APCs are macrophages, dendritic cells, and B cells.
Titer: A laboratory measurement of the concentration of a substance in a solution (e.g., an antibody titer measures the presence and amount of antibodies in the blood).
Toll-like receptors: A family of pattern recognition receptors involved in the detection of structures associated with pathogens or damaged host tissues.
Vertical transmission: The transmission of infection from one generation to the next (e.g., from mother to infant prenatally, during delivery, or in the postnatal period via breast milk.