# References

Ablashi DV, Chatlynne LG, Whitman JE Jr, Cesarman E. 2002. Spectrum of Kaposi’s sarcoma-associated herpesvirus, or human herpesvirus 8, diseases. Clin Microbiol Rev. 15(3):439–464. 10.1128/CMR.15.3.439-464.2002 12097251
Al-Maghrabi JA. 2011. Castleman’s disease. Update on pathogenesis. Saudi Med J. 32(5):451–458. 21556463
Alaggio R, Cecchetto G, Bisogno G, Gambini C, Calabro ML, Inserra A, Boldrini R, De Salvo GL, d’Amore ESG, Dall’igna P. 2010. Inflammatory myofibroblastic tumors in childhood: A report from the Italian Cooperative Group studies. Cancer. 116(1):216–226. 19852031
Alagiozoglou L, Morris L, Bredell H, Martin DJ, Sitas F. 2003. Human herpesvirus-8 antibodies and DNA in HIV-1 infected patients in South Africa. Epidemiol Infect. 131(3):1125–1129. 10.1017/S0950268803001146 14959780
Albini A, Aluigi M, Benelli R, Berti E, Biberfeld P, Blasig C, Calabro M, Calvo F, Chiecobianchi L, Corbellino M, et al. 1996. Oncogenesis in HIV-infection. Int J Oncol. 9(1):5–8. 21541473
Albrecht D, Meyer T, Lorenzen T, Stoehr A, Arndt R, Plettenberg A. 2004. Epidemiology of HHV-8 infection in HIV-positive patients with and without Kaposi sarcoma: Diagnostic relevance of serology and PCR. J Clin Virol. 30(2):145–149. 10.1016/j.jcv.2003.09.017 15125870
American Cancer Society (ACS). 2014. Kaposi sarcoma. American Cancer Society. https://www.cancer.org/cancer/kaposi-sarcoma.html.
Amodio E, Goedert JJ, Barozzi P, Riva G, Firenze A, Bonura F, Viviano E, Romano N, Luppi M. 2011 a. Differences in Kaposi sarcoma-associated herpesvirus-specific and herpesvirus-non-specific immune responses in classic Kaposi sarcoma cases and matched controls in Sicily. Cancer Sci. 102(10):1769–1773. 10.1111/j.1349-7006.2011.02032.x 21740480
Amodio E, Valentini M, Gori-Savellini G, Valenti RM, Romano N, Goedert JJ, Cusi MG. 2011 b. Prevalence of toscana and sicilian phlebovirus antibodies in classic Kaposi sarcoma case patients and control subjects in sicily. J Infect Dis. 204(9):1423–1426. 10.1093/infdis/jir546 21900487
An FQ, Folarin HM, Compitello N, Roth J, Gerson SL, McCrae KR, Fakhari FD, Dittmer DP, Renne R. 2006. Long-term-infected telomerase-immortalized endothelial cells: A model for Kaposi’s sarcoma-associated herpesvirus latency in vitro and in vivo. J Virol. 80(10):4833–4846. 10.1128/JVI.80.10.4833-4846.2006 16641275
Anderson LA, Lauria C, Romano N, Brown EE, Whitby D, Graubard BI, Li Y, Messina A, Gafa L, Vitale F, et al. 2008. Risk factors for classical Kaposi sarcoma in a population-based case-control study in Sicily. Cancer Epidemiol Biomarkers Prev. 17(12):3435–3443. 10.1158/1055-9965.EPI-08-0671 19064559
Andreoni M, Sarmati L, Nicastri E, El Sawaf G, El Zalabani M, Uccella I, Bugarini R, Parisi SG, Rezza G. 2002. Primary human herpesvirus 8 infection in immunocompetent children. JAMA. 287(10):1295–1300. 10.1001/jama.287.10.1295 11886321
Aoki Y, Yarchoan R, Wyvill K, Okamoto S, Little RF, Tosato G. 2001. Detection of viral interleukin-6 in Kaposi sarcoma-associated herpesvirus-linked disorders. Blood. 97(7):2173–2176. 10.1182/blood.V97.7.2173 11264189
Armstrong AW, Lam KH, Chase EP. 2013. Epidemiology of classic and AIDS-related Kaposi’s sarcoma in the USA: Incidence, survival, and geographical distribution from 1975 to 2005. Epidemiol Infect. 141(1):200–206. 10.1017/S0950268812000325 22404880
Ascoli V, Lo Coco F, Torelli G, Vallisa D, Cavanna L, Bergonzi C, Luppi M. 2002. Human herpesvirus 8-associated primary effusion lymphoma in HIV—patients: A clinicopidemiologic variant resembling classic Kaposi’s sarcoma. Haematologica. 87(4):339–343. 11940475
Ascoli V, Sirianni MC, Mezzaroma I, Mastroianni CM, Vullo V, Andreoni M, Narciso P, Scalzo CC, Nardi F, Pistilli A, et al. 1999. Human herpesvirus-8 in lymphomatous and nonlymphomatous body cavity effusions developing in Kaposi’s sarcoma and multicentric Castleman’s disease. Ann Diagn Pathol. 3(6):357–363. 10.1016/S1092-9134(99)80014-8 10594287
Ashlock BM, Ma Q, Issac B, Mesri EA. 2014. Productively infected murine Kaposi’s sarcoma-like tumors define new animal models for studying and targeting KSHV oncogenesis and replication. PLoS One. 9(1):e87324. 10.1371/journal.pone.0087324 24489895
Asou H, Tasaka T, Said JW, Daibata M, Kamada N, Koeffler HP. 2000. Co-infection of HHV-6 and HHV-8 is rare in primary effusion lymphoma. Leuk Res. 24(1):59–61. 10.1016/S0145-2126(99)00144-7 10634647
Bais C, Van Geelen A, Eroles P, Mutlu A, Chiozzini C, Dias S, Silverstein RL, Rafii S, Mesri EA. 2003. Kaposi’s sarcoma associated herpesvirus G protein-coupled receptor immortalizes human endothelial cells by activation of the VEGF receptor-2/ KDR. Cancer Cell. 3(2):131–143. 10.1016/S1535-6108(03)00024-2 12620408
Barozzi P, Luppi M, Facchetti F, Mecucci C, Alu M, Sarid R, Rasini V, Ravazzini L, Rossi E, Festa S, et al. 2003. Post-transplant Kaposi sarcoma originates from the seeding of donor-derived progenitors. Nat Med. 9(5):554–561. 10.1038/nm862 12692543
Barozzi P, Luppi M, Masini L, Marasca R, Savarino M, Morselli M, Ferrari MG, Bevini M, Bonacorsi G, Torelli G. 1996. Lymphotropic herpes virus (EBV, HHV-6, HHV-8) DNA sequences in HIV negative Castleman’s disease. Clin Mol Pathol. 49(4):M232–M235. 10.1136/mp.49.4.M232 16696081
Beachler DC, Gellert LL, Jacobson LP, Ambinder RF, Breen EC, Martinez-Maza O, Rabkin CS, Kaslow RA, D’Souza G. 2011. Kaposi sarcoma-associated herpesvirus serum DNA and antibodies not associated with subsequent non-Hodgkin lymphoma risk. J Acquir Immune Defic Syndr. 56(2):188–192. 10.1097/QAI.0b013e3181ff976b 21116187
Bélec L, Authier FJ, Mohamed AS, Soubrier M, Gherardi RK. 1999. Antibodies to human herpesvirus 8 in POEMS (polyneuropathy, organomegaly, endocrinopathy, m protein, skin changes) syndrome with multicentric Castleman’s disease. Clin Infect Dis. 28:678–679. 10.1086/515169 10194095
Benavente Y, Mbisa G, Labo N, Casabonne D, Becker N, Maynadie M, Foretova L, Cocco PL, Nieters A, Staines A, et al. 2011. Antibodies against lytic and latent Kaposi’s sarcoma-associated herpes virus antigens and lymphoma in the European EpiLymph case-control study. Br J Cancer. 105(11):1768–1771. 10.1038/bjc.2011.392 21952625
Bhutani M, Polizzotto MN, Uldrick TS, Yarchoan R. 2015. Kaposi sarcoma-associated herpesvirus-associated malignancies: Epidemiology, pathogenesis, and advances in treatment. Semin Oncol. 42(2):223–246. 10.1053/j.seminoncol.2014.12.027 25843728
Boivin G, Gaudreau A, Toma E, Lalonde R, Routy JP, Murray G, Handfield J, Bergeron MG. 1999. Human herpesvirus 8 DNA load in leukocytes of human immunodeficiency virus-infected subjects: Correlation with the presence of Kaposi’s sarcoma and response to anticytomegalovirus therapy. Antimicrob Agents Chemother. 43(2):377–380. 10.1128/AAC.43.2.377 9925538
Bonekamp D, Horton KM, Hruban RH, Fishman EK. 2011. Castleman disease: The great mimic. Radiographics. 31(6):1793–1807. 10.1148/rg.316115502 21997995
Boulanger E, Afonso PV, Yahiaoui Y, Adle-Biassette H, Gabarre J, Agbalika F. 2008. Human herpesvirus-8 (HHV-8)-associated primary effusion lymphoma in two renal transplant recipients receiving rapamycin. Am J Transplant. 8(3):707–710. 10.1111/j.1600-6143.2007.02110.x 18261181
Boulanger E, Duprez R, Delabesse E, Gabarre J, Macintyre E, Gessain A. 2005. Mono/oligoclonal pattern of Kaposi Sarcoma-associated herpesvirus (KSHV/HHV-8) episomes in primary effusion lymphoma cells. Int J Cancer. 115(4):511–518. 10.1002/ijc.20926 15700304
Bryant-Greenwood P, Sorbara L, Filie AC, Little R, Yarchoan R, Wilson W, Raffeld M, Abati A. 2003. Infection of mesothelial cells with human herpes virus 8 in human immunodeficiency virus-infected patients with Kaposi’s sarcoma, Castleman’s disease, and recurrent pleural effusions. Mod Pathol. 16(2):145–153. 10.1097/01.MP.0000052374.61768.79 12591967
Burbelo PD, Kovacs JA, Wagner J, Bayat A, Rhodes CS, De Souza Y, Greenspan JS, Iadarola MJ. 2012. The cancer-associated virus landscape in HIV patients with oral hairy leukoplakia, Kaposi’s sarcoma, and non-Hodgkin lymphoma. Aids Res Treat. 2012:634523. 10.1155/2012/634523 22924124
Cai Q, Verma SC, Lu J, Robertson ES. 2010. Molecular biology of Kaposi’s sarcoma-associated herpesvirus and related oncogenesis. Adv Virus Res. 78:87–142. 10.1016/B978-0-12-385032-4.00003-3 21040832
Campbell DM, Rappocciolo G, Jenkins FJ, Rinaldo CR. 2014 a. Dendritic cells: Key players in human herpesvirus 8 infection and pathogenesis. Front Microbiol. 5:452. 10.3389/fmicb.2014.00452 25221546
Campbell M, Kung HJ, Izumiya Y. 2014 b. Long non-coding RNA and epigenetic gene regulation of KSHV. Viruses. 6(11):4165–4177. 10.3390/v6114165 25375882
Cannon MJ, Dollard SC, Black JB, Edlin BR, Hannah C, Hogan SE, Patel MM, Jaffe HW, Offermann MK, Spira TJ, et al. 2003. Risk factors for Kaposi’s sarcoma in men seropositive for both human herpesvirus 8 and human immunodeficiency virus. AIDS. 17(2):215–222. 10.1097/00002030-200301240-00012 12545082
Casper C, Krantz EM, Corey L, Kuntz SR, Wang J, Selke S, Hamilton S, Huang ML, Wald A. 2008. Valganciclovir for suppression of human herpesvirus-8 replication: A randomized, double-blind, placebo-controlled, crossover trial. J Infect Dis. 198(1):23–30. 10.1086/588820 18491970
Casper C, Nichols WG, Huang ML, Corey L, Wald A. 2004. Remission of HHV-8 and HIV-associated multicentric Castleman disease with ganciclovir treatment. Blood. 103(5):1632–1634. 10.1182/blood-2003-05-1721 14615380
Castleman B, Iverson L, Menendez VP. 1956. Localized mediastinal lymphnode hyperplasia resembling thymoma. Cancer. 9(4):822–830. 10.1002/1097-0142(195607/08)9:4<822::AID-CNCR2820090430>3.0.CO;2-4 13356266
Cattamanchi A, Saracino M, Selke S, Huang ML, Magaret A, Celum C, Corey L, Wald A, Casper C. 2011. Treatment with valacyclovir, famciclovir, or antiretrovirals reduces human herpesvirus-8 replication in HIV-1 seropositive men. J Med Virol. 83(10):1696–1703. 10.1002/jmv.22194 21837785
Cattani P, Capuano M, Graffeo R, Ricci R, Cerimele F, Cerimele D, Nanni G, Fadda G. 2001. Kaposi’s sarcoma associated with previous human herpesvirus 8 infection in kidney transplant recipients. J Clin Microbiol. 39(2):506–508. 10.1128/JCM.39.2.506-508.2001 11158097
Cattani P, Capuano M, Lesnoni La Parola I, Guido R, Santangelo R, Cerimele F, Masini C, Nanni G, Fadda G, Cerimele D. 1998. Human herpesvirus 8 in Italian HIV-seronegative patients with Kaposi sarcoma. Arch Dermatol. 134(6):695–699. 10.1001/archderm.134.6.695 9645637
Cavallin LE, Goldschmidt-Clermont P, Mesri EA. 2014. Molecular and cellular mechanisms of KSHV oncogenesis of Kaposi’s sarcoma associated with HIV/AIDS. PLoS Pathog. 10(7):e1004154. 10.1371/journal.ppat.1004154 25010730
Cesarman E, Chang Y, Moore PS, Said JW, Knowles DM. 1995. Kaposi’s sarcoma-associated herpesvirus-like DNA sequences in AIDS-related body-cavity-based lymphomas. N Engl J Med. 332(18):1186–1191. 10.1056/NEJM199505043321802 7700311
Chang Y, Cesarman E, Pessin MS, Lee F, Culpepper J, Knowles DM, Moore PS. 1994. Identification of herpesvirus-like DNA sequences in AIDS-associated Kaposi’s sarcoma. Science. 266(5192):1865–1869. 10.1126/science.7997879 7997879
Chang Y, Moore PS, Talbot SJ, Boshoff CH, Zarkowska T, Godden K, Paterson H, Weiss RA, Mittnacht S. 1996. Cyclin encoded by KS herpesvirus. Nature. 382(6590):410. 10.1038/382410a0 8684480
Chang-Moore L. 2009. Kaposi's Sarcoma-Associated Herpesvirus (KSHV). Chang-Moore Laboratory. https://www.tumorvirology.pitt.edu/kshvrsch.html. [Accessed: January 26, 2015]
Chao C, Jacobson LP, Jenkins FJ, Tashkin D, Martinez-Maza O, Roth MD, Ng L, Margolick JB, Chmiel JS, Zhang ZF, et al. 2009. Recreational drug use and risk of Kaposi’s sarcoma in HIV- and HHV-8-coinfected homosexual men. AIDS Res Hum Retroviruses. 25(2):149–156. 10.1089/aid.2008.0196 19108691
Chatlynne LG, Lapps W, Handy M, Huang YQ, Masood R, Hamilton AS, Said JW, Koeffler HP, Kaplan MH, Friedman-Kien A, et al. 1998. Detection and titration of human herpesvirus-8-specific antibodies in sera from blood donors, acquired immunodeficiency syndrome patients, and Kaposi’s sarcoma patients using a whole virus enzyme-linked immunosorbent assay. Blood. 92(1):53–58. 10.1182/blood.V92.1.53.413k30_53_58 9639499
Chen W, Huang Q, Zuppan CW, Rowsell EH, Cao JD, Weiss LM, Wang J. 2009. Complete absence of KSHV/HHV-8 in posttransplant lymphoproliferative disorders: An immunohistochemical and molecular study of 52 cases. Am J Clin Pathol. 131(5):632–639. 10.1309/AJCP2T4IIIZKBHMI 19369621
Coluzzi M, Calabrò ML, Manno D, Chieco-Bianchi L, Schulz TF, Ascoli V. 2003. Reduced seroprevalence of Kaposi’s sarcoma-associated herpesvirus (KSHV), human herpesvirus 8 (HHV8), related to suppression of Anopheles density in Italy. Med Vet Entomol. 17(4):461–464. 10.1111/j.1365-2915.2003.00465.x 14651663
Corbellino M, Poirel L, Aubin JT, Paulli M, Magrini U, Bestetti G, Galli M, Parravicini C. 1996. The role of human herpesvirus 8 and Epstein-Barr virus in the pathogenesis of giant lymph node hyperplasia (Castleman’s disease). Clin Infect Dis. 22(6):1120–1121. 10.1093/clinids/22.6.1120 8783733
Cronin DM, Warnke RA. 2009. Castleman disease: An update on classification and the spectrum of associated lesions. Adv Anat Pathol. 16(4):236–246. 10.1097/PAP.0b013e3181a9d4d3 19546611
Damania B. 2010. Targeting the PI3K/Akt/mTOR pathway in AIDS-associated malignancies. In: Dittmer DP, Crown S, editors. Molecular basis for therapy of AIDS-defining cancers. Berlin, Germany: Springer Science and Business Media, LLC; p. 153–156. 10.1007/978-1-4419-1513-9_9
Davis DA, Naiman NE, Wang V, Shrestha P, Haque M, Hu D, Anagho HA, Carey RF, Davidoff KS, Yarchoan R. 2015. Identification of caspase cleavage sites in KSHV latency-associated nuclear antigen and their effects on caspase-related host defense responses. PLoS Pathog. 11(7):e1005064. 10.1371/journal.ppat.1005064 26218605
Decker LL, Shankar P, Khan G, Freeman RB, Dezube BJ, Lieberman J, Thorley-Lawson DA. 1996. The Kaposi sarcoma-associated herpesvirus (KSHV) is present as an intact latent genome in KS tissue but replicates in the peripheral blood mononuclear cells of KS patients. J Exp Med. 184(1):283–288. 10.1084/jem.184.1.283 8691144
Dedicoat M, Newton R. 2003. Review of the distribution of Kaposi’s sarcoma-associated herpesvirus (KSHV) in Africa in relation to the incidence of Kaposi’s sarcoma. Br J Cancer. 88(1):1–3. 10.1038/sj.bjc.6600745 12556950
Deloose ST, Smit LA, Pals FT, Kersten MJ, van Noesel CJ, Pals ST. 2005. High incidence of Kaposi sarcoma-associated herpesvirus infection in HIV-related solid immunoblastic/plasmablastic diffuse large B-cell lymphoma. Leukemia. 19(5):851–855. 10.1038/sj.leu.2403709 15744337
Department of Health and Human Services (DHHS). 2013. Guidelines for the prevention and treatment of opportunistic infections among HIV-exposed and HIV-infected children. Bethesda, MD: National Institutes of Health; p. 384.
Department of Health and Human Services (DHHS). 2014. Guidelines for the prevention and treatment of opportunistic infections in HIV-infected adults and adolescents. Bethesda, MD: National Institutes of Health; p. 407.
Dittmer DP, Damania B, Sin SH. 2015. Animal models of tumorigenic herpesviruses—an update. Curr Opin Virol. 14:145–150. 10.1016/j.coviro.2015.09.006 26476352
Dotti G, Fiocchi R, Motta T, Facchinetti B, Chiodini B, Borleri GM, Gavazzeni G, Barbui T, Rambaldi A. 1999. Primary effusion lymphoma after heart transplantation: A new entity associated with human herpesvirus-8. Leukemia. 13(5):664–670. 10.1038/sj.leu.2401390 10374868
Dourmishev LA, Dourmishev AL, Palmeri D, Schwartz RA, Lukac DM. 2003. Molecular genetics of Kaposi’s sarcoma-associated herpesvirus (human herpesvirus-8) epidemiology and pathogenesis. Microbiol Mol Biol Rev. 67(2):175–212. 10.1128/MMBR.67.2.175-212.2003 12794189
Dukers NH, Renwick N, Prins M, Geskus RB, Schulz TF, Weverling GJ, Coutinho RA, Goudsmit J. 2000. Risk factors for human herpesvirus 8 seropositivity and seroconversion in a cohort of homosexual men. Am J Epidemiol. 151(3):213–224. 10.1093/oxfordjournals.aje.a010195 10670545
Dupin N, Diss TL, Kellam P, Tulliez M, Du MQ, Sicard D, Weiss RA, Isaacson PG, Boshoff C. 2000. HHV-8 is associated with a plasmablastic variant of Castleman disease that is linked to HHV-8-positive plasmablastic lymphoma. Blood. 95(4):1406–1412. 10.1182/blood.V95.4.1406.004k26_1406_1412 10666218
Dupin N, Fisher C, Kellam P, Ariad S, Tulliez M, Franck N, van Marck E, Salmon D, Gorin I, Escande JP, et al. 1999. Distribution of human herpesvirus-8 latently infected cells in Kaposi’s sarcoma, multicentric Castleman’s disease, and primary effusion lymphoma. Proc Natl Acad Sci USA. 96(8):4546–4551. 10.1073/pnas.96.8.4546 10200299
Duprez R, Lacoste V, Brière J, Couppié P, Frances C, Sainte-Marie D, Kassa-Kelembho E, Lando MJ, Essame Oyono JL, Nkegoum B, et al. 2007. Evidence for a multiclonal origin of multicentric advanced lesions of Kaposi sarcoma. J Natl Cancer Inst. 99(14):1086–1094. 10.1093/jnci/djm045 17623796
Dupuy A, Schulz T, Chevret S, Agbalika F, Pellet C, Janier M, Dupin N, Verola O, Calvo F, Lebbe C. 2009. Asymmetrical transmission of human herpesvirus 8 among spouses of patients with Kaposi sarcoma. Br J Dermatol. 160(3):540–545. 10.1111/j.1365-2133.2008.08966.x 19077076
Edelman DC. 2005. Human herpesvirus 8—a novel human pathogen. Virol J. 2:78–78. 10.1186/1743-422X-2-78 16138925
El-Osta HE, Kurzrock R. 2011. Castleman’s disease: From basic mechanisms to molecular therapeutics. Oncologist. 16(4):497–511. 10.1634/theoncologist.2010-0212 21441298
Engels EA, Atkinson JO, Graubard BI, McQuillan GM, Gamache C, Mbisa G, Cohn S, Whitby D, Goedert JJ. 2007 a. Risk factors for human herpesvirus 8 infection among adults in the United States and evidence for sexual transmission. J Infect Dis. 196(2):199–207. 10.1086/518791 17570106
Engels EA, Biggar RJ, Marshall VA, Walters MA, Gamache CJ, Whitby D, Goedert JJ. 2003. Detection and quantification of Kaposi’s sarcoma-associated herpesvirus to predict AIDS-associated Kaposi’s sarcoma. AIDS. 17(12):1847–1851. 10.1097/00002030-200308150-00015 12891072
Engels EA, Mbulaiteye SM, Othieno E, Gomez M, Mathew S, Cesarman E, Knowles DM, Chadburn A. 2007 b. Kaposi sarcoma-associated herpesvirus in non-Hodgkin lymphoma and reactive lymphadenopathy in Uganda. Hum Pathol. 38(2):308–314. 10.1016/j.humpath.2006.08.009 17097130
Fajgenbaum DC, van Rhee F, Nabel CS. 2014. HHV-8-negative, idiopathic multicentric Castleman disease: Novel insights into biology, pathogenesis, and therapy. Blood. 123(19):2924–2933. 10.1182/blood-2013-12-545087 24622327
Fakhari FD, Jeong JH, Kanan Y, Dittmer DP. 2006. The latency-associated nuclear antigen of Kaposi sarcoma-associated herpesvirus induces B cell hyperplasia and lymphoma. J Clin Invest. 116(3):735–742. 10.1172/JCI26190 16498502
Francès C, Mouquet C, Calvez V. 1999. Human herpesvirus 8 and renal transplantation. N Engl J Med. 340(13):1045 , author reply 1046. 10.1056/NEJM199904013401314 10189287
Francès C, Mouquet C, Marcelin AG, Barete S, Agher R, Charron D, Benalia H, Dupin N, Piette JC, Bitker MO, et al. 2000. Outcome of kidney transplant recipients with previous human herpesvirus-8 infection. Transplantation. 69(9):1776–1779. 10.1097/00007890-200005150-00008 10830210
Fukumoto H, Kanno T, Hasegawa H, Katano H. 2011. Pathology of Kaposi’s sarcoma-associated herpesvirus infection. Front Microbiol. 2:175. 10.3389/fmicb.2011.00175 21904536
Ganem D. 2010. KSHV and the pathogenesis of Kaposi sarcoma: Listening to human biology and medicine. J Clin Invest. 120(4):939–949. 10.1172/JCI40567 20364091
Gao SJ, Kingsley L, Li M, Zheng W, Parravicini C, Ziegler J, Newton R, Rinaldo CR, Saah A, Phair J, et al. 1996. KSHV antibodies among Americans, Italians and Ugandans with and without Kaposi’s sarcoma. Nat Med. 2(8):925–928. 10.1038/nm0896-925 8705864
García-Astudillo LA, Leyva-Cobian F. 2006. Human herpesvirus-8 infection and Kaposi’s sarcoma after liver and kidney transplantation in different geographical areas of Spain. Transpl Immunol. 17(1):65–69. 10.1016/j.trim.2006.09.008 17157220
Gérard L, Meignin V, Galicier L, Fieschi C, Leturque N, Piketty C, Fonquernie L, Agbalika F, Oksenhendler E. 2009. Characteristics of non-Hodgkin lymphoma arising in HIV-infected patients with suppressed HIV replication. AIDS. 23(17):2301–2308. 10.1097/QAD.0b013e328330f62d 19752717
Gessain A, Sudaka A, Briere J, Fouchard N, Nicola MA, Rio B, Arborio M, Troussard X, Audouin J, Diebold J, et al. 1996. Kaposi sarcoma-associated herpes-like virus (human herpesvirus type 8) DNA sequences in multicentric Castleman’s disease: Is there any relevant association in non-human immunodeficiency virus-infected patients? Blood. 87(1):414–416. 10.1182/blood.V87.1.414.414 8547672
Giffin L, Damania B. 2014. KSHV: Pathways to tumorigenesis and persistent infection. Adv Virus Res. 88:111–159. 10.1016/B978-0-12-800098-4.00002-7 24373311
Giuliani M, Cordiali-Fei P, Castilletti C, Di Carlo A, Palamara G, Boros S, Rezza G. 2007. Incidence of human herpesvirus 8 (HHV-8) infection among HIV-uninfected individuals at high risk for sexually transmitted infections. BMC Infect Dis. 7:143. 10.1186/1471-2334-7-143 18053246
Gloghini A, Dolcetti R, Carbone A. 2013. Lymphomas occurring specifically in HIV-infected patients: From pathogenesis to pathology. Semin Cancer Biol. 23(6):457–467. 10.1016/j.semcancer.2013.08.004 23999127
Goedert JJ, Vitale F, Lauria C, Serraino D, Tamburini M, Montella M, Messina A, Brown EE, Rezza G, Gafa L, et al. 2002. Risk factors for classical Kaposi’s sarcoma. J Natl Cancer Inst. 94(22):1712–1718. 10.1093/jnci/94.22.1712 12441327
Gopal S, Fedoriw Y, Montgomery ND, Kampani C, Krysiak R, Sanders MK, Dittmer DP, Liomba NG. 2014. Multicentric Castleman’s disease in Malawi. Lancet. 384(9948):1158. 10.1016/S0140-6736(14)61366-0 25241721
Greenblatt RM, Jacobson LP, Levine AM, Melnick S, Anastos K, Cohen M, DeHovitz J, Young MA, Burns D, Miotti P, et al. 2001. Human herpesvirus 8 infection and Kaposi’s sarcoma among human immunodeficiency virus-infected and -uninfected women. J Infect Dis. 183(7):1130–1134. 10.1086/319270 11237842
Grulich AE, Olsen SJ, Luo K, Hendry O, Cunningham P, Cooper DA, Gao SJ, Chang Y, Moore PS, Kaldor JM. 1999. Kaposi’s sarcoma-associated herpesvirus: A sexually transmissible infection? J Acquir Immune Defic Syndr Hum Retrovirol. 20(4):387–393. 10.1097/00042560-199904010-00010 10096584
Guo HG, Sadowska M, Reid W, Tschachler E, Hayward G, Reitz M. 2003. Kaposi’s sarcoma-like tumors in a human herpesvirus 8 ORF74 transgenic mouse. J Virol. 77(4):2631–2639. 10.1128/JVI.77.4.2631-2639.2003 12552002
Güvenc MG, Midilli K, Ozdogan A, Inci E, Tahamiler R, Enver O, Sirin G, Ergin S, Kuskucu M, Divanoglu EO, et al. 2008. Detection of HHV-8 and HPV in laryngeal carcinoma. Auris Nasus Larynx. 35(3):357–362. 10.1016/j.anl.2007.08.006 17977679
Herman PS, Shogreen MR, White WL. 1998. The evaluation of human herpesvirus 8 (Kaposi’s sarcoma-associated herpesvirus) in cutaneous lesions of Kaposi’s sarcoma: A study of formalin-fixed paraffin-embedded tissue. Am J Dermatopathol. 20(1):7–11. 10.1097/00000372-199802000-00002 9504662
Hiatt KM, Nelson AM, Lichy JH, Fanburg-Smith JC. 2008. Classic Kaposi Sarcoma in the United States over the last two decades: A clinicopathologic and molecular study of 438 non-HIV-related Kaposi Sarcoma patients with comparison to HIV-related Kaposi Sarcoma. Mod Pathol. 21(5):572–582. 10.1038/modpathol.2008.15 18376387
Hill AB. 1965. The environment and disease: Association or causation? J R Soc Med. 108(1):32–37. 10.1177/0141076814562718 25572993
Hosseini-Moghaddam SM, Soleimanirahbar A, Mazzulli T, Rotstein C, Husain S. 2012. Post renal transplantation Kaposi’s sarcoma: A review of its epidemiology, pathogenesis, diagnosis, clinical aspects, and therapy. Transpl Infect Dis. 14(4):338–345. 10.1111/j.1399-3062.2011.00714.x 22316356
Hosseinipour MC, Sweet KM, Xiong J, Namarika D, Mwafongo A, Nyirenda M, Chiwoko L, Kamwendo D, Hoffman I, Lee J, et al. 2014. Viral profiling identifies multiple subtypes of Kaposi’s sarcoma. MBio. 5(5):e01633-14. 10.1128/mBio.01633-14 25249280
Howard MR, Whitby D, Bahadur G, Suggett F, Boshoff C, Tenant-Flowers M, Schulz TF, Kirk S, Matthews S, Weller IV, et al. 1997. Detection of human herpesvirus 8 DNA in semen from HIV-infected individuals but not healthy semen donors. AIDS. 11(2):F15–F19. 10.1097/00002030-199702000-00001 9030358
Huang WY, Hayes R, Pfeiffer R, Viscidi RP, Lee FK, Wang YF, Reding D, Whitby D, Papp JR, Rabkin CS. 2008. Sexually transmissible infections and prostate cancer risk. Cancer Epidemiol Biomarkers Prev. 17(9):2374–2381. 10.1158/1055-9965.EPI-08-0173 18768506
Humphrey RW, O’Brien TR, Newcomb FM, Nishihara H, Wyvill KM, Ramos GA, Saville MW, Goedert JJ, Straus SE, Yarchoan R. 1996. Kaposi’s sarcoma (KS)-associated herpesvirus-like DNA sequences in peripheral blood mononuclear cells: Association with KS and persistence in patients receiving anti-herpesvirus drugs. Blood. 88(1):297–301. 10.1182/blood.V88.1.297.297 8704186
International Agency for Research on Cancer (IARC). 1997 a. IARC Working Group on the Evaluation of Carcinogenic Risks to Humans. Lyon, France: International Agency for Research on Cancer; Epstein-Barr virus and Kaposi’s sarcoma herpesvirus/human herpesvirus 8; p. 549.
International Agency for Research on Cancer (IARC). 1997 b. Epstein-Barr Virus and Kaposi’s Sarcoma Herpesvirus/Human Herpesvirus 8. Lyon, France: International Agency for Research on Cancer; Karposi sarcoma herpesvirus/Human herpesvirus 8; p. 375–492.
International Agency for Research on Cancer (IARC). 2008. WHO Classification of Tumours of Haematopoietic and Lymphoid Tissues. Vol. 2. 4th ed. Lyon, France: International Agency for Research on Cancer.
International Agency for Research on Cancer (IARC). 2012. Biological Agents. Lyon, France: International Agency for Research on Cancer; Karposi sarcoma herpesvirus; p. 169–214.
Ismail SI, Mahmoud IS, Salman MA, Sughayer MA, Mahafzah AM. 2011. Frequent detection of Human Herpes Virus-8 in bone marrow of Jordanian patients of multiple myeloma. Cancer Epidemiol. 35(5):471–474. 10.1016/j.canep.2010.10.006 21130059
Jacobson LP, Jenkins FJ, Springer G, Munoz A, Shah KV, Phair J, Zhang Z, Armenian H. 2000. Interaction of human immunodeficiency virus type 1 and human herpesvirus type 8 infections on the incidence of Kaposi’s sarcoma. J Infect Dis. 181(6):1940–1949. 10.1086/315503 10837173
Jalilvand S, Shoja Z, Mokhtari-Azad T, Nategh R, Gharehbaghian A. 2011. Seroprevalence of Human herpesvirus 8 (HHV-8) and incidence of Kaposi’s sarcoma in Iran. Infect Agent Cancer. 6:5. 10.1186/1750-9378-6-5 21527020
Jalilvand S, Tornesello ML, Buonaguro FM, Buonaguro L, Naraghi ZS, Shoja Z, Ziaee AA, Hamkar R, Shahmahmoodi S, Nategh R, et al. 2012. Molecular epidemiology of human herpesvirus 8 variants in Kaposi’s sarcoma from Iranian patients. Virus Res. 163(2):644–649. 10.1016/j.virusres.2011.09.027 21963664
Judde JG, Lacoste V, Briere J, Kassa-Kelembho E, Clyti E, Couppie P, Buchrieser C, Tulliez M, Morvan J, Gessain A. 2000. Monoclonality or oligoclonality of human herpesvirus 8 terminal repeat sequences in Kaposi’s sarcoma and other diseases. J Natl Cancer Inst. 92(9):729–736. 10.1093/jnci/92.9.729 10793109
Kanno T, Sato Y, Nakamura T, Sakamoto K, Sata T, Katano H. 2010. Genotypic and clinicopathological characterization of Kaposi’s sarcoma-associated herpesvirus infection in Japan. J Med Virol. 82(3):400–406. 10.1002/jmv.21715 20087946
Kapelushnik J, Ariad S, Benharroch D, Landau D, Moser A, Delsol G, Brousset P. 2001. Post renal transplantation human herpesvirus 8-associated lymphoproliferative disorder and Kaposi’s sarcoma. Br J Haematol. 113(2):425–428. 10.1046/j.1365-2141.2001.02740.x 11380409
Katano H, Hoshino Y, Morishita Y, Nakamura T, Satoh H, Iwamoto A, Herndier B, Mori S. 1999. Establishing and characterizing a CD30-positive cell line harboring HHV-8 from a primary effusion lymphoma. J Med Virol. 58(4):394–401. 10.1002/(SICI)1096-9071(199908)58:4<394::AID-JMV12>3.0.CO;2-H 10421407
Kazakov DV, Prinz BM, Michaelis S, Schmid M, Muller B, Adams V, Burg G, Kempf W. 2002. Study of HHV-8 DNA sequences in archival biopsies from lesional skin of Kaposi’s sarcoma, various mesenchymal tumors and related reactive conditions. J Cutan Pathol. 29(5):279–281. 10.1034/j.1600-0560.2002.290503.x 12100627
Kedes DH, Ganem D, Ameli N, Bacchetti P, Greenblatt R. 1997. The prevalence of serum antibody to human herpesvirus 8 (Kaposi sarcoma-associated herpesvirus) among HIV-seropositive and high-risk HIV-seronegative women. JAMA. 277(6):478–481. 10.1001/jama.1997.03540300046032 9020272
Kedes DH, Operskalski E, Busch M, Kohn R, Flood J, Ganem D. 1996. The seroepidemiology of human herpesvirus 8 (Kaposi’s sarcoma-associated herpesvirus): Distribution of infection in KS risk groups and evidence for sexual transmission. Nat Med. 2(8):918–924. 10.1038/nm0896-918 8705863
Keller R, Zago A, Viana MC, Bourboulia D, Desgranges C, Casseb J, Moura WV, Dietze R, Collandre H. 2001. HHV-8 infection in patients with AIDS-related Kaposi’s sarcoma in Brazil. Braz J Med Biol Res. 34(7):879–886. 10.1590/S0100-879X2001000700007 11449306
Kishimoto K, Kitamura T, Hirayama Y, Tate G, Mitsuya T. 2009. Cytologic and immunocytochemical features of EBV negative primary effusion lymphoma: Report on seven Japanese cases. Diagn Cytopathol. 37(4):293–298. 10.1002/dc.21022 19217041
Knowlton ER, Lepone LM, Li J, Rappocciolo G, Jenkins FJ, Rinaldo CR. 2013. Professional antigen presenting cells in human herpesvirus 8 infection. Front Immunol. 3:427. 10.3389/fimmu.2012.00427 23346088
Kollmann K, Heller G, Schneckenleithner C, Warsch W, Scheicher R, Ott RG, Schafer M, Fajmann S, Schlederer M, Schiefer AI, et al. 2013. A kinase-independent function of CDK6 links the cell cycle to tumor angiogenesis. Cancer Cell. 24(2):167–181. 10.1016/j.ccr.2013.07.012 23948297
Koski L, Ngoma T, Mwaiselage J, Le L, Soliman AS. 2014. Changes in the pattern of Kaposi's sarcoma at Ocean Road Cancer Institute in Tanzania (2006-2011). Int J STD AIDS.
Krown SE, Lee JY, Dittmer DP. 2008. More on HIV-associated Kaposi’s sarcoma. N Engl J Med. 358(5):535–536, author reply 536. 10.1056/NEJMc072994 18234764
Labo N, Miley W, Benson CA, Campbell TB, Whitby D. 2015. Epidemiology of Kaposi’s sarcoma-associated herpesvirus in HIV-1-infected US persons in the era of combination antiretroviral therapy. AIDS. 29(10):1217–1225. 10.1097/QAD.0000000000000682 26035321
Lager I, Altini M, Coleman H, Ali H. 2003. Oral Kaposi’s sarcoma: A clinicopathologic study from South Africa. Oral Surg Oral Med Oral Pathol Oral Radiol Endod. 96(6):701–710. 10.1016/S1079-2104(03)00370-6 14676761
Laney AS, Cannon MJ, Jaffe HW, Offermann MK, Ou CY, Radford KW, Patel MM, Spira TJ, Gunthel CJ, Pellett PE, et al. 2007. Human herpesvirus 8 presence and viral load are associated with the progression of AIDS-associated Kaposi’s sarcoma. AIDS. 21(12):1541–1545. 10.1097/QAD.0b013e3282202b7d 17630548
Lanternier F, Lebbe C, Schartz N, Farhi D, Marcelin AG, Kerob D, Agbalika F, Verola O, Gorin I, Janier M, et al. 2008. Kaposi’s sarcoma in HIV-negative men having sex with men. AIDS. 22(10):1163–1168. 10.1097/QAD.0b013e3283031a8a 18525262
Lefrère JJ, Meyohas MC, Mariotti M, Meynard JL, Thauvin M, Frottier J. 1996. Detection of human herpesvirus 8 DNA sequences before the appearance of Kaposi’s sarcoma in human immunodeficiency virus (HIV)-positive subjects with a known date of HIV seroconversion. J Infect Dis. 174(2):283–287. 10.1093/infdis/174.2.283 8699056
Li Q, He M, Zhou F, Ye F, Gao SJ. 2014. Activation of Kaposi’s sarcoma-associated herpesvirus (KSHV) by inhibitors of class III histone deacetylases: Identification of sirtuin 1 as a regulator of the KSHV life cycle. J Virol. 88(11):6355–6367. 10.1128/JVI.00219-14 24672028
Luppi M, Barozzi P, Maiorana A, Collina G, Ferrari MG, Marasca R, Morselli M, Rossi E, Ceccherini-Nelli L, Torelli G. 1996. Frequency and distribution of herpesvirus-like DNA sequences (KSHV) in different stages of classic Kaposi’s sarcoma and in normal tissues from an Italian population. Int J Cancer. 66(4):427–431. 10.1002/(SICI)1097-0215(19960516)66:4<427::AID-IJC3>3.0.CO;2-Y 8635855
Luppi M, Barozzi P, Schulz TF, Setti G, Staskus K, Trovato R, Narni F, Donelli A, Maiorana A, Marasca R, et al. 2000 a. Bone marrow failure associated with human herpesvirus 8 infection after transplantation. N Engl J Med. 343(19):1378–1385. 10.1056/NEJM200011093431905 11070102
Luppi M, Barozzi P, Schulz TF, Trovato R, Donelli A, Narni F, Sheldon J, Marasca R, Torelli G. 2000 b. Nonmalignant disease associated with human herpesvirus 8 reactivation in patients who have undergone autologous peripheral blood stem cell transplantation. Blood. 96(7):2355–2357. 10.1182/blood.V96.7.2355.h8002355_2355_2357 11001882
Magri MC, Carbone PH, de los Santos-Fortuna E, Caterino-de-Araujo A. 2009. A comparative study of the frequency of antibody and titers against human herpesvirus 8 latent and lytic antigens in “at-risk” individuals and among patients with Kaposi’s sarcoma. J Med Virol. 81(7):1292–1297. 10.1002/jmv.21513 19475629
Marcelin AG, Roque-Afonso AM, Hurtova M, Dupin N, Tulliez M, Sebagh M, Arkoub ZA, Guettier C, Samuel D, Calvez V, et al. 2004. Fatal disseminated Kaposi’s sarcoma following human herpesvirus 8 primary infections in liver-transplant recipients. Liver Transpl. 10(2):295–300. 10.1002/lt.20058 14762870
Martin JN. 2007. The epidemiology of KSHV and its association with malignant disease. In: Arvin A, Campadelli-Fiume G, Mocarski E, Moore PS, Roizman B, Whitley R, Yamanishi K, editors. Human Herpesviruses: Biology, Therapy, and Immunoprophylaxis. Cambridge: Cambridge University Press. 10.1017/CBO9780511545313.055
Martin JN, Ganem DE, Osmond DH, Page-Shafer KA, Macrae D, Kedes DH. 1998. Sexual transmission and the natural history of human herpesvirus 8 infection. N Engl J Med. 338(14):948–954. 10.1056/NEJM199804023381403 9521982
Martró E, Esteve A, Schulz TF, Sheldon J, Gambus G, Munoz R, Whitby D, Casabona J, Euro-Shaks study group. 2007. Risk factors for human Herpesvirus 8 infection and AIDS-associated Kaposi’s sarcoma among men who have sex with men in a European multicentre study. Int J Cancer. 120(5):1129–1135. 10.1002/ijc.22281 17154170
Massambu C, Pyakurel P, Kaaya E, Enbom M, Urassa W, Demirhan I, Loewer J, Linde A, Chandra A, Heiden T, et al. 2003. Serum HHV8 DNA and Tat antibodies in Kaposi’s sarcoma patients with and without HIV-1 infection. Anticancer Res. 23 3B:2389–2395. 12894519
McDonald AC, Jenkins FJ, Bunker CH, Wilson JW, Patrick AL, Weissfeld JL. 2011. A case-cohort study of human herpesvirus 8 seropositivity and incident prostate cancer in Tobago. Infect Agent Cancer. 6:25. 10.1186/1750-9378-6-25 22151996
McLemore MS, Haigentz M Jr, Smith RV, Nuovo GJ, Alos L, Cardesa A, Brandwein-Gensler M. 2010. Head and neck squamous cell carcinomas in HIV-positive patients: A preliminary investigation of viral associations. Head Neck Pathol. 4(2):97–105. 10.1007/s12105-010-0171-9 20333562
Melbye M, Cook PM, Hjalgrim H, Begtrup K, Simpson GR, Biggar RJ, Ebbesen P, Schulz TF. 1998. Risk factors for Kaposi’s-sarcoma-associated herpesvirus (KSHV/HHV-8) seropositivity in a cohort of homosexual men, 1981-1996. Int J Cancer. 77(4):543–548. 10.1002/(SICI)1097-0215(19980812)77:4<543::AID-IJC12>3.0.CO;2-7 9679756
Mesri EA, Cesarman E. 2011. Kaposi’s sarcoma herpesvirus oncogenesis is a notch better in 3D. Cell Host Microbe. 10(6):529–531. 10.1016/j.chom.2011.11.008 22177556
Mesri EA, Cesarman E, Boshoff C. 2010. Kaposi’s sarcoma and its associated herpesvirus. Nat Rev Cancer. 10(10):707–719. 10.1038/nrc2888 20865011
Mesri EA, Feitelson MA, Munger K. 2014. Human viral oncogenesis: A cancer hallmarks analysis. Cell Host Microbe. 15(3):266–282. 10.1016/j.chom.2014.02.011 24629334
Miller G, Rigsby MO, Heston L, Grogan E, Sun R, Metroka C, Levy JA, Gao SJ, Chang Y, Moore P. 1996. Antibodies to butyrate-inducible antigens of Kaposi’s sarcoma-associated herpesvirus in patients with HIV-1 infection. N Engl J Med. 334(20):1292–1297. 10.1056/NEJM199605163342003 8609946
Min J, Katzenstein DA. 1999. Detection of Kaposi’s sarcoma-associated herpesvirus in peripheral blood cells in human immunodeficiency virus infection: Association with Kaposi’s sarcoma, CD4 cell count, and HIV RNA levels. AIDS Res Hum Retroviruses. 15(1):51–55. 10.1089/088922299311709 10024052
Minhas V, Wood C. 2014. Epidemiology and transmission of Kaposi’s sarcoma-associated herpesvirus. Viruses. 6(11):4178–4194. 10.3390/v6114178 25375883
Mohamadian Roshan N, Jafarian A, Ayatollahi H, Ghazvini K, Abbas Tabatabaee S. 2014. Correlation of laryngeal squamous cell carcinoma and infections with either HHV-8 or HPV-16/18. Pathol Res Pract. 210:205–209. 10.1016/j.prp.2013.12.001 24417904
Monini P, de Lellis L, Cassai E. 1996 a. Absence of HHV-8 in prostate and semen: Author’s reply. N Engl J Med. 335(6):1237–1239.
Monini P, de Lellis L, Fabris M, Rigolin F, Cassai E. 1996 b. Kaposi’s sarcoma-associated herpesvirus DNA sequences in prostate tissue and human semen. N Engl J Med. 334(18):1168–1172. 10.1056/NEJM199605023341805 8602183
Montaner S, Sodhi A, Ramsdell AK, Martin D, Hu J, Sawai ET, Gutkind JS. 2006. The Kaposi’s sarcoma-associated herpesvirus G protein-coupled receptor as a therapeutic target for the treatment of Kaposi’s sarcoma. Cancer Res. 66(1):168–174. 10.1158/0008-5472.CAN-05-1026 16397229
Moody R, Zhu Y, Huang Y, Cui X, Jones T, Bedolla R, Lei X, Bai Z, Gao SJ. 2013. KSHV microRNAs mediate cellular transformation and tumorigenesis by redundantly targeting cell growth and survival pathways. PLoS Pathog. 9(12):e1003857. 10.1371/journal.ppat.1003857 24385912
Moore PS, Chang Y. 1995. Detection of herpesvirus-like DNA sequences in Kaposi’s sarcoma in patients with and without HIV infection. N Engl J Med. 332(18):1181–1185. 10.1056/NEJM199505043321801 7700310
Moore PS, Chang Y. 1998. Kaposi’s sarcoma (KS), KS-associated herpesvirus, and the criteria for causality in the age of molecular biology. Am J Epidemiol. 147(3):217–221. 10.1093/oxfordjournals.aje.a009440 9482495
Moore PS, Chang Y. 2010. Why do viruses cause cancer? Highlights of the first century of human tumour virology. Nat Rev Cancer. 10(12):878–889. 10.1038/nrc2961 21102637
Moore PS, Chang Y. 2014. The conundrum of causality in tumor virology: The cases of KSHV and MCV. Semin Cancer Biol. 26:4–12. 10.1016/j.semcancer.2013.11.001 24304907
Moore PS, Kingsley LA, Holmberg SD, Spira T, Gupta P, Hoover DR, Parry JP, Conley LJ, Jaffe HW, Chang Y. 1996. Kaposi’s sarcoma-associated herpesvirus infection prior to onset of Kaposi’s sarcoma. AIDS. 10(2):175–180. 10.1097/00002030-199602000-00007 8838705
Mousavi SM, Sundquist J, Hemminki K. 2014. Risk of Kaposi sarcoma among immigrants to Sweden. Acta Derm Venereol. 94(4):476–477. 10.2340/00015555-1754 24212288
Mutlu AD, Cavallin LE, Vincent L, Chiozzini C, Eroles P, Duran EM, Asgari Z, Hooper AT, La Perle KM, Hilsher C, et al. 2007. In vivo-restricted and reversible malignancy induced by human herpesvirus-8 KSHV: A cell and animal model of virally induced Kaposi’s sarcoma. Cancer Cell. 11(3):245–258. 10.1016/j.ccr.2007.01.015 17349582
Mwakigonja AR, Pyakurel P, Kokhaei P, Pak F, Lema LK, Kaaya EE, Biberfeld P. 2008. Human herpesvirus-8 (HHV-8) sero-detection and HIV association in Kaposi’s sarcoma (KS), non-KS tumors and non-neoplastic conditions. Infect Agent Cancer. 3:10. 10.1186/1750-9378-3-10 18590556
Nador RG, Cesarman E, Chadburn A, Dawson DB, Ansari MQ, Sald J, Knowles DM. 1996. Primary effusion lymphoma: A distinct clinicopathologic entity associated with the Kaposi’s sarcoma-associated herpes virus. Blood. 88(2):645–656. 10.1182/blood.V88.2.645.bloodjournal882645 8695812
Nalwoga A, Cose S, Wakeham K, Miley W, Ndibazza J, Drakeley C, Elliott A, Whitby D, Newton R. 2015. Association between malaria exposure and Kaposi’s sarcoma-associated herpes virus seropositivity in Uganda. Trop Med Int Health. 20(5):665–672. 10.1111/tmi.12464 25611008
National Cancer Institute (NCI). 2014. A snapshot of Kaposi sarcoma. National Cancer Institute. https://www.cancer.gov/researchandfunding/snapshots/kaposisarcoma. [Accessed: February 20, 2015]
National Toxicology Program (NTP). 2015. Handbook for preparing the report on carcinogens monographs. Research Triangle Park, NC: National Toxicology Program. https://ntp.niehs.nih.gov/ntp/roc/handbook/roc_handbook_508.pdf.
Nawar EW, Cole SR, Farzadegan H, Witt MD, Jenkins FJ, Margolick JB, Phair JP, Jacobson LP. 2008. Sexual activity and Kaposi’s sarcoma among human immunodeficiency virus type 1 and human herpesvirus type 8-coinfected men. Ann Epidemiol. 18(7):517–521. 10.1016/j.annepidem.2008.03.009 18504143
Newton R, Carpenter L, Casabonne D, Beral V, Babiker A, Darbyshire J, Weller I, Weiss R, Kwan A, Bourboulia D, et al. 2006. A prospective study of Kaposi’s sarcoma-associated herpesvirus and Epstein-Barr virus in adults with human immunodeficiency virus-1. Br J Cancer. 94(10):1504–1509. 10.1038/sj.bjc.6603100 16705315
Newton R, Ziegler J, Bourboulia D, Casabonne D, Beral V, Mbidde E, Carpenter L, Parkin DM, Wabinga H, Mbulaiteye S, et al. 2003 a. Infection with Kaposi’s sarcoma-associated herpesvirus (KSHV) and human immunodeficiency virus (HIV) in relation to the risk and clinical presentation of Kaposi’s sarcoma in Uganda. Br J Cancer. 89(3):502–504. 10.1038/sj.bjc.6601113 12888820
Newton R, Ziegler J, Bourboulia D, Casabonne D, Beral V, Mbidde E, Carpenter L, Reeves G, Parkin DM, Wabinga H, et al. 2003 b. The sero-epidemiology of Kaposi’s sarcoma-associated herpesvirus (KSHV/HHV-8) in adults with cancer in Uganda. Int J Cancer. 103(2):226–232. 10.1002/ijc.10817 12455037
Noel JC. 1995. Kaposi’s sarcoma and KSHV. Lancet. 346(8986):1359. 10.1016/S0140-6736(95)92370-5 7475782
Nsubuga MM, Biggar RJ, Combs S, Marshall V, Mbisa G, Kambugu F, Mehta M, Biryahwaho B, Rabkin CS, Whitby D, et al. 2008. Human herpesvirus 8 load and progression of AIDS-related Kaposi sarcoma lesions. Cancer Lett. 263(2):182–188. 10.1016/j.canlet.2007.12.025 18234418
O'Brien TR, Kedes D, Ganem D, Macrae DR, Rosenberg PS, Molden J, Goedert JJ. 1999. Evidence for concurrent epidemics of human herpesvirus 8 and human immunodeficiency virus type 1 in US homosexual men: Rates, risk factors, and relationship to Kaposi’s sarcoma. J Infect Dis. 180(4):1010–1017. 10.1086/315039 10479125
Ogoina D, Onyemelukwe GC, Musa BO, Babadoko A. 2011. Human Herpesvirus 8 infections and AIDS-associated Kaposi sarcoma in Zaria, Northern Nigeria. J Int Assoc Physicians AIDS Care (Chic). 10(1):43–48. 10.1177/1545109710387300 21368014
Oksenhendler E, Boulanger E, Galicier L, Du MQ, Dupin N, Diss TC, Hamoudi R, Daniel MT, Agbalika F, Boshoff C, et al. 2002. High incidence of Kaposi sarcoma-associated herpesvirus-related non-Hodgkin lymphoma in patients with HIV infection and multicentric Castleman disease. Blood. 99(7):2331–2336. 10.1182/blood.V99.7.2331 11895764
Oksenhendler E, Boutboul D, Beldjord K, Meignin V, de Labarthe A, Fieschi C, Dossier A, Agbalika F, Parravicini C, Tosato G, et al. 2013. Human herpesvirus 8+ polyclonal IgMlambda B-cell lymphocytosis mimicking plasmablastic leukemia/lymphoma in HIV-infected patients. Eur J Haematol. 91(6):497–503. 10.1111/ejh.12191 23992152
Pan ZG, Zhang QY, Lu ZB, Quinto T, Rozenvald IB, Liu LT, Wilson D, Reddy V, Huang Q, Wang HY, et al. 2012. Extracavitary KSHV-associated large B-Cell lymphoma: A distinct entity or a subtype of primary effusion lymphoma? Study of 9 cases and review of an additional 43 cases. Am J Surg Pathol. 36(8):1129–1140. 10.1097/PAS.0b013e31825b38ec 22790853
Panagiotakis GI, Papadogianni D, Chatziioannou MN, Lasithiotaki I, Delakas D, Spandidos DA. 2013. Association of human herpes, papilloma and polyoma virus families with bladder cancer. Tumour Biol. 34(1):71–79. 10.1007/s13277-012-0512-2 22972505
Pantry SN, Medveczky PG. 2009. Epigenetic regulation of Kaposi’s sarcoma-associated herpesvirus replication. Semin Cancer Biol. 19(3):153–157. 10.1016/j.semcancer.2009.02.010 19429478
Parravicini C, Chandran B, Corbellino M, Berti E, Paulli M, Moore PS, Chang Y. 2000. Differential viral protein expression in Kaposi’s sarcoma-associated herpesvirus-infected diseases: Kaposi’s sarcoma, primary effusion lymphoma, and multicentric Castleman’s disease. Am J Pathol. 156(3):743–749. 10.1016/S0002-9440(10)64940-1 10702388
Parravicini C, Olsen SJ, Capra M, Poli F, Sirchia G, Gao SJ, Berti E, Nocera A, Rossi E, Bestetti G, et al. 1997. Risk of Kaposi’s sarcoma-associated herpes virus transmission from donor allografts among Italian posttransplant Kaposi’s sarcoma patients. Blood. 90(7):2826–2829. 9326251
Parry JP, Moore PS. 1997. Corrected prevalence of Kaposi’s sarcoma (KS)-associated herpesvirus infection prior to onset of KS. AIDS. 11(1):127–128. 9110091
Pellett PE, Wright DJ, Engels EA, Ablashi DV, Dollard SC, Forghani B, Glynn SA, Goedert JJ, Jenkins FJ, Lee TH, et al. 2003. Multicenter comparison of serologic assays and estimation of human herpesvirus 8 seroprevalence among US blood donors. Transfusion. 43(9):1260–1268. 10.1046/j.1537-2995.2003.00490.x 12919429
Pelser C, Middeldorp J, Mbulaiteye SM, Lauria C, Messina A, Viviano E, Romano N, Vitale F, Goedert JJ. 2010. Risk of classical Kaposi sarcoma by plasma levels of Epstein-Barr virus antibodies, sCD26, sCD23 and sCD30. Infect Agent Cancer. 5:18. 10.1186/1750-9378-5-18 20939920
Polizzotto MN, Uldrick TS, Hu D, Yarchoan R. 2012. Clinical manifestations of Kaposi sarcoma herpesvirus lytic activation: Multicentric Castleman disease (KSHV-MCD) and the KSHV inflammatory cytokine syndrome. Front Microbiol. 3:73. 10.3389/fmicb.2012.00073 22403576
Powles T, Stebbing J, Bazeos A, Hatzimichael E, Mandalia S, Nelson M, Gazzard B, Bower M. 2009. The role of immune suppression and HHV-8 in the increasing incidence of HIV-associated multicentric Castleman’s disease. Ann Oncol. 20(4):775–779. 10.1093/annonc/mdn697 19179554
Purushothaman P, Uppal T, Verma SC. 2015. Molecular biology of KSHV lytic reactivation. Viruses. 7(1):116–153. 10.3390/v7010116 25594835
Qin Z, Kearney P, Plaisance K, Parsons CH. 2010. Pivotal advance: Kaposi’s sarcoma-associated herpesvirus (KSHV)-encoded microRNA specifically induce IL-6 and IL-10 secretion by macrophages and monocytes. J Leukoc Biol. 87(1):25–34. 10.1189/jlb.0409251 20052801
Quinlivan EB, Wang RX, Stewart PW, Kolmoltri C, Regamey N, Erb P, Vernazza PL, Swiss HIVCS. 2001. Longitudinal sero-reactivity to human herpesvirus 8 (KSHV) in the Swiss HIV Cohort 4.7 years before KS. J Med Virol. 64(2):157–166. 10.1002/jmv.1031 11360248
Rabkin CS, Shepherd FA, Wade JA. 1999. Human herpesvirus 8 and renal transplantation. N Engl J Med. 340(13):1045–1046. 10.1056/NEJM199904013401314 10189288
Reddy D, Mitsuyasu R. 2011. HIV-associated multicentric Castleman disease. Curr Opin Oncol. 23(5):475–481. 10.1097/CCO.0b013e328349c233 21760504
Regamey N, Cathomas G, Schwager M, Wernli M, Harr T, Erb P. 1998. High human herpesvirus 8 seroprevalence in the homosexual population in Switzerland. J Clin Microbiol. 36(6):1784–1786. 10.1128/JCM.36.6.1784-1786.1998 9620422
Renwick N, Halaby T, Weverling GJ, Dukers NH, Simpson GR, Coutinho RA, Lange JM, Schulz TF, Goudsmit J. 1998. Seroconversion for human herpesvirus 8 during HIV infection is highly predictive of Kaposi’s sarcoma. AIDS. 12(18):2481–2488. 10.1097/00002030-199818000-00018 9875587
Rezza G, Andreoni M, Dorrucci M, Pezzotti P, Monini P, Zerboni R, Salassa B, Colangeli V, Sarmati L, Nicastri E, et al. 1999. Human herpesvirus 8 seropositivity and risk of Kaposi’s sarcoma and other acquired immunodeficiency syndrome-related diseases. J Natl Cancer Inst. 91(17):1468–1474. 10.1093/jnci/91.17.1468 10469747
Rothman KJ, Greenland S. 2005. Causation and causal inference in epidemiology. Am J Public Health. 95 Suppl 1:S144–S150. 10.2105/AJPH.2004.059204 16030331
Rouhani P, Fletcher CD, Devesa SS, Toro JR. 2008. Cutaneous soft tissue sarcoma incidence patterns in the U.S.: An analysis of 12,114 cases. Cancer. 113(3):616–627. 10.1002/cncr.23571 18618615
Sadeghian MH, Katebi M, Ayatollahi H, Keramati MR. 2008. Immunohistochemical study association between human herpesvirus 8 and multiple myeloma. Int J Hematol. 88(3):283–286. 10.1007/s12185-008-0135-y 18629602
Schönrich G, Raftery M, Schnitzler P, Rohr U, Goldschmidt H. 1998. Absence of a correlation between Kaposi’s sarcoma-associated herpesvirus (KSHV/HHV-8) and multiple myeloma. Blood. 92(9):3474–3475. 10.1182/blood.V92.9.3474 9787190
SEER. 2015. SEER Stat Fact Sheets: Myeloma. National Cancer Institute. https://seer.cancer.gov/statfacts/html/mulmy.html.
Senba M, Buziba N, Mori N, Morimoto K, Nakamura T. 2011. Increased prevalence of Kaposis sarcoma-associated herpesvirus in the Kaposis sarcoma-endemic area of western Kenya in 1981-2000. Acta Virol. 55(2):161–164. 10.4149/av_2011_02_161 21692565
Simbiri KO, Jha HC, Kayembe MK, Kovarik C, Robertson ES. 2014. Oncogenic viruses associated with vulva cancer in HIV-1 patients in Botswana. Infect Agent Cancer. 9:28. 10.1186/1750-9378-9-28 25225572
Simonelli C, Spina M, Cinelli R, Talamini R, Tedeschi R, Gloghini A, Vaccher E, Carbone A, Tirelli U. 2003. Clinical features and outcome of primary effusion lymphoma in HIV-infected patients: A single-institution study. J Clin Oncol. 21(21):3948–3954. 10.1200/JCO.2003.06.013 14581418
Sin SH, Dittmer DP. 2013. Viral latency locus augments B-cell response in vivo to induce chronic marginal zone enlargement, plasma cell hyperplasia, and lymphoma. Blood. 121(15):2952–2963. 10.1182/blood-2012-03-415620 23365457
Sin SH, Kim Y, Eason A, Dittmer DP. 2015. KSHV latency locus cooperates with myc to drive lymphoma in mice. PLoS Pathog. 11(9):e1005135. 10.1371/journal.ppat.1005135 26327622
Sitas F, Carrara H, Beral V, Newton R, Reeves G, Bull D, Jentsch U, Pacella-Norman R, Bourboulia D, Whitby D, et al. 1999. Antibodies against human herpesvirus 8 in black South African patients with cancer. N Engl J Med. 340(24):1863–1871. 10.1056/NEJM199906173402403 10369849
Sitas F, Newton R. 2001. Kaposi’s sarcoma in South Africa. J Natl Cancer Inst Monogr. 2000(28):1–4. 10.1093/oxfordjournals.jncimonographs.a024250 11158199
Smith NA, Sabin CA, Gopal R, Bourboulia D, Labbet W, Boshoff C, Barlow D, Band B, Peters BS, de Ruiter A, et al. 1999. Serologic evidence of human herpesvirus 8 transmission by homosexual but not heterosexual sex. J Infect Dis. 180(3):600–606. 10.1086/314926 10438345
Sodhi A, Montaner S, Patel V, Zohar M, Bais C, Mesri EA, Gutkind JS. 2000. The Kaposi’s sarcoma-associated herpes virus G protein-coupled receptor up-regulates vascular endothelial growth factor expression and secretion through mitogen-activated protein kinase and p38 pathways acting on hypoxia-inducible factor 1alpha. Cancer Res. 60(17):4873–4880. 10987301
Soulier J, Grollet L, Oksenhendler E, Cacoub P, Cazals-Hatem D, Babinet P, d’Agay MF, Clauvel JP, Raphael M, Degos L, et al. 1995. Kaposi’s sarcoma-associated herpesvirus-like DNA sequences in multicentric Castleman’s disease. Blood. 86(4):1276–1280. 10.1182/blood.V86.4.1276.bloodjournal8641276 7632932
Stiller CA, Trama A, Brewster DH, Verne J, Bouchardy C, Navarro C, Chirlaque MD, Marcos-Gragera R, Visser O, Serraino D, et al. 2014. Descriptive epidemiology of Kaposi sarcoma in Europe. Report from the RARECARE project. Cancer Epidemiol. 38(6):670–678. 10.1016/j.canep.2014.09.009 25454979
Su CC, Tseng KC, Lin MN, Hsieh TC, Chu TY. 2014. High seroprevalence of human herpesvirus type 8 in patients with hepatocellular carcinoma. Eur J Clin Microbiol Infect Dis. 25037870
Sullivan RJ, Pantanowitz L, Casper C, Stebbing J, Dezube BJ. 2008. HIV/AIDS: Epidemiology, pathophysiology, and treatment of Kaposi sarcoma-associated herpesvirus disease: Kaposi sarcoma, primary effusion lymphoma, and multicentric Castleman disease. Clin Infect Dis. 47(9):1209–1215. 10.1086/592298 18808357
Sutcliffe S, Till C, Jenkins FJ, Gaydos CA, Goodman PJ, Hoque AM, Hsing AW, Thompson IM, Nelson WG, De Marzo AM, et al. 2015. Prospective study of human herpesvirus type 8 serostatus and prostate cancer risk in the placebo arm of the Prostate Cancer Prevention Trial. Cancer Causes Control. 26(1):35–44. 10.1007/s10552-014-0480-5 25359302
Szalai E, Gerlei Z, Szlavik J, Szladek G, Patel R, Hunyadi J, Gergely L, Juhasz A. 2005. Prevalence of human herpesvirus-8 infection in HIV-positive patients with and without Kaposi’s sarcoma in Hungary. FEMS Immunol Med Microbiol. 43(2):265–268. 10.1016/j.femsim.2004.08.012 15681157
Talat N, Schulte KM. 2011. Castleman’s disease: Systematic analysis of 416 patients from the literature. Oncologist. 16(9):1316–1324. 10.1634/theoncologist.2011-0075 21765191
Tedeschi R, Kvarnung M, Knekt P, Schulz TF, Szekely L, De Paoli PD, Aromaa A, Teppo L, Dillner J. 2001. A prospective seroepidemiological study of human herpesvirus-8 infection and the risk of multiple myeloma. Br J Cancer. 84(1):122–125. 10.1054/bjoc.2000.1527 11139326
Tedeschi R, Luostarinen T, De Paoli P, Gislefoss RE, Tenkanen L, Virtamo J, Koskela P, Hallmans G, Lehtinen M, Dillner J. 2005. Joint Nordic prospective study on human herpesvirus 8 and multiple myeloma risk. Br J Cancer. 93(7):834–837. 10.1038/sj.bjc.6602751 16136049
Testa A, Baiocchini A, Comandini UV, Falasca L, Nardacci R, Maritti M, Loiacono L, Bibbolino C, Rizzi EB, Cristofaro M, et al. 2010. Fatal sclerosing peritonitis associated with primary effusion lymphoma after liver transplantation: A case report. Transplant Proc. 42(9):3849–3853. 10.1016/j.transproceed.2010.08.039 21094868
Tiussi RM, Caus AL, Diniz LM, Lucas EA. 2012. Kaposi’s sarcoma: Clinical and pathological aspects in patients seen at the Hospital Universitario Cassiano Antonio Moraes - Vitoria - Espirito Santo - Brazil. An Bras Dermatol. 87(2):220-227. 10.1590/S0365-05962012000200005
Uldrick TS, Polizzotto MN, Wyvill K, Aleman K, Marshall V, Little RF, Filie A, Raffeld M, Steinberg SM, Pittaluga S, et al. 2012. Kaposi sarcoma herpesvirus (KSHV)-associated lymphomas are associated with markedly elevated serum IL-10, elevated IL-6, IL-17 and circulating KSHV. Infect Agent Cancer. 7 Suppl 1:39. 10.1186/1750-9378-7-S1-P39
Uldrick TS, Whitby D. 2011. Update on KSHV epidemiology, Kaposi Sarcoma pathogenesis, and treatment of Kaposi Sarcoma. Cancer Lett. 305(2):150–162. 10.1016/j.canlet.2011.02.006 21377267
van der Kuyl AC, Polstra AM, van den Burg R, Jan Weverling G, Goudsmit J, Cornelissen M. 2005. Cytomegalovirus and human herpesvirus 8 DNA detection in peripheral blood monocytic cells of AIDS patients: Correlations with the presence of Kaposi’s sarcoma and CMV disease. J Med Virol. 76(4):541–546. 10.1002/jmv.20396 15977227
Venkataraman G, Uldrick TS, Aleman K, O’Mahony D, Karcher DS, Steinberg SM, Raffeld MA, Marshall V, Whitby D, Little RF, et al. 2013. Bone marrow findings in HIV-positive patients with Kaposi sarcoma herpesvirus-associated multicentric Castleman disease. Am J Clin Pathol. 139(5):651–661. 10.1309/AJCPKGF7U8AWQBVG 23596117
Wakeham K, Johnston WT, Nalwoga A, Webb EL, Mayanja BN, Miley W, Elliott AM, Whitby D, Newton R. 2015. Trends in Kaposi’s sarcoma-associated Herpesvirus antibodies prior to the development of HIV-associated Kaposi’s sarcoma: A nested case-control study. Int J Cancer. 136(12):2822–2830. 10.1002/ijc.29329 25395177
Wang QJ, Jenkins FJ, Jacobson LP, Kingsley LA, Day RD, Zhang ZW, Meng YX, Pellett PE, Kousoulas KG, Baghian A, et al. 2001. Primary human herpesvirus 8 infection generates a broadly specific CD8(+) T-cell response to viral lytic cycle proteins. Blood. 97(8):2366–2373. 10.1182/blood.V97.8.2366 11290599
Wen KW, Damania B. 2010. Kaposi sarcoma-associated herpesvirus (KSHV): Molecular biology and oncogenesis. Cancer Lett. 289(2):140–150. 10.1016/j.canlet.2009.07.004 19651473
Westrop SJ, Lagos D, Boshoff C, Bower M, Imami N. 2012. African ancestry and innate immunity contribute to the incidence of multicentric Castleman’s disease in HIV-1/Kaposi’s sarcoma herpesvirus-coinfected individuals. Future Virol. 7(7):729–734. 10.2217/fvl.12.54
Whitby D, Howard MR, Tenant-Flowers M, Brink NS, Copas A, Boshoff C, Hatzioannou T, Suggett FE, Aldam DM, Denton AS, et al. 1995. Detection of Kaposi sarcoma associated herpesvirus in peripheral blood of HIV-infected individuals and progression to Kaposi’s sarcoma. Lancet. 346(8978):799–802. 10.1016/S0140-6736(95)91619-9 7674745
Whitby D, Luppi M, Barozzi P, Boshoff C, Weiss RA, Torelli G. 1998. Human herpesvirus 8 seroprevalence in blood donors and lymphoma patients from different regions of Italy. J Natl Cancer Inst. 90(5):395–397. 10.1093/jnci/90.5.395 9498490
Widmer IC, Erb P, Grob H, Itin P, Baumann M, Stalder A, Weber R, Cathomas G. 2006. Human herpesvirus 8 oral shedding in HIV-infected men with and without Kaposi sarcoma. J Acquir Immune Defic Syndr. 42(4):420–425. 10.1097/01.qai.0000226790.31463.e6 16791117
Wu TT, Qian J, Ang J, Sun R. 2012. Vaccine prospect of Kaposi sarcoma-associated herpesvirus. Curr Opin Virol. 2(4):482–488. 10.1016/j.coviro.2012.06.005 22795202
Xiao J, Selvaggi SM, Leith CP, Fitzgerald SA, Stewart J 3rd. 2013. Kaposi sarcoma herpesvirus/human herpesvirus-8-negative effusion-based lymphoma: Report of 3 cases and review of the literature. Cancer Cytopathol. 121(11):661–669. 10.1002/cncy.21311 23765802
Xu GJ, Kula T, Xu Q, Li MZ, Vernon SD, Ndung’u T, Ruxrungtham K, Sanchez J, Brander C, Chung RT, et al. 2015. Viral immunology. Comprehensive serological profiling of human populations using a synthetic human virome. Science. 348(6239):aaa0698. 10.1126/science.aaa0698 26045439
Yang TY, Chen SC, Leach MW, Manfra D, Homey B, Wiekowski M, Sullivan L, Jenh CH, Narula SK, Chensue SW, et al. 2000. Transgenic expression of the chemokine receptor encoded by human herpesvirus 8 induces an angioproliferative disease resembling Kaposi’s sarcoma. J Exp Med. 191(3):445–454. 10.1084/jem.191.3.445 10662790
Yiakoumis X, Pangalis GA, Kyrtsonis MC, Vassilakopoulos TP, Kontopidou FN, Kalpadakis C, Korkolopoulou P, Levidou G, Androulaki A, Siakantaris MP, et al. 2010. Primary effusion lymphoma in two HIV-negative patients successfully treated with pleurodesis as first-line therapy. Anticancer Res. 30(1):271–276. 20150647
Zago A, Bourboulia D, Viana MC, Collandre H, Dietze R, Boshoff C, Keller R. 2000. Seroprevalence of human herpesvirus 8 and its association with Kaposi sarcoma in Brazil. Sex Transm Dis. 27(8):468–472. 10.1097/00007435-200009000-00009 10987454
Zhang H, Yang XY, Hong T, Feldman T, Bhattacharyya PK. 2010. Kaposi sarcoma-associated herpesvirus (human herpesvirus type 8)-associated extracavitary lymphoma: Report of a case in an HIV-positive patient with simultaneous kaposi sarcoma and a review of the literature. Acta Haematol. 123(4):237–241. 10.1159/000314347 20484888
Zhu X, Guo Y, Yao S, Yan Q, Xue M, Hao T, Zhou F, Zhu J, Qin D, Lu C. 2014. Synergy between Kaposi’s sarcoma-associated herpesvirus (KSHV) vIL-6 and HIV-1 Nef protein in promotion of angiogenesis and oncogenesis: Role of the AKT signaling pathway. Oncogene. 33(15):1986–1996. 10.1038/onc.2013.136 23604117
zur Hausen H. 1994. Molecular pathogenesis of cancer of the cervix and its causation by specific human papillomavirus types. Curr Top Microbiol Immunol. 186:131–156. 10.1007/978-3-642-78487-3_8 8205839
zur Hausen H. 2001. Oncogenic DNA viruses. Oncogene. 20(54):7820–7823. 10.1038/sj.onc.1204958 11753664
zur Hausen H, de Villiers EM. 2014. Cancer “causation” by infections—individual contributions and synergistic networks. Semin Oncol. 41(6):860–875. 10.1053/j.seminoncol.2014.10.003 25499643