# 5 Overall Cancer Hazard Evaluation and Listing Recommendation

Human T-cell lymphotropic virus type 1 (HTLV-1) is known to be a human carcinogen based on sufficient evidence from studies in humans. This conclusion is based on epidemiological and molecular studies showing that it causes adult T-cell leukemia/lymphoma in humans, together with supporting evidence from mechanistic studies demonstrating the biological plausibility of its carcinogenicity in humans (Table 5-1). The body of epidemiological studies for liver cancer was judged inadequate based on several limitations such as the small number of studies or few exposed subjects. In addition, there is potential confounding from infection with hepatitis B or C viruses and no available molecular data. Epidemiological studies provided limited evidence for a decreased risk for gastric cancer; however, no molecular data were available for these cancer sites (Table 5-2).

Table 5-1 Summary of the Evidence for HTLV-1 and Adult T-cell Leukemia/Lymphoma from Human Studies

Types of Studies | Adult T-cell Leukemia/Lymphoma (ATLL)
Epidemiological Positive associations | Original link established by case reports/case series; over 550 cases primarily from Japan and South America (1985–2005). HTLV-1 carriers developed ATLL (8 cohorts). Risk higher with higher viral load or proviral load in 4 case-control studies nested in HTLV-1 cohort studies.
Molecular (human tissue) Clonality % HTLV-1 infected tumors HTLV-1 protein expression Other | Monoclonal >90% 40% Tax, 100% HBZ Diagnostic criteria for ATLL
Level of evidence | Sufficient

ATLL = adult T-cell leukemia/lymphoma; HBZ = HTLV-1 basic leucine zipper factor; HTLV = human T-cell lymphotropic virus; NA = not available.

Table 5-2 Summary of the Evidence for HTLV-1 and Gastric and Liver Cancer from Human Studies

Types of Studies | Gastric Cancer | Liver Cancer
Epidemiological Positive associations | Decreased risks in 3 cohort and 1 case-control study. Helicobacter pylori positivity lower in HTLV-1 group compared with negative group. | Positive associations in all studies (4 case-control and 2 cohort studies); most not significant and modest ORs. Bias and confounding cannot be ruled out (potential confounding from infection with hepatitis B or C viruses)
Molecular (human tissue) | No available information | No available information
Level of evidence | Limited for decreased risk | Inadequate

HTLV = human T-cell lymphotropic virus; OR = odds ratio.

Data are inadequate to evaluate the association between HTLV-1 and cutaneous T-cell lymphoma, which has inconsistent evidence from epidemiological studies and no available evidence from molecular studies.

The following tables provide the level of evidence recommendations for the carcinogenicity of HTLV-1 for each endpoint from studies in humans, including the key data from both epidemiological and molecular studies in humans.