# 4 Mechanisms and Other Relevant Data

Human T-cell lymphotropic virus type 1 (HTLV-1) was the first oncogenic human retrovirus discovered (Poiesz et al. 1980; Poiesz et al. 1981; Yoshida et al. 1982). It has been established as the causal factor in adult T-cell leukemia/lymphoma as its presence is a part of the diagnostic criteria for this cancer (IARC 1996).

This section provides a brief background on HTLV-1 biology and the clinical characteristics of adult T-cell leukemia/lymphoma (Section 4.1), the role of risk modifiers (Section 4.2), adult T-cell leukemia/lymphoma pathogenesis (Section 4.3), a mode-of-action evaluation (Section 4.4), and a synthesis of this information (Section 4.5).

## 4.1 Background

Adult T-cell leukemia/lymphoma is a malignancy defined, in part, by the presence of HTLV-1, and develops only in some HTLV-1-infected people. The retrovirus infects primarily CD4+ T cells, incorporates into the cellular DNA, and becomes a life-long infection (see Section 1. Properties and Detection). The cancer latency period can be 40 to 60 years long and a small percentage (3% to 5%) of carriers will develop adult T-cell leukemia/lymphoma in their lifetime (Mortreux et al. 2003). The virus is endemic to Japan, Central and South America, the Caribbean, and sub-Saharan Africa, and is also found in some parts of the United States (Cesarman and Mesri 2007; Chang et al. 2014; Ciminale et al. 2014).

HTLV-1 infects cells primarily by cell-to-cell contact and is poorly infectious as a free virion (Jacobson and Massoud 2013). The primary mode of transmission of HTLV-1 is from mother to child through breast milk; however, it can also be transmitted by blood or blood products or sexual contact (IARC 1996). The virus has been detected in dendritic cells, monocytes, endothelial cells, and B and T lymphocytes (Yao and Wigdahl 2000).

The HTLV-1 RNA genome integrates into cellular DNA using viral reverse transcriptase and integrase enzymes (Jacobson and Massoud 2013). The provirus is amplified primarily via monoclonal proliferation of infected CD4+ cells using the host DNA polymerase. Thus, copy numbers of the virus in an individual increase through mitosis of infected cells and not through viral reverse transcriptase (IARC 1996). Clonally expanded T cells carry the latent HTLV-1 infection, and adult T-cell leukemia/lymphoma originates from the clonal population of cells (IARC 1996; Moulés et al. 2005). ATLL does not appear to arise from the largest clones but from one of the numerous small clones in carriers suggesting that other oncogenic events are important in its pathogenesis (Cook et al. 2014). Details of adult T-cell leukemia/lymphoma risk modifiers and oncogenesis are presented in Section 4.2.

## 4.2 Risk Modifiers

The mechanism to explain why some HTLV-1 carriers develop adult T-cell leukemia/lymphoma is not completely understood; however, it is known that host immune status affects viral infection and maintenance of a proviral carrier state (Matsuoka and Jeang 2007). In general, there is evidence that perturbations in immune surveillance and factors influencing immune status can affect proviral load (number of cells infected) and factors that allow stimulation of T-cell proliferation that can lead to this aggressive cancer (Mortreux et al. 2003). Therefore, control of T-cell proliferation in asymptomatic carriers would be important for prevention of adult T-cell leukemia/lymphoma (Mortreux et al. 2003).

Another potential risk modifier is Strongyloides stercoralis (threadworm) infection because it can enhance the progression of HTLV-1 infection by increasing the number of lymphocytes infected and shortening the latency period of adult T-cell leukemia/lymphoma development. S. stercoralis infection has been shown to induce a mitogenic T-cell response via activation of the IL-2/IL-2R cytokine system (Gabet et al. 2000; Satoh et al. 2002). The degree of infected T-cell proliferation correlates with the frequency of somatic mutations and accounts for the decreased latency period (Mortreux et al. 2003). A chronic carrier state of S. stercoralis infection can last for decades but can become a hyperinfection due to decreased immunosurveillance with HTLV-1 infection (Marcos et al. 2008; Satoh et al. 2002). In general, patients with co-infections are younger than those without parasite co-infection (Weatherhead and Mejia 2014).

## 4.3 Adult T-cell Leukemia/Lymphoma Pathogenesis

Adult T-cell leukemia/lymphoma develops in two stages. In the first stage, Tax, a viral protein, induces polyclonal proliferation of infected T cells; in the second stage, Tax expression is eliminated or reduced by the host’s cytotoxic T lymphocytes. Tax is highly immunogenic and cells expressing this protein would be more likely to be eliminated by the host immune system. In the absence of Tax expression, continued cell proliferation may continue through HTLV-1 bZip (HBZ) RNA and protein production and through host oncogenic alterations such as with p16^INK4A^ and p53 tumor suppressor genes resulting in clonal selection and lymphomagenesis (Matsuoka and Jeang 2007; Mesri et al. 2014; Satou et al. 2006). Tax is expressed in about 40% of adult T-cell leukemia/lymphoma cases; lack of expression is due to deletions, epigenetic changes in the 5′ long terminal repeat (5′-LTR), and genetic changes in the Tax sequence (Giam and Jeang 2007; Matsuoka 2005). However, HBZ gene expression is conserved in adult T-cell leukemia/lymphoma and correlates with proviral load (Zhao and Matsuoka 2012).

Humanized mouse models are under development to further investigate adult T-cell leukemia pathogenesis from HTLV-1 infection. In the mouse model, “Human Immune System” (HIS) Rag2^-/-^γ_c_^-/-^, HTLV-1 infected human lymphocytes from thymus and spleen expressed CD25 indicating activation, and this activation correlated with the presence of Tax mRNA and increased NF-kB expression (Villaudy et al. 2011). However, there was no evidence of humoral immunity or T-cell mediated cytotoxicity. In another model, HTLV-1-infected IBMI-huNOG mice recapitulated ATLL-like symptoms, including oligoclonal proliferation of HTLV-1-infected T cells and the presence of flower cells, as well as HTLV-1 specific immune responses (Tezuka et al. 2014).

### 4.3.1 Tax Gene and Protein

Tax is a gene unique to HTLV that produces a pleiotropic trans-acting viral protein. It contributes to HTLV-1 oncogenesis by affecting both viral and host functions. Research has shown that Tax affects cell cycle, cell proliferation, DNA repair, and cell survival pathways, and triggers genetic instability (Currer et al. 2012; Matsuoka and Jeang 2007; Mesri et al. 2014; Mortreux et al. 2003). In addition, Tax has been shown to immortalize T cells both in vitro and in vivo in the absence of other viral factors (Grossman et al. 1995; Pozzatti et al. 1990; Tanaka et al. 1990; Yao and Wigdahl 2000), and the malignant transforming ability of Tax has been demonstrated in vitro in the Rat-1 fibroblast cell line in a soft-agar assay and in vivo in nude mice (IARC 2012).

Although Tax promotes cell-cycle progression and plays a role in tumor initiation, it is debated whether Tax alone is sufficient for cell immortalization because, although Tax enables increased expression of IL-2, Tax alone does not enable transition to IL-2 independent growth so it is thought that other factors are involved (Currer et al. 2012).

Some of the key cancer pathways promoted by Tax are listed below.

- Constitutive activation of NF-κB. Tax interacts with the NF-κB family of transcription factors leading to increased expression of IL-2, IL-2 receptor and IL-6 (Currer et al. 2012). NF-κB proteins are involved with T-cell proliferation, growth, and survival and constitutive expression occurs with some viruses and some cancers (Cesarman and Mesri 2007; Yoshida 2001).
- Post-translational modification. Tax both undergoes and promotes post-translational modification of cellular proteins essential for interaction with various host cell proteins, such as NF-κB, and for translocation to different compartments within the cell (Currer et al. 2012).
- Cell-cycle promotion and cell survival. Tax disrupts cell-cycle checkpoints through interactions with cell-cycle proteins, promoting cell proliferation and prevention of apoptosis (Currer et al. 2012).
- Promotion of genetic instability. Tax also localizes at the centrosome during the mitosis phase of the cell cycle, suggesting that Tax has a role in promoting aneuploidy (Currer et al. 2012; Zane and Jeang 2014).
- Promotion of DNA damage and inhibition of DNA repair. Tax has been shown to produce reactive oxygen species within human cells, which can directly result in DNA damage (Kinjo et al. 2010). In addition, Tax has been shown to interfere with multiple DNA repair mechanisms: excision repair, mismatch repair, non-homologous end joining, and DNA damage response signaling leading to genomic instability (Currer et al. 2012).

Further, Tax interactions may play a role in cellular transformation; of particular interest is the role of miRNAs in cellular transformation. Although HTLV-1 does not produce viral miRNAs, Tax has been shown to modulate host miRNAs (Moles and Nicot 2015). Tax can regulate the effects of host miRNA promoting cell proliferation, survival, and immune evasion (Mesri et al. 2014). Tax down-regulates miRNAs that target p300 mRNA increasing viral transcription and also has been found to modulate other host miRNAs thus controlling host mRNA transcription (see Table 4-1) (Rahman et al. 2012; Sampey et al. 2012).

Table 4-1 Regulation of Host miRNA by HTLV-1 Infected Cells

Host miRNA | Direction of Regulation | mRNA Affected | Resultant Biological Effect
miR-21 | Up | PTEN | Anti-apoptotic
miR-93 | Up | P21 MICB | Anti-apoptotic, immune evasion
miR-132, miR-149, miR-873 | Down | P300 AChE | Increase viral transcription Pro-inflammatory
miR-143-p3 | Up | PKA GRα | Proliferation Proliferation
miR-155 | Up | TP53INP1 Unknown | Anti-apoptotic Increase IFN-γ
miR-146a | Up | Unknown | Proliferation

Source: Sampey et al. (2012).

AChE = acetyl cholinesterase; GRα = glucocorticoid receptor alpha; MICB = major histocompatibility complex chain I chain-related B; PKA = protein kinase A; PTEN = phosphatase and tensin homolog; TP53INP1 = tumor protein P53 inducible nuclear protein 1.

### 4.3.2 HTLV-1 bZip Protein (HBZ)

HBZ gene is on the complementary DNA strand to Tax. HBZ promotes T-cell proliferation in its mRNA form and suppresses Tax-mediated viral transcription in its protein form (Zhao and Matsuoka 2012). HBZ is expressed, in addition to Tax, by HTLV-1 in infected cells and is essential for continuous expansion and immortalization of adult T-cell leukemia/lymphoma cells (IARC 2012). Unlike Tax, HBZ is not immunogenic and expression continues with Tax down-regulation allowing for survival of Tax-negative cells (IARC 2012).

Some of the key cancer pathways affected by HBZ are listed below.

- It sustains proliferative signaling. Knock-down of HBZ in adult T-cell leukemia/lymphoma cells decreases the growth of these cells (Satou et al. 2006).
- It enables replicative immortality and activation of invasion and metastasis. HBZ activates hTERT expression, which is supportive of cell immortalization. hTERT expression is important for activation of telomerase expression leading to cell immortalization and is also related to clinical aggressiveness of leukemias and other malignancies (Borowiak et al. 2013; Matsuoka and Jeang 2007; Mesri et al. 2014).
- It promotes cell proliferation and resists cell death. HBZ RNA promotes transcription of E2F, a cell-cycle promoter, and activates transcription of JUND, JUN and ATF prosurvival genes (Mesri et al. 2014; Satou et al. 2006).
- Several host transcription factors bind HBZ protein, modulating their transcriptional activity. Signaling pathways are related to T-cell differentiation, immune response, and growth (Zhao and Matsuoka 2012).
- It promotes immune evasion. HBZ inhibits CD4 T-cell responses by suppression of the IFN-γ promoter, resulting in impaired host immunity in vivo (Zhao and Matsuoka 2012).

## 4.4 Mode-of-action Evaluation

HTLV-1 oncogenesis results from Tax-mediated dysregulation of host replication and survival pathways (Mesri et al. 2014). However, the current understanding is that the effect of HTLV-1 Tax expression alone is not sufficient for cell immortalization (Currer et al. 2012), HBZ expression as well as mutations in host genes, are important factors leading to immortalization and malignant transformation of infected cells (Matsuoka and Jeang 2007; Matsuoka and Yasunaga 2013). Table 4-2 depicts key molecular oncogenic pathways of HTLV-1.

Table 4-2 Cancer Hallmarks Associated with HTLV-1 Infection and Adult T-cell Leukemia/Lymphoma

Viral Gene | Pathways | Cancer Hallmark
Tax | NFκB | Proliferation, growth, survival
Tax | CREB | Regulates CPB/p300; transcriptional factor regulation
Tax | PI3K | Promotes cell survival and growth
Tax | DDR | Inhibits DNA damage response and interacts with mitotic spindle
HBZ | c-jun | Promotes cell survival
HBZ | E2F | Promotes cell proliferation
HBZ | Activates htert | Enables replicative immortality

Source: Mesri et al. (2014).

## 4.5 Synthesis

HTLV-1 infection is necessary but not sufficient for cancer development since not everyone infected with this virus develops adult T-cell leukemia/lymphoma. Host, environmental, and viral factors are all determinants. The viral protein Tax induces polyclonal proliferation of infected T-cells, but it is also highly immunogenic. Tax-negative cells survive since HBZ RNA and protein and host mutations support cell survival and can lead to cell immortalization. Alterations in host genes, such as mutations or deletions in tumor suppressor genes p53 and p16, can lead to increased genetic instability and malignant transformation. Although the HTLV-1 genes Tax and HBZ are key in the oncogenic process, host and environmental factors such as immunosuppression or T-cell proliferation in HTLV-1 carriers can increase viral load and push clonal selection to malignancy.