# 3 Human Cancer Studies

Human T-cell lymphotropic virus type 1 (HTLV-1) is a retrovirus whose association with cancer has been explored in numerous studies. The NTP used the IARC monographs on HTLV-1 (IARC 1996; 2012) as a resource for key studies on cancer conducted prior to 2008 together with new studies identified between 2008 and 2015 to evaluate the scientific evidence for specific cancer endpoints for the RoC, independently of IARC’s conclusions.

Only the adult T-cell leukemia/lymphoma endpoint is evaluated in depth. There are few studies on other cancer endpoints, cutaneous T-cell lymphoma, other B- and T-cell lymphomas, and gastric cancer, which are briefly reviewed. HTLV-1 detection methods varied across studies, with exposure detected primarily in tissues through particle agglutination assay, enzyme-linked immunosorbent assay (ELISA), and western blot (see Section 1.2 for more information).

The cancer hazard evaluation of HTLV-1 from human cancer studies is divided into three parts: the first (Section 3.1) summarizes the approach for selecting the literature specific to HTLV-1; the second (Sections 3.2 and 3.3) discusses the cancer hazard evaluation for specific cancer endpoints; and the last (Section 3.4) summarizes the evaluations across endpoints. The literature search strategy is described in Appendix A.

## 3.1 Selection of the Relevant Literature

A systematic literature search of major databases, citations, and other authoritative sources from 2008 to January 2015 was conducted. The literature search strategy is described in Appendix A. For this review of HTLV-1, all case-control and cohort studies (regardless of cancer endpoint) and case-series studies on the relationship between HTLV-1 and adult T-cell leukemia/lymphoma published since 2008 are included.

## 3.2 Cancer Hazard Assessment: Human T-cell Lymphotropic Virus Type 1

This section provides a brief background on adult T-cell leukemia/lymphoma, summarizes the findings for studies for each study design, discusses relevant cofactors and integrates the evidence for the association between adult T-cell leukemia/lymphoma and HTLV-1 across studies. The review consists of case-series and eight cohort studies. HTLV-1 is part of the diagnostic criteria for adult T-cell leukemia/lymphoma. As such, relative risks (odds ratios) cannot be calculated, and no case-control studies have been conducted on risk.

### 3.2.1 Background Information

Adult T-cell leukemia/lymphoma is a rare and aggressive T-cell malignancy most commonly found in HTLV-1 endemic areas such as Japan, the Caribbean, and the Middle East. Prevalence of adult T-cell leukemia/lymphoma varies with geographic location. In Japan, adult T-cell leukemia/lymphoma incidence among HTLV-1 positive carriers has been reported as 92 per 100,000 males, and 44 per 100,000 females (Koga et al. 2010). In endemic areas of Japan, adult T-cell leukemia/lymphoma accounts for over 51% of all non-Hodgkin lymphomas, while the overall prevalence of adult T-cell leukemia/lymphoma in Japan (nationwide) is 7.5% of all lymphomas (Iwanaga et al. 2012). Other endemic areas such as the Caribbean, Central and South America, and the Middle East report low prevalence rates of disease (Iwanaga et al. 2012). Adult T-cell leukemia/lymphoma is rare in non-endemic areas, such as the United States, with an age-adjusted incidence rate of 0.05 for men and 0.03 for women per 100,000 (Iwanaga et al. 2012; Yamamoto and Goodman 2008), although it should be noted that the majority of cases in the United States have occurred in immigrants from endemic areas (Gonçalves et al. 2010). Adult T-cell leukemia/lymphoma prognosis is poor, with a median survival time of less than 12 months (Matutes 2007).

Based on clinicopathological features, adult T-cell leukemia/lymphoma has been classified into four major subtypes: acute type (most prevalent and prototype of adult T-cell leukemia/lymphoma), lymphoma type, chronic type, and smoldering type (a slow-growing type of adult T-cell leukemia/lymphoma) (IARC 1996).

### 3.2.2 Studies of HTLV-1 and Adult T-cell Leukemia/Lymphoma

The endemic nature of adult T-cell leukemia/lymphoma was first recognized in 1977, when the first case reports were published (Uchiyama et al. 1977). A viral etiology for this disease was proposed (Takatsuki et al. 1977), and HTLV-1 was identified within a few years (Poiesz et al. 1980). Initial case reports and case series of adult T-cell leukemia/lymphoma, conducted in HTLV-1-endemic regions, found a very high prevalence of HTLV-1 among cases (>90%), compared with the general population from which the cases came (see Table 5 in the IARC review (1996) of HTLV-1 for prevalence of anti-HTLV-1 individuals in adult T-cell leukemia/lymphoma (greater than 250 cases) and other lymphoma cases and controls from endemic regions). Because of this strong association seen among adult T-cell leukemia/lymphoma cases, HTLV-1 was considered the cause of adult T-cell leukemia/lymphoma. HTLV-1 infection is now considered a necessary, but not sufficient, cause of adult T-cell leukemia/lymphoma, and is part of the diagnostic criteria (IARC 1996). IARC (2012) also reviewed eight case-series studies published between 1996 and 2005 reporting on over 300 cases of HTLV-associated adult T-cell leukemia/lymphoma in South America, Japan, and other Asian countries (see Table 2.1 (https://monographs.iarc.fr/ENG/Monographs/vol100B/100B-07-Table2.1.pdf) in IARC (2012)). Proviral HTLV-1 DNA is integrated in a monoclonal fashion in all cases of adult T-cell leukemia/lymphoma (Yoshida et al. 1984). Clonality provides evidence that infection precedes tumor development. This correlation between adult T-cell leukemia/lymphoma and HTLV-1 complicates the epidemiological assessment of the association, as studies that traditionally produce measures of association (such as case-control studies and cohort studies) are limited.

The estimated lifetime risk of an HTLV-1 carrier developing adult T-cell leukemia/lymphoma is about one per thousand person years, or 2% to 4% over a lifetime post-infection (Matutes 2007; Murphy et al. 1989). Adult T-cell leukemia/lymphoma occurs most frequently in adults, 20 to 40 years after initial HTLV-1 infection, though average age at onset differs by region, with an average age of 40 in Central and South America, and an average age of 60 in Japan (Iwanaga et al. 2012). High proviral load is an independent risk factor for development of adult T-cell leukemia/lymphoma (Akbarin et al. 2013; Iwanaga et al. 2012).

HTLV-1 positivity is part of the diagnostic criteria for adult T-cell leukemia/lymphoma and, as such, studies of risk compared to non-exposed individuals have not been conducted. All cases in the included studies below are HTLV-1 positive, and no negative controls are available. Eight cohort studies have been conducted on predictors of disease, risk of disease among HTLV-1 carriers, and mortality rate. Six of these cohort studies have been in Japan, where HTLV-1 is endemic, while two newer studies have been conducted in the United States (Biswas et al. 2010) and in Israel (Stienlauf et al. 2013). Adult T-cell leukemia/lymphoma mortality rates (per 100,000) among HTLV-1 carriers ranged from 35.8 to 190.5 while adult T-cell leukemia/lymphoma incidence rates (per 100,000) ranged from 57.4 to 137.7 (Table 3-1). In Japan, there is evidence of greater adult T-cell leukemia/lymphoma incidence, and mortality, among men than women; six of the eight studies reported incidence and/or mortality rates to be higher for men than women (Arisawa et al. 2000; Arisawa et al. 2003; Arisawa et al. 2006; Hisada et al. 2001; Stienlauf et al. 2013; Tokudome et al. 1991). Modeling data from Jamaica have not identified higher disease penetrance in HTLV-1-infected men compared to women (Murphy et al. 1991).

Table 3-1 Summary of Studies of HTLV-1 and Adult T-cell Leukemia/Lymphoma

Study | Country/ Population Enrollment Period | Population Size (HTLV+) Age Follow-up | | Exposure Group (# Cases/Deaths) | Findings (95% CI) | Covariates | Comments
Cohort HTLV-1 carriers^a^
Tokudome et al. (1991) | Japan 1984–1987 | | 3,991 Men: 1,797 Women: 2,194 Age ≥40 Follow-up 1984–1989 | Death from ATLL Men: 3 Women: 2 | Crude mortality rate/100,000: 68.1 (12.8–201.7) 35.8 (3.4–131.5) | – | Higher risk of HTLV among men
Iwata et al. (1994) | Japan 1984–1990 | | 503 Age ≥30 Follow-up 1992–1997 | Death from ATLL 2 | Crude mortality rate/100,000: 77 | – | Higher risk of HTLV among men
Arisawa et al. (2000) | Japan 1985–1996 | | [2,973] Men: [1,242] Women: [1,731] Age 35–82 Follow-up 1985–1995 | Incidence cases of ATLL Men: 24 Women: 16 Men Women | Cases/100,000 PY: 137.7 (88.3–204.9) 57.4 (32.8–93.2) Total lifetime risk (30–79 years): 6.6 (3.8–9.2) 2.1 (1.0–3.1) | Age adjusted | Higher risk of HTLV among men
Hisada et al. (2001) | Japan 1984–1997 | | 550 Age 64–83 Follow-up 1984–1997 | Death from ATLL Men: 4 Women: 2 Men Women | Crude mortality rate/100,000 PY 190.5 (51.9–487.7) 51.7 (6.3–186.8) Adjusted mortality rate/100,000 PY 209.1 (57.0–535.2) 60.9 (7.4–219.9) | Adjusted rate based on PY of observation attributable to perinatal transmission | Higher risk of HTLV-1 among men
Arisawa et al. (2003) | Japan 1985–1992 | | Men: 1,852 Women: 2,284 Age 40–69 Follow-up 1993–2000 | Deaths from ATLL Total: 10 Men: 8 Women: 2 | Crude mortality rate/100,000 125 (60–230)^c^ | – | Higher risk of HTLV-1 among men
Arisawa et al. (2006) | Japan 1985–1987 | | Men: 1,078 Women: 1,655 Age 39–92 Follow-up 1985–2001 | Incident case of ATLL Total: 2 Men: 1 Women: 1 | Crude incidence rate/100,000 PY 71 (9–255)^c^ | – | Higher risk of HTLV-1 among men
Biswas et al. (2010) | USA 1990–1992 | | 155 Ages ≥8 Follow-up 1992–2009 | Deaths from ATLL 1 | NA | – | –
Stienlauf et al. (2013) | Israel 1995–2009 | | 90 Average age: 50.2 Average follow up 9.2 ± 6 years | Incidence of ATLL Total: 3 Men: 2 Women: 1 | Crude incidence rate/100 HTLV-1 carrier-years: 0.37 (0.13–1.08) | – | –
Nested case-control studies in HTLV-1 cohorts^b^
Hisada et al. (1998a) 1988–1991 | Japan Miyazaki cohort study | | Cases 215/controls 215 | Ably+ High proviral load (N = 64) Male gender (N = 81) Ably++ High proviral load (N = 18) Male gender (N = 30) Males: Ably+ (N = 25) Ably++ (N = 9) Females: Ably+ (N = 27) Ably++ (N = 9) | OR (95% CI) 8.9 (4.1–19.5) 1.5 (0.73–3.1) 19.7 (6.9–56.1) 2.8 (1.0–7.8) High proviral load 15.5 (0.33–6.6) 30.2 (4.4–209.5) 5.5 (2.0–15.2) 18.1 (4.1–80.6) | High proviral load adjusted for age, gender, leukocyte categories. Male gender adjusted for age, proviral load, leukocyte category Gender Ably ORs adjusted for age, leukocyte categories | Pre-diagnosis predictors of ATLL
Hisada et al. (1998b) | Japan MCS cohort | | 5 cases/38 matched controls | Anti-HTLV-1/level Anti-Tax/unit | OR (95% CI) 1.6 (0.94–3.8) 0.78 | Matched on age, gender, study screens. Also adjusted for other viral markers, smoking, leukocyte count | Pre-diagnosis predictors of ATLL
Arisawa et al. (2002) | Japan | | 29 cases/158 matched controls | sIL-2R ≥500 U/mL vs. <500 (N = 18) anti-HTLV-1 titer ≥1,024 vs. <1,024 (N = 17) anti-Tax (N = 18) | OR (95% CI) 20.5 (4.5–194) 2.9 (0.98–9.5) 0.59 (0.15–2.0) | Matched for gender, birth year, date of first blood draw | Pre-diagnosis predictors of ATLL
Okayama et al. (2004) | Japan MCS cohort | | 4 cases/37 matched controls | Proviral load/per 1,000 copies | OR (95% CI) 1.42 (1.04–2.10) | Matched for age and gender | Pre-diagnosis predictors of ATLL

Studies prior to 2009 were reviewed by IARC (2012), and results shown are adapted here from IARC Table 2.2 (https://monographs.iarc.fr/ENG/Monographs/vol100B/100B-07-Table2.2.pdf) and Table 2.4 (https://monographs.iarc.fr/ENG/Monographs/vol100B/100B-07-Table2.4.pdf).

Ably = flower cell-like abnormal lymphocytes; ATLL = adult T-cell leukemia/lymphoma; CI = confidence interval; HAM/TSP = HTLV-1 associated myelopathy/tropical spastic paraparesis; NA = not available; OR = odds ratio; PY = person years; sIL-2R = soluble interleukin-2 receptor-α; [ ] = population calculated from proportions of seropositivity.

^a^ Some HIV carriers identified from screening.

^b^ Viral and serum immune markers.

^c^ Reported in the article as rate per 1,000.

Four nested case-control analyses, nested within prospective HTLV-1 cohorts, have investigated both viral and serological predictors of adult T-cell leukemia/lymphoma on a small number of incident cases (Arisawa et al. 2002; Hisada et al. 1998a; Hisada et al. 1998b; Okayama et al. 2004). These studies found that higher proviral load, higher antibody titers, and a higher prevalence of soluble interleukin-2 receptor-α were more likely to lead to an adult T-cell leukemia/lymphoma diagnosis (Table 3-1). For more details, see Table 2.4 (https://monographs.iarc.fr/ENG/Monographs/vol100B/100B-07-Table2.4.pdf) in IARC (2012).

### 3.2.3 Host Susceptibility and Cofactors

Several host susceptibility characteristics have been suggested as potential risk factors for adult T-cell leukemia/lymphoma among HTLV-1 carriers. As discussed above (Table 3-1), male carriers of HTLV-1 appear to be at increased risk for development of adult T-cell leukemia/lymphoma compared with female carriers at least in Japan. Additionally, the risk of developing adult T-cell leukemia/lymphoma is suspected to be associated with early and/or mother-to-child HTLV-1 infection, which may play a role in the development of adult T-cell leukemia/lymphoma. One study in the Caribbean found that almost all mothers of adult T-cell leukemia/lymphoma cases were HTLV-1 positive; all the patients were breastfed (Bartholomew et al. 1998). Two studies have suggested that there may be differences in the viral and immune markers between Jamaican and Japanese HTLV-1-carriers and non-carriers, which could in part help explain differences in adult T-cell leukemia/lymphoma incidence seen between the two populations (reviewed by IARC 2012).

There is evidence in the literature that co-infection with the parasitic roundworm Strongyloides stercoralis (threadworm) is an effect modifier of HTLV-1 and adult T-cell leukemia/lymphoma. Plumelle et al. (1997) reported adult T-cell leukemia/lymphoma patients who were also positive for S. stercoralis were younger at diagnosis than those infected with HTLV-1 alone. Two additional studies (Gabet et al. 2000; Satoh et al. 2002) found that HTLV-1 carriers who were co-infected with S. stercoralis had substantially higher HTLV-1 proviral loads, compared with those infected with HTLV-1 only. This evidence suggests S. stercoralis may increase risk of adult T-cell leukemia/lymphoma in HTLV-1 carriers. (For more details, see Table 2.11 (https://monographs.iarc.fr/ENG/Monographs/vol100B/100B-07-Table2.11.pdf) in IARC (2012)).

### 3.2.4 Integration of the Evidence across Studies

Because of the high prevalence of HTLV-1 infection and monoclonal integration of the virus in almost all adult T-cell leukemia/lymphoma cases, monoclonal integration is now part of the diagnostic definition of the disease (IARC 1996; 2012). In addition, proviral HTLV-1 DNA is integrated in a monoclonal fashion in all cases of adult T-cell leukemia/lymphoma. Among HTLV-1 carriers, cohort studies are suggestive of an increased risk of disease and mortality in males compared with females. Four nested case-control studies among HTLV-1 carriers found high proviral loads, higher antibody titers, and higher prevalence of soluble interleukin-2 receptor-α to be strong pre-diagnosis predictors of adult T-cell leukemia/lymphoma. Co-infection with S. stercoralis may increase the risk of adult T-cell leukemia/lymphoma in HTLV-1 carriers.

## 3.3 Cancer Hazard Evaluation

### 3.3.1 Other Lymphomas/Leukemias

The IARC (2012) review of studies for these cancer endpoints and HTLV-1 is available in the supplemental Tables 2.6 (https://monographs.iarc.fr/ENG/Monographs/vol100B/100B-07-Table2.6.pdf), 2.7 (https://monographs.iarc.fr/ENG/Monographs/vol100B/100B-07-Table2.7.pdf), and 2.8 (https://monographs.iarc.fr/ENG/Monographs/vol100B/100B-07-Table2.8.pdf) of IARC (2012), along with Table 5 (https://monographs.iarc.fr/ENG/Monographs/vol67/index.php) in the IARC (1996) review.

Early evidence presented by one study (Pancake et al. 1996) was suggestive of an association between cutaneous T-cell lymphoma and HTLV-1 based on the presence of HTLV-1 proteins or antibodies to proteins in 60 cutaneous T-cell lymphoma patients. However, 6 case-series studies, reviewed by IARC (2012), from multiple locations throughout the world, could not replicate the results of this study. These studies, which included 2 to 127 patients, did not detect HTLV-1 DNA (integrated) in tumor tissue or antibody in serum from patients with cutaneous T-cell lymphoma (IARC (2012), Table 2.6 (https://monographs.iarc.fr/ENG/Monographs/vol100B/100B-07-Table2.6.pdf)). No new studies on this association have been published since the last review.

Several case series have examined HTLV-1 infection in cases of B- and T-cell lymphomas; however, there was very little evidence of HTLV-1 involvement in these lymphomas in the published case series reviewed by IARC (2012). Thomas et al. (2010) studied 53 patients with large granular lymphocytic leukemia (a T-cell leukemia) and 10,000 healthy volunteer blood donors as non-matched controls. No large granular lymphocytic leukemia cases, and only one control, were positive for HTLV-1 (IARC (2012), Table 2.7 (https://monographs.iarc.fr/ENG/Monographs/vol100B/100B-07-Table2.7.pdf)). One study (Marin et al. 2002) found some evidence of T-cell lymphoma cases among HTLV-1 carriers; however, the authors stated that these might have been cases of adult T-cell leukemia/lymphoma. Gastric lymphomas of T-cell origin were also investigated as having HTLV-1 involvement. Some cases of HTLV-1-positive gastric lymphoma cases were reported; however, results were generally negative, and adult T-cell leukemia/lymphoma presenting as gastric lymphoma could not be ruled out (IARC (2012), Table 2.8 (https://monographs.iarc.fr/ENG/Monographs/vol100B/100B-07-Table2.8.pdf)) (Sakata et al. 2001; Shimada-Hiratsuka et al. 1997). Findings for other types of lymphomas/leukemias were limited to one or two studies per cancer endpoint (IARC 1996; 2012).

### 3.3.2 Solid Tumors

A small number of epidemiologic studies have investigated the association between HTLV-1 and other cancer endpoints; however, the association was not strong because most studies had few cases. Four studies, three cohort and one case-control study, have investigated the association of HTLV-1 and gastric cancer; two of which (Arisawa et al. 2003; Matsumoto et al. 2008) were reviewed by IARC (2012). These studies all found a decreased risk for gastric cancer among those who were HTLV-1 positive. Three cohort studies in Japan found the relative risks of gastric cancer among individuals who were HTLV-1 positive to be 0.42 (95% CI = 0.17 to 0.99; 1 exposed case) (Arisawa et al. 2003), 0.62 (non-significant; 95% CI and exposed cases not reported) (Arisawa et al. 2006), and an odds ratio (OR) = 0.38 (95% CI = 0.21 to 0.70; 14 exposed cases) (Matsumoto et al. 2008). The latter study found that Helicobacter pylori positivity was lower (p = 0.07) in the HTLV-1-positive group (61.7%) compared with the negative group (71.6%) suggesting that HTLV-1 might reduce the risk of H. pylori infection. In a recent case-control study of 201 gastric cancer patients in Iran, Tahaei et al. (2011) found the OR for gastric cancer among HTLV-1 positive was 0.27 (95% CI = 0.03 to 2.43) based on one exposed case.

Several studies, including four case-control studies (Okayama et al. (1995), reviewed by IARC (1996), Asou et al. (1986); Iida et al. (1988); Kamihira et al. (1994)) and two prospective cohort studies (Arisawa et al. 2003; 2006) have reported positive associations with liver cancer although the interpretation is complicated by limitations of the studies (see Table 3-2). All of the studies were conducted in Japan where there are major risks factor for liver cancer of hepatitis B (HBV) and C (HCV) viruses and thus it is unclear whether HTLV-1 could be a possible co-factor or is a confounder. One study of HCV-infected cases and controls suggested that HTLV-1 increases the risk of HCV-associated liver cancer in men (Kamihira et al. 1994). In case-control studies, it is unclear whether HTLV-1 is a possible risk factor for liver cancer or if the development of the malignancy contributes to expression of HTLV-1 latent infection. In addition patients with liver cancer are likely to receive blood transfusions that may result in both HTLV-1 and hepatitis infections (Asou et al. 1986). In the cohort studies, the risk of liver cancer grew with increasing HTLV-1 antibody in the cohort study of Japanese atomic bomb survivors (Arisawa et al. 2006), which had an adequate follow-up (15 to 16 years). Relative risk was not statistically significant in the second cohort study; however, the follow-up was short (6 to 7 years) (Arisawa et al. 2003).

Table 3-2 Summary of Studies of HTLV-1 and Liver Cancer

Study Country | Population | HTLV-1 Positivity | OR or RR (95% CI); Exposed Cases | Comments
Case-control studies
Asou et al. (1986) Japan | 33 cases 22,726 controls (health survey) | NR^a^ 2.98% | SIR (observed/ expected^b^) 2.6 (5/1.94) | Excluded cases with history of blood transfusion; higher risk of all malignancy
Iida et al. (1988) Japan | 40 cases 62,000 local blood donors | 17.5% 4.7% p < 0.001 | NR | 6/7 cases had history of transfusion
Kamihira et al. (1994) Japan | 181 cases 77,540 local blood donors | 20.4% 3.8% | NR | Significant association between HTLV-1 and HCV infection in controls
Okayama et al. (1995) Japan | 43 HCV-positive cases (33 men and 10 women) HCV-positive chronic hepatitis | 30.2% 9.5% | Men 12.8 (3.3–52.3); 11 Women 1.3 (0.7–10.1); 2 | Adjusted for age History of transfusion similar between cases and controls
Prospective cohort studies
Arisawa et al. (2003) Japan | 4,136 Hospital outpatient or check up without cancer 1985–1992 | Men 22.9% Women 26.2% | Mortality 1.2 (0.64–2.4); 14 Incidence 1.4 (0.79–2.7); 17 | Adjusted for sex, age, smoking and drinking habits, history of blood transfusion, and motive for examination Short follow up (mean 7.6 years)
Arisawa et al. (2006) Japan | 2,728 Atomic bomb survivors 1985–1987 | Men 8.2% Women 8.5% | Incidence 2.1 (1.0–4.6); 8 | Adjusted for sex, age, smoking and drinking habits Average follow up 15.4 years

HCV = hepatitis C virus; NR = not reported; OR = odds ratio; RR = risk ratio; SIR = standardized incidence ratio.

^a^ HTLV-1 positivity for all cancers with blood transfusion = 26% and without blood transfusion = 15%.

^b^ Expected numbers of cases based on age and sex distribution in the healthy individuals.

Findings for other types of solid tumors were limited to one or two studies per cancer endpoint (IARC 1996; 2012).

## 3.4 Synthesis across Cancer Endpoints

A summary of the evidence for HTLV-1 infection and the different cancer endpoints from epidemiological studies is provided in Table 3-3. The level of evidence from cancer studies in human also considers studies of tissues from humans in addition to epidemiological studies and is provided in Section 5.

Table 3-3 Summary of HTLV Cancer Endpoints and Strength of the Epidemiological Evidence

Cancer Endpoint | Strength of Evidence
Adult T-cell leukemia/lymphoma | • Infection with HTLV-1 is part of the diagnostic criteria of ATLL. • Consistent evidence across multiple studies. • Prospective studies and clonality indicate that infection precedes diagnosis.
Cutaneous T-cell lymphoma | • Inconsistent evidence in multiple case series. • No epidemiologic studies available.
Gastric cancer | • Although several studies reported a decreased risk of gastric cancer most studies had few cases.
Liver cancer | • Although several studies found an increased risk of liver cancer among HTLV-1-infected individuals, the body of literature is limited by small number of studies or exposed subjects and potential confounding from infection with hepatitis B or C viruses.

ATLL = Adult T-cell leukemia/lymphoma.