# 2 Human Exposure

## 2.1 Prevalence and Transmission

Most available human T-cell lymphotropic virus type 1 (HTLV-1) prevalence studies in the United States have focused on blood donor or injection drug user (IDU) populations (Gessain and Cassar 2012). The first detailed U.S. study conducted in more than a decade reported a seroprevalence of 0.0051% (reported as 5.1 cases per 100,000) in 2,047,740 first-time blood donors in a network of blood centers located in the western, southern, and northern United States examined over the time period of 2000 to 2009 (Chang et al. 2014; Cook and Taylor 2014). Previous studies reported U.S. HTLV-1 seroprevalences ranging from 0.009% to 0.025% measured in approximately 40,000 blood donors in 8 cities in geographically distinct areas and reporting that HTLV-1 was found primarily in the southeastern and southwestern United States; in 1.7 million donors at 5 U.S. blood centers during 1991 to 1995; and in approximately 21,000 individuals representing blood donors, various patient populations, and retroviral risk groups (Murphy et al. 1999; Poiesz et al. 2001; Williams et al. 1988). The number of HTLV-1-infected persons in the United States has been estimated to range from 90,000 to 100,000 persons (Gessain and Cassar 2012). No analyses of HTLV-1 prevalence in blood, serum, or urine specimens from the National Health and Nutrition Examination Survey (NHANES) have been identified.

Worldwide prevalence of HTLV-1 has been variously reported as 10 million to 20 million infected persons (de Thé and Bomford 1993) or 5 million to 10 million (Gessain and Cassar 2012). However, these numbers should be considered as estimates of minimum numbers because both studies examined certain endemic regions (southwestern Japan, sub-Saharan Africa, the Caribbean islands, and parts of South America) but not all populations. For example, Gessain and Cassar (2012) based their estimates on areas with a total of 1.5 billion people that did not include China, India, or other highly populated regions in the approximately 7 billion total world population in 2012 (PRB 2012). Prevalence varies geographically, and HTLV-1 can be found in high-endemicity clusters near regions where it may be nearly absent (Gessain and Cassar 2012; IARC 2012). Generally, highly endemic areas include southwestern Japan, parts of sub-Saharan Africa, the Caribbean Islands, and South America (IARC 2012). Seroprevalence increases with age and especially in women in these areas (Gessain and Cassar 2012). Infections have also been reported in Melanesia, Papua New Guinea, and the Solomon Islands, and among Australian aborigines (IARC 2012; Kannian and Green 2010). Prevalence is low in Europe and North America where HTLV-1 is found mainly in immigrants from endemic countries (IARC 2012).

The 3 main transmission modes for HTLV-1 are vertical, sexual, and parenteral, all of which require cell-to-cell contact (IARC 2012). The routes of transmission include the transfer of infected cells from one person to another through blood transfusions, breast-feeding, and sexual intercourse (Carpentier et al. 2015; Cook et al. 2013; Schäfer et al. 2015). Blood transfusion is a direct route of infection. Breast-feeding and sexual intercourse, however, require the HTLV-1 infected cells to cross a mucosal epithelium. Mucosal epithelium can be traversed in several different ways (Carpentier et al. 2015). Infected macrophages might transmigrate through an intact epithelium, infected cells might cross through breaks in the epithelium, epithelial cells might become infected and transfer the virus to uninfected cells that come in contact with their basal end, or virions could cross the epithelial cells by transcytosis. Transcytosis occurs when virus from infected T cells is endocytosed by the epithelial cells on the apical end and then is passed to the basal end inside a vesicle, never coming in contact with the cytoplasm.

The highest rates of HTLV-1 transmission are from vertical transmission via breastfeeding and are as high as 30% in southern Japan. Risk of HTLV-1 infection in children from vertical transmission corresponds to the mother’s breast milk proviral load and to breastfeeding duration. Vertical transmission occurs rarely in utero (e.g., during the intrauterine period or peripartum) in <5% of cases (Ichimaru et al. 1991). Risk factors for sexual transmission include unprotected sex with an infected partner, multiple lifetime sexual partners, and infection with sexually transmitted diseases (STDs) (IARC 2012). Findings from one study of couples in Japan with one seropositive and one seronegative partner showed a higher male-to-female transmission rate; however, another study in a different geographic location (Latin America) did not, possibly due in part to differences in sexual practices between genders and seroprevalence of sexually transmitted diseases among populations. HTLV-1 transmission via the transfusion of cellular blood products is very efficient, with transmission of at least 40% (Manns et al. 1992), and blood donors have been screened for HTLV-1 antibody in the United States since 1988. HTLV infection is also transmitted via injection drug use, although HTLV-2 is more common than HTLV-1 in this risk group (Khabbaz et al. 1992). Organ-transplantation-acquired infection has been reported in Germany (Glowacka et al. 2013) and the United States (Ramanan et al. 2014).

## 2.2 Diseases (Non-cancer), Prevention, and Treatment

Most HTLV-1-infected individuals are lifelong asymptomatic carriers (Cook et al. 2013), and only 2% to 5% of infected people develop diseases related to the virus (Hlela and Bittencourt 2014). HTLV-1 associated myelopathy/tropical spastic paraparesis (HAM/TSP), an inflammatory central nervous system disease, is the most common clinical manifestation of HTLV-1 (Fuzii et al. 2014). Other diseases associated with HTLV-1 include HTLV-1 uveitis, an inflammatory disorder affecting intraocular tissues (Kamoi and Mochizuki 2012), and infective dermatitis associated with HTLV-1, a chronic and recurrent eczema that occurs during childhood and rarely in adolescence or adulthood (Hlela and Bittencourt 2014).

Prenatal screening for HTLV-1 and counseling of seropositive mothers to avoid breastfeeding reduces mother-to-child transmission; in Japan, avoidance of breastfeeding by HTLV-1-infected mothers reduced transmission from 20% to 3%, and efforts to eliminate breastfeeding or reduce breastfeeding duration to less than 12 months also reduced transmission (Hino 2011; IARC 2012). Following the practices that prevent sexually transmitted infections, e.g., use of condoms and avoiding multiple and anonymous sexual partners, can reduce sexual transmission (Yoshimitsu et al. 2013). In addition, counseling and education of injection drug users (e.g., implementation of harm reduction practices) may be effective in reducing HTLV-1 infection among this population (Gonçalves et al. 2010). Blood screening has reduced the risk of transfusion-related transmission (McKendall 2014); screening the U.S. blood supply for HTLV-1 began in 1988 (ARC 2015).

Prevention involves four major areas for actions to reduce transmission of HTLV-1: blood transfusion, sexual transmission, breastfeeding, and vaccine development (McKendall 2014). There is currently no vaccine against HTLV-1 (ACS 2015; CDC 2015; FDA 2015); however, vaccine development efforts are ongoing (Kuo et al. 2011).

## 2.3 Summary

The number of human T-cell lymphotropic virus type 1 (HTLV-1)-infected persons in the United States has been estimated to range from 90,000 to 100,000 persons, indicating that a significant number of people living in the United States are exposed to (HTLV-1). Worldwide prevalence of HTLV-1 is highest in endemic areas including southwestern Japan, parts of sub-Saharan Africa, the Caribbean Islands, and South America; numbers of infected persons range from 5 million to 20 million people, although the estimates generally did not include all countries. The 3 main transmission modes for HTLV-1 are vertical, sexual, and parenteral, all of which require cell-to-cell contact. The highest rates for vertical transmission involve breastfeeding, although transmission in utero from mother to fetus has also been reported as a possibility. Most HTLV-1 infected individuals are lifelong asymptomatic carriers and only 2% to 5% of infected people develop diseases, such as HTLV-1 associated myelopathy/tropical spastic paraparesis, related to the virus. Prevention of HTLV-1 transmission is based on blocking the known routes of transmission, including blood transfusion, sexual transmission, and breastfeeding. Although there is currently no vaccine against HTLV-1, vaccine development efforts are ongoing.