# 1 Properties and Detection

This section reviews the biology, detection, transmission, prevention, and treatment of the human T-cell lymphotropic virus type 1 (HTLV-1). The specific topics covered include the properties (Section 1.1) and detection (Section 1.2).

## 1.1 Properties

The following section reviews the types of HTLV, its structure, life cycle, and course of infection.

### 1.1.1 Family and Type

Human T-cell lymphotropic virus type 1 (HTLV-1) is a delta-type retrovirus, in the subfamily Orthoretrovirinae, which has four types: HTLV-1, HTLV-2, HTLV-3, and HTLV-4 (Gessain and Cassar 2012; IARC 2012). HTLV-1 was the first oncoretrovirus to be discovered in humans and was isolated in 1979 from peripheral blood lymphocytes in a patient thought to have T-cell lymphoma (Poiesz et al. 1980). HTLV-1 is very similar to bovine leukemia virus and simian T-cell leukemia virus; all three viruses have an extra pX region in their genome containing regulatory and accessory genes (Jacobson and Massoud 2013). HTLV-2 has been associated with myelopathy, pulmonary infections, and elevated lymphocyte and platelet counts but not with neoplasms (IARC 1996; 2012; Murphy et al. 1997a; 1997b). HTLV-3 and HTLV-4 have not been associated with hematological diseases. The genomes of HTLV-1 isolated from humans in different parts of the world vary (IARC 1996; 2012; Jacobson and Massoud 2013). HTLV-1 is divided into four clades, or subtypes, with similar nucleotide sequences in specific viral genes. These include the Cosmopolitan, Japanese, African, and Melanesian clades. Humans are the natural host for HTLV-1, but other mammals (rabbits, rats, mice, and New World monkeys) have been infected experimentally.

### 1.1.2 Virus Structure and Genome

The HTLV-1 virion (80 to 100 nm diameter) consists of a lipid membrane envelope with two surface proteins surrounding a protein matrix, inside which is a protein capsid containing two copies of the viral single-stranded RNA (ssRNA) genome and the enzymes reverse transcriptase, integrase, and protease (see Figure 1-1) (IARC 1996; 2012; Jacobson and Massoud 2013). The HTLV-1 genome is about 9 kb long and contains three major genes that encode multiple structural proteins (env and gag genes), enzymes (pol genes), regulatory proteins (Tax and Rex), and accessory proteins (p12, p13, p30, and HBZ), all of which are flanked by two long terminal repeats (LTRs). The lipid membrane envelope is created by budding off from the host cell membrane, which has been modified by insertion of two viral glycoproteins produced from the env gene. The env gene produces a single protein that is cleaved by a cellular protease into gp21, which has a transmembrane domain anchoring it into the membrane envelope, and gp46, which attaches to gp21 (IARC 2012; Schäfer et al. 2015). The gag gene produces a precursor protein (p53) that is cleaved by the viral protease to give rise to the matrix protein (p19), the viral capsid protein (p24), and the nucleocapsid protein (p15) (IARC 1996; 2012). The pol gene codes for three proteins (reverse transcriptase, integrase, and protease) that are created by frame shifts. Tax and Rex are regulatory proteins found in the pX region, near the 3' end, which produces at least four open reading frames by alternate mRNA splicing and internal initiation codons (IARC 2012; Jacobson and Massoud 2013). Viral gene expression is controlled by promoters and enhancers in the two LTR regions and are regulated by Tax protein. Tax regulates the expression of viral genes and some host genes that promote cell proliferation (see Section 4.3). However, Tax is immunogenic and anti-Tax immune responses lead to a decrease in Tax expression. Even with decreased expression of Tax, cell proliferation continues to be promoted by HBZ, which also can suppress Tax expression. HBZ is less immunogenic than Tax; therefore, HBZ becomes the predominant driver of cell proliferation in later stages of infection. This allows for the clonal expansion of latently infected cells.

Figure 1-1

Human T-cell Lymphotropic Virus Particle

Source: CreativeCommons.org.

### 1.1.3 Infection and Replication

Free HTLV-1 viruses are unstable and not very infectious (Carpentier et al. 2015; IARC 1996; 2012; Jacobson and Massoud 2013; Schäfer et al. 2015). Transmission of infection occurs primarily through cell-to-cell contact between an infected and uninfected cell; cell-free virus transmission has been described but it is much less efficient (Gross and Thoma-Kress 2016). HTLV-1 infects T cells, mainly CD4 T cells, and to a lesser extent CD8 T cells. Infection of other hematopoietic cells (dendritic cells, monocytes, macrophages, B cells) and glial cells and endothelial cells is less efficient, though antigen-presenting cells (dendritic cells and macrophages) may play a major role in facilitating cell-to-cell transmission (Carpentier et al. 2015; IARC 1996; 2012; Jacobson and Massoud 2013; Schäfer et al. 2015). In vitro studies have demonstrated that dendritic cells can be infected without cell-to-cell contact (i.e., cell-free) and a role for this route of infection has been proposed as a possible way that HTLV-1 infection is initially acquired (Gross and Thoma-Kress 2016).

HTLV-1 viruses bind to uninfected cells by the Env protein, gp46 (Cook et al. 2013; IARC 1996; 2012; Jacobson and Massoud 2013; Schäfer et al. 2015), inducing a conformational change in the protein that allows it to bind to cellular glucose transporter 1 and facilitates fusion of the viral and cellular membranes. Cell-to-cell transmission of HTLV-1 viruses occurs through several possible mechanisms (Carpentier et al. 2015; Gross and Thoma-Kress 2016; Jacobson and Massoud 2013; Schäfer et al. 2015) (see Figure 1-2). Cell-to-cell attachments can occur in a way that protects the virions from the surrounding environment, called a virological synapse. Extracellular viral transfer can occur when viral particles attach to the infected cell’s membrane during viral budding, which can then come in contact with uninfected cells. The close contact between virally infected antigen-presenting cells and T cells allows budding viruses to infect T cells. Epithelial or endothelial cells with intercellular conduits, such as gap junctions, can allow the virus to pass to neighboring cells.

Figure 1-2

HTLV Infection and Replication Cycle

Source: Carpentier et al. (2015).

When the viral and cellular membranes fuse, the viral contents empty into the cytoplasm releasing the ssRNA genome, along with reverse transcriptase, integrase, and protease enzymes (Cook et al. 2013; IARC 1996; 2012; Jacobson and Massoud 2013; Schäfer et al. 2015). The ssRNA genome is then replicated by reverse transcriptase to a DNA genome, which integrates into the host cell genome. The virus can either remain latent and replicate clonally during mitosis along with the host cell genome or it can produce more viruses that can infect other cells through cell-to-cell contact. Reverse transcriptase is an error-prone polymerase and introduces random mutations into the viral genome. However, HTLV-1 does not go through as many rounds of replication or produce as many progeny as other retroviruses, such as human immunodeficiency virus (HIV), and has better genetic stability. Instead, the provirus is amplified along with the host genome during cell division (Gessain and Cassar 2012; Kubota et al. 2007). During virion production, viral proteins are produced and ssRNA is expressed and binds to the cell membrane, which contains the Env proteins. The newly-formed virion buds off and sticks to the outside of the host cell or is transferred to uninfected cells. The protease enzyme inside the newly formed virion cleaves multi-gene proteins, causing the virus to mature to its infectious form (see Figure 1-2).

The HTLV-1 virion is immunogenic, so active viral production will elicit a cytotoxic T-cell immune response (Carpentier et al. 2015; Cook et al. 2013). This results in clearing out cells that are producing virus particles, leading to a predominance of infected cells in the latent phase. During the latent phase, Tax protein promotes host cell proliferation, but Tax itself is immunogenic and will elicit a cytotoxic T-cell immune response. In order to maintain a latent infection, Tax expression must be suppressed. It has been found that Tax expression is either mutationally inactivated or epigenetically suppressed by methylation in about half of acute T cell lymphoma cases. The accessory protein HTLV-1 bZIP factor (HBZ) is constitutively expressed and can also promote host cell proliferation. However, HBZ is not as immunogenic as Tax and might not elicit an immune response against the infected cells, allowing for maintenance of clonal expansion in the latent phase.

## 1.2 Detection

HTLV-1 is rarely detected free in bodily fluids, but it is found in peripheral mononuclear blood cells in breast milk, blood, semen, and cerebral spinal fluid (Carpentier et al. 2015; IARC 1996; Schäfer et al. 2015). Detection of HTLV-1 infection consists of tests to detect either a) anti-HTLV-1 antibodies, b) HTLV-1 RNA/DNA, or c) HTLV-1 in culture. Although procedures are prescribed for donor screening and tissue testing to ensure that tissues intended for human transplant are free of HTLV-1, some vascularized human organs for transplantation are excluded from testing.

### 1.2.1 Detection of Anti-HTLV-1 Antibodies or Antigens

HTLV-1 viral antigens are found in fluids at very low levels and are not routinely used for diagnosis (IARC 1996). Detection of anti-HTLV-1 antibodies is used to diagnose an infection. IgG anti-HTLV antibodies are produced continually during most of the HTLV infection, while IgA and IgM are produced temporarily during the beginning of the infection. Anti-HTLV antibody screening tests are usually done initially, with positive specimens then tested using a supplemental test that offers the ability to differentiate HTLV-1 from HTLV-2.

Screening immunoassays for HTLV-1 consist of laboratory-based tests, such as enzyme-linked immunosorbent assays (ELISA), particle agglutination assays, and immunofluorescence assays (IARC 1996). ELISA assays use either purified virions, viral peptides, or recombinant proteins, with specific peptides and recombinant proteins offering higher specificity. Particle agglutination tests use viral antigen-containing gelatin particles, which are cross-linked by anti-HTLV antibodies. Immunofluorescence tests rely on staining of HTLV-producing cell lines.

Supplemental tests include western blot, immunofluorescence, and recombinant immunoblot (RIBA) (IARC 1996; Sabino et al. 1999). Both western blots and ELISA use purified virions. Antibodies are commonly found that are specific for Gag proteins (p19, p24, p53) and Env glycoproteins (gp21 and gp46). The strain of HTLV can be differentiated by adding synthetic viral gp46 peptides that are derived from either HTLV-1 or HTLV-2 to the western blots. A positive test for at least one Gag and one Env protein is needed for confirmation of anti-HTLV-1 antibodies. Immunofluorescence assays also can differentiate HTLV-1 from HTLV-2. PCR is able to clarify indeterminate western blot and ELISA results, can differentiate HTLV-1 from HTLV-2 (Sabino et al. 1999) and is supplanting the western blot in usage.

### 1.2.2 Detection of RNA

Detection of viral RNA or DNA is usually carried out on peripheral mononuclear cells in blood, semen, and breast milk (Carpentier et al. 2015; IARC 1996; Schäfer et al. 2015). Detection of viral RNA requires very sensitive methods (IARC 1996). Reverse transcription-polymerase chain reaction (RT-PCR) is used to detect HTLV-1 specific pol and tax genes, as they have a lower variability among strains. Alternatively, the long terminal repeat or env gene can be amplified by PCR and then subjected to restriction enzyme digestion to differentiate HTLV-1 from HTLV-2. Nested PCR is more sensitive than single-round PCR and is needed to detect low levels of HTLV in some people. The amount of HTLV proviral DNA can be measured using quantitative assays based upon real-time PCR and is usually expressed as HTLV copies per peripheral blood mononuclear cell. This allows for quantitation of the percentage of peripheral blood cells with integrated viral genomes, which usually remain stable over many years (Cook et al. 2013). However, the percentage of cells with the virus varies widely among individuals. This percentage is likely determined primarily by the cytotoxic T cell response against HTLV-1 infected cells.

### 1.2.3 Detection of HTLV-1 by Viral Culture

Long-term culture of peripheral blood mononuclear cells with IL-2 or co-culture with phytohemagglutinin-stimulated cord blood cells can result in virion production (IARC 1996). The cultured virions can then be detected by electron microscopy or immunofluorescence using antibodies against Env glycoprotein (gp46) or Gag proteins (p19 or p24). Gag proteins released into the culture medium can also be detected by antigen capture assay.

## 1.3 Summary

Human T-cell lymphotropic virus type 1 (HTLV-1) is an enveloped RNA retrovirus found in T-cell lymphoma. HTLV-1 contains regulatory and accessory genes that promote proliferation of T cells, predominately CD4 T cells. HTLV-1 is unstable as a free virion and transmission requires cell-to-cell contact in most cases, with antigen-presenting cells thought to play a major role in infecting CD4 T cells. However, cell-free infection of dendritic cells in vitro has been described. Selective pressure from anti-viral immune responses often leads to loss of expression of some regulatory genes in latently infected cells, and the immune response is thought to play a major factor in determining viral load. Cell proliferation is promoted by Tax and HBZ. Tax itself is immunogenic; for a latent infection to be maintained, Tax expression is suppressed, and host cell proliferation is maintained by HBZ, which is less immunogenic than Tax, allowing for clonal expansion of latently infected cells. Detection of HTLV-1 is most commonly carried out by measurement of anti-HTLV-1 antibodies. Other detection methods include measurement of viral RNA or DNA from peripheral mononuclear cells in blood, semen, and breast milk or use of in vitro culture techniques for peripheral blood mononuclear cells or cord blood cells. Specimens with positive results are further tested in a confirmatory laboratory-based Western blot immunoassay, polymerase chain reaction, immunofluorescence assay, or recombinant immunoblot assay.