# Abbreviations

  5′-LTR: 5′ long terminal repeat
  Ably: flower cell-like abnormal lymphocytes
  AchE: acetyl cholinesterase
  ATLL: adult T-cell leukemia/lymphoma
  CDC: Centers for Disease Control and Prevention
  CFR: Code of Federal Regulations
  CI: confidence interval
  DNA: deoxyribonucleic acid
  DOT: Department of Transportation
  dsDNA: double-stranded DNA
  ELISA: enzyme-linked immunosorbent assays
  FDA: Food and Drug Administration
  GRα: glucocorticoid receptor alpha
  HAM/TSP: HTLV-1 associated myelopathy/tropical spastic paraparesis
  HBV: hepatitis B virus
  HCV: hepatitis C virus
  HIV: human immunodeficiency virus
  HBZ: HTLV-1 bZIP factor
  HTLV: human T-cell lymphotropic virus-1
  IARC: International Agency for Research on Cancer
  IDU: injection drug user
  IgA: immunoglobulin A
  IgG: immunoglobulin G
  IgM: immunoglobulin M
  IL-2: interleukin 2
  LTR: long terminal repeat
  MICB: major histocompatibility complex chain I chain-related B
  miRNA: microRNA
  mRNA: messenger RNA
  NA: not available
  NF-κB: nuclear factor kappa B
  NHANES: National Health and Nutrition Examination Survey
  NR: not reported
  NTP: National Toxicology Program
  OR: odds ratio
  OSHA: Occupational Safety and Health Administration
  PCR: polymerase chain reaction
  PKA: protein kinase A
  PTEN: phosphatase and tensin homolog
  PY: person years
  RNA: ribonucleic acid
  RR: relative risk
  RT-PCR: reverse transcriptase-polymerase chain reaction
  ssRNA: single-stranded RNA
  SIR: standardized incidence ratios
  sIL2S: soluble interleukin-2 receptor-α
  STD: sexually transmitted disease
  TP53INP1: tumor protein P53 inducible nuclear protein 1
  USA: United States of America