# Glossary

Capsid: The protein coat surrounding the nucleic acid of a virus.
Case report: Detailed descriptions of a few patients or clinical cases (frequently, just one sick person) with an unusual disease or complication, uncommon combinations of diseases, an unusual or misleading semiology, cause, or outcome (maybe a surprising recovery). They often are preliminary observations that are later refuted. They cannot estimate disease frequency or risk (e.g., for lack of a valid denominator).
Case series: A collection of subjects (usually, patients) with common characteristics used to describe some clinical, pathophysiological, or operational aspect of a disease, treatment, exposure, or diagnostic procedure. A case series does not include a comparison group and is often based on prevalent cases and on a sample of convenience. Common selection biases and confounding severely limit their power to make causal inferences.
Case-comparison study (case-control study, case referent study): The observational epidemiological study of persons with the disease (or another outcome variable) of interest and a suitable control group of persons without the disease (comparison group, reference group). The potential relationship of a suspected risk factor or an attribute to the disease is examined by comparing the diseased and non-diseased subjects with regard to how frequently the factor or attribute is present (or, if quantitative, the levels of the attribute) in each of the groups (diseased and non-diseased).
Codon: A specific sequence of three consecutive nucleotides that is part of the genetic code and that specifies a particular amino acid in a protein or starts or stops protein synthesis.
Diagnostic criteria: The specific combination of signs, symptoms, and test results that a clinician uses to identify a person as representing a case of a particular disease or condition.
Hyperinfection: Infection by large numbers of organisms as a result of immunologic deficiency.
Immunoassay: A laboratory technique that uses the binding between an antigen and its homologous antibody to identify and quantify the specific antigen or antibody in a sample.
Inverse polymerase chain reaction: A variant of polymerase chain reaction used to amplify and clone unknown DNA that flanks one end of a known DNA sequence and for which no primers are available. Inverse PCR is useful in identifying flanking DNA sequences of genomic inserts. Similar to other PCR methods, inverse PCR amplifies target DNA using DNA polymerase.
microRNA: small, non-coding RNA molecules approximately 22 nucleotides in length that act post translationally in a regulatory role to target messenger RNAs for cleavage or translational expression.
Monoclonal: Pertaining to or designating a group of identical cells or organisms derived from a single cell or organism.
Nude mouse (athymic nude mouse): A type of laboratory mouse that is hairless, lacks a normal thymus gland, and has a defective immune system because of a genetic mutation. Athymic nude mice are often used in cancer research because they do not reject tumor cells, from mice or other species.
Open reading frame: A portion of a DNA molecule that, when translated into amino acids, contains no stop codons.
Parenteral: By some other means than through the gastrointestinal tract; the parenteral route of infection involves breaks in the skin such as cuts and scrapes, puncture wounds, bites, and burns.
Polyclonal: Pertaining to or designating a group of cells or organisms derived from several cells.
Polymerase chain reaction: A laboratory technique used to produce large amounts of specific DNA fragments. Polymerase chain reaction is used for genetic testing and to diagnose disease.
Smoldering type adult T-cell leukemia/lymphoma: A slow-growing type of adult T-cell leukemia/lymphoma characterized by less than 5% neoplastic lymphocytes in the peripheral blood, absence of lymphadenopathy and hypercalcemia, and occasional skin or pulmonary lesions.
Titer: A laboratory measurement of the concentration of a substance in a solution (e.g., an antibody titer measures the presence and amount of antibodies in the blood).
Vertical transmission: The transmission of infection from one generation to the next (e.g., from mother to infant prenatally, during delivery, or in the postnatal period via breast milk.