# References

Akbarin MM, Rahimi H, Hassannia T, Shoja Razavi G, Sabet F, Shirdel A. 2013. Comparison of HTLV-I proviral load in adult T cell leukemia/lymphoma (ATL), HTLV-I-associated myelopathy (HAM-TSP) and healthy carriers. Iran J Basic Med Sci. 16(3):208–212. 24470863
American Cancer Society (ACS). 2015. Viruses that can lead to cancer. https://www.cancer.org/cancer/cancercauses/othercarcinogens/infectiousagents/infectiousagentsandcancer/infectious-agents-and-cancer-viruses. [Accessed on 8/26/15]
American Red Cross (ARC). 2015. Blood testing. American Red Cross. https://www.redcrossblood.org/print/learn-about-blood/what-happens-donated-blood/blood-testing.
Arisawa K, Katamine S, Kamihira S, et al. 2002. A nested case-control study of risk factors for adult T-cell leukemia/lymphoma among human T-cell lymphotropic virus type-I carriers in Japan. Cancer Causes Control. 13:657–663. 10.1023/A:1019511224501 12296513
Arisawa K, Sobue T, Yoshimi I, Soda M, Shirahama S, Doi H, Katamine S, Saito H, Urata M. 2003. Human T-lymphotropic virus type-I infection, survival and cancer risk in southwestern Japan: A prospective cohort study. Cancer Causes Control. 14(9):889–896. 10.1023/B:CACO.0000003853.82298.96 14682446
Arisawa K, Soda M, Akahoshi M, Fujiwara S, Uemura H, Hiyoshi M, Takeda H, Kashino W, Suyama A. 2006. Human T-cell lymphotropic virus type-1 infection and risk of cancer: 15.4 year longitudinal study among atomic bomb survivors in Nagasaki, Japan. Cancer Sci. 97(6):535–539. 10.1111/j.1349-7006.2006.00212.x 16734733
Arisawa K, Soda M, Endo S, Kurokawa K, Katamine S, Shimokawa I, Koba T, Takahashi T, Saito H, Doi H, et al. 2000. Evaluation of adult T-cell leukemia/lymphoma incidence and its impact on non-Hodgkin lymphoma incidence in southwestern Japan. Int J Cancer. 85(3):319–324. 10.1002/(SICI)1097-0215(20000201)85:3<319::AID-IJC4>3.0.CO;2-B 10652420
Asou N, Kumagai T, Uekihara S, Ishii M, Sato M, Sakai K, Nishimura H, Yamaguchi K, Takatsuki K. 1986. HTLV-I seroprevalence in patients with malignancy. Cancer. 58(4):903–907. 10.1002/1097-0142(19860815)58:4<903::AID-CNCR2820580417>3.0.CO;2-J 3013397
Bartholomew C, Jack N, Edwards J, Charles W, Corbin D, Cleghorn FR, Blattner WA. 1998. HTLV-I serostatus of mothers of patients with adult T-cell leukemia and HTLV-I-associated myelopathy/tropical spastic paraparesis. J Hum Virol. 1(4):302–305. 10195256
Biswas HH, Kaidarova Z, Garratty G, Gibble JW, Newman BH, Smith JW, Ziman A, Fridey JL, Sacher RA, Murphy EL. 2010. Increased all-cause and cancer mortality in HTLV-II infection. J Acquir Immune Defic Syndr. 54(3):290–296. 10.1097/QAI.0b013e3181cc5481 20512047
Borowiak M, Kuhlmann AS, Girard S, Gazzolo L, Mesnard JM, Jalinot P, Dodon MD. 2013. HTLV-1 bZIP factor impedes the menin tumor suppressor and upregulates JunD-mediated transcription of the hTERT gene. Carcinogenesis. 34(11):2664–2672. 10.1093/carcin/bgt221 23784080
Carpentier A, Barez PY, Hamaidia M, Gazon H, de Brogniez A, Perike S, Gillet N, Willems L. 2015. Modes of human T cell leukemia virus type 1 transmission, replication and persistence. Viruses. 7(7):3603–3624. 10.3390/v7072793 26198240
Centers for Disease Control and Prevention (CDC). 2015. List of vaccines used in United States. https://www.cdc.gov/vaccines/vpd-vac/vaccines-list.htm. [Accessed: August 26, 2015]
Cesarman E, Mesri EA. 2007. Kaposi sarcoma-associated herpesvirus and other viruses in human lymphomagenesis. Curr Top Microbiol Immunol. 312:263–287. 10.1007/978-3-540-34344-8_10 17089801
Chang YB, Kaidarova Z, Hindes D, Bravo M, Kiely N, Kamel H, Dubay D, Hoose B, Murphy EL. 2014. Seroprevalence and demographic determinants of human T-lymphotropic virus type 1 and 2 infections among first-time blood donors—United States, 2000-2009. J Infect Dis. 209(4):523–531. 10.1093/infdis/jit497 24068702
Ciminale V, Rende F, Bertazzoni U, Romanelli MG. 2014. HTLV-1 and HTLV-2: Highly similar viruses with distinct oncogenic properties. Front Microbiol. 5:398. 10.3389/fmicb.2014.00398 25120538
Cook LB, Elemans M, Rowan AG, Asquith B. 2013. HTLV-1: Persistence and pathogenesis. Virology. 435(1):131–140. 10.1016/j.virol.2012.09.028 23217623
Cook LB, Melamed A, Niederer H, Valganon M, Laydon D, Foroni L, Taylor GP, Matsuoka M, Bangham CR. 2014. The role of HTLV-1 clonality, proviral structure, and genomic integration site in adult T-cell leukemia/lymphoma. Blood. 123(25):3925–3931. 10.1182/blood-2014-02-553602 24735963
Cook LB, Taylor GP. 2014. HTLV-1 and HTLV-2 prevalence in the United States. J Infect Dis. 209(4):486–487. 10.1093/infdis/jit558 24154735
Currer R, Van Duyne R, Jaworski E, Guendel I, Sampey G, Das R, Narayanan A, Kashanchi F. 2012. HTLV tax: A fascinating multifunctional co-regulator of viral and cellular pathways. Front Microbiol. 3:406. 10.3389/fmicb.2012.00406 23226145
de Thé G, Bomford R. 1993. An HTLV-I vaccine: Why, how, for whom? AIDS Res Hum Retroviruses. 9(5):381–386. 10.1089/aid.1993.9.381 8318266
Fuzii HT, da Silva Dias GA, de Barros RJ, Falcao LF, Quaresma JA. 2014. Immunopathogenesis of HTLV-1-assoaciated myelopathy/tropical spastic paraparesis (HAM/TSP). Life Sci. 104(1-2):9–14. 10.1016/j.lfs.2014.03.025 24704970
Gabet AS, Mortreux F, Talarmin A, Plumelle Y, Leclercq I, Leroy A, Gessain A, Clity E, Joubert M, Wattel E. 2000. High circulating proviral load with oligoclonal expansion of HTLV-1 bearing T cells in HTLV-1 carriers with strongyloidiasis. Oncogene. 19(43):4954–4960. 10.1038/sj.onc.1203870 11042682
Gessain A, Cassar O. 2012. Epidemiological aspects and world distribution of HTLV-1 infection. Front Microbiol. 3(NOV). 10.3389/fmicb.2012.00388 23162541
Giam CZ, Jeang KT. 2007. HTLV-1 Tax and adult T-cell leukemia. Front Biosci. 12:1496–1507. 10.2741/2163 17127397
Glowacka I, Korn K, Potthoff SA, Lehmann U, Kreipe HH, Ivens K, Barg-Hock H, Schulz TF, Heim A. 2013. Delayed seroconversion and rapid onset of lymphoproliferative disease after transmission of human T-cell lymphotropic virus type 1 from a multiorgan donor. Clin Infect Dis. 57(10):1417–1424. 10.1093/cid/cit545 23956168
Gonçalves DU, Proietti FA, Ribas JG, Araujo MG, Pinheiro SR, Guedes AC, Carneiro-Proietti AB. 2010. Epidemiology, treatment, and prevention of human T-cell leukemia virus type 1-associated diseases. Clin Microbiol Rev. 23(3):577–589. 10.1128/CMR.00063-09 20610824
Gross C, Thoma-Kress AK. 2016. Molecular mechanisms of HTLV-1 cell-to-cell transmission. Viruses. 8(3):74. 10.3390/v8030074 27005656
Grossman WJ, Kimata JT, Wong FH, Zutter M, Ley TJ, Ratner L. 1995. Development of leukemia in mice transgenic for the tax gene of human T-cell leukemia virus type I. Proc Natl Acad Sci USA. 92(4):1057–1061. 10.1073/pnas.92.4.1057 7862633
Hill AB. 1965. The environment and disease: Association or causation? Proc R Soc Med. 58(5):295–300. 10.1177/003591576505800503 14283879
Hino S. 2011. Establishment of the milk-borne transmission as a key factor for the peculiar endemicity of human T-lymphotropic virus type 1 (HTLV-1): The ATL Prevention Program Nagasaki. Proc Jpn Acad, Ser B Phys Biol Sci. 87(4):152–166. 10.2183/pjab.87.152 21558754
Hisada M, Okayama A, Shioiri S, Spiegelman DL, Stuver SO, Mueller NE. 1998 a. Risk factors for adult T-cell leukemia among carriers of human T-lymphotropic virus type I. Blood. 92(10):3557–3561. 10.1182/blood.V92.10.3557.422k09_3557_3561 9808547
Hisada M, Okayama A, Spiegelman D, Mueller NE, Stuver SO. 2001. Sex-specific mortality from adult T-cell leukemia among carriers of human T-lymphotropic virus type I. Int J Cancer. 91(4):497–499. 10.1002/1097-0215(20010215)91:4<497::AID-IJC1044>3.0.CO;2-A 11251972
Hisada M, Okayama A, Tachibana N, Stuver SO, Spiegelman DL, Tsubouchi H, Mueller NE. 1998 b. Predictors of level of circulating abnormal lymphocytes among human T-lymphotropic virus type I carriers in Japan. Int J Cancer. 77(2):188–192. 10.1002/(SICI)1097-0215(19980717)77:2<188::AID-IJC3>3.0.CO;2-M 9650550
Hlela C, Bittencourt A. 2014. Infective dermatitis associated with HTLV-1 mimics common eczemas in children and may be a prelude to severe systemic diseases. Dermatol Clin. 32(2):237–248. 10.1016/j.det.2013.11.006 24680009
Ichimaru M, Ikeda S, Kinoshita K, Hino S, Tsuji Y. 1991. Mother-to-child transmission of HTLV-1. Cancer Detect Prev. 15(3):177–181. 1905579
Iida S, Fujiyama S, Yoshida K, Morishita T, Shibata J, Sato T, Nishimura Y. 1988. The seroprevalence of anti-HTLV-1 antibodies in patients with various liver diseases. Hepatogastroenterology. 35(5):242–244. 3229734
International Agency for Research on Cancer (IARC). 1996. Human Immunodeficiency Viruses and Human T-Cell Lymphotropic Viruses. Lyon, France: International Agency for Research on Cancer; Human T-cell lymphotropic viruses; p. 261–390.
International Agency for Research on Cancer (IARC). 1997 a. Epstein-Barr Virus and Kaposi’s Sarcoma Herpesvirus/Human Herpesvirus 8. Lyon, France: IARC Working Group on the Evaluation of Carcinogenic Risks to Humans; Epstein-Barr virus; p. 47–373.
International Agency for Research on Cancer (IARC). 1997 b. IARC Working Group on the Evaluation of Carcinogenic Risks to Humans. Lyon, France: International Agency for Research on Cancer; Epstein-Barr virus and Kaposi’s sarcoma herpesvirus/human herpesvirus 8; p. 549.
International Agency for Research on Cancer (IARC). 2012. Biological Agents. Lyon, France: International Agency for Research on Cancer; Human T-cell lymphotropic viruse type 1; p. 315–340.
Iwanaga M, Watanabe T, Yamaguchi K. 2012. Adult T-cell leukemia: A review of epidemiological evidence. Front Microbiol. 3:322. 10.3389/fmicb.2012.00322 22973265
Iwata K, Ito S, Saito H, Ito M, Nagatomo M, Yamasaki T, Yoshida S, Suto H, Tajima K. 1994. Mortality among inhabitants of an HTLV-I endemic area in Japan. Jpn J Cancer Res. 85(3):231–237. 10.1111/j.1349-7006.1994.tb02087.x 8188520
Jacobson S, Massoud R. 2013. Human T-cell lymphotropic virus type 1 infection. Birkhauser Advances in Infectious Diseases. Basel, Switzerland: Springer; p. 183–207.
Kamihira S, Yamada Y, Sohda H, Atogami S, Tomonaga M, Egawa S, Fujii M, Chifu K. 1994. Human T-lymphotropic virus type-I influence on hepatotropic virus infections and the subsequent development of hepatocellular carcinoma. Cancer Detect Prev. 18(5):329–334. 7812978
Kamoi K, Mochizuki M. 2012. HTLV-1 uveitis. Front Microbiol. 3(Article 270):1-4.
Kannian P, Green PL. 2010. Human T lymphotropic virus type 1 (HTLV-1): Molecular biology and oncogenesis. Viruses. 2(9):2037–2077. 10.3390/v2092037 21994719
Khabbaz RF, Onorato IM, Cannon RO, Hartley TM, Roberts B, Hosein B, Kaplan JE. 1992. Seroprevalence of HTLV-1 and HTLV-2 among intravenous drug users and persons in clinics for sexually transmitted diseases. N Engl J Med. 326(6):375–380. 10.1056/NEJM199202063260604 1729620
Kinjo T, Ham-Terhune J, Peloponese JM Jr, Jeang KT. 2010. Induction of reactive oxygen species by human T-cell leukemia virus type 1 tax correlates with DNA damage and expression of cellular senescence marker. J Virol. 84(10):5431–5437. 10.1128/JVI.02460-09 20219913
Koga Y, Iwanaga M, Soda M, Inokuchi N, Sasaki D, Hasegawa H, Yanagihara K, Yamaguchi K, Kamihira S, Yamada Y. 2010. Trends in HTLV-1 prevalence and incidence of adult T-cell leukemia/lymphoma in Nagasaki, Japan. J Med Virol. 82(4):668–674. 10.1002/jmv.21738 20166187
Kubota R, Hanada K, Furukawa Y, Arimura K, Osame M, Gojobori T, Izumo S. 2007. Genetic stability of human T lymphotropic virus type I despite antiviral pressures by CTLs. J Immunol. 178(9):5966–5972. 10.4049/jimmunol.178.9.5966 17442981
Kuo C-WS, Mirsaliotis A, Brighty DW. 2011. Antibodies to the envelope glycoprotein of human T cell leukemia virus type 1 robustly activate cell-mediated cytotoxic responses and directly neutralize viral infectivity at multiple steps of the entry process. J Immunol. 187(1):361–371. 10.4049/jimmunol.1100070 21646298
Manns A, Wilks RJ, Murphy EL, Haynes G, Figueroa JP, Barnett M, Hanchard B, Blattner WA. 1992. A prospective study of transmission by transfusion of HTLV-I and risk factors associated with seroconversion. Int J Cancer. 51(6):886–891. 10.1002/ijc.2910510609 1639536
Marcos LA, Terashima A, Dupont HL, Gotuzzo E. 2008. Strongyloides hyperinfection syndrome: An emerging global infectious disease. Trans R Soc Trop Med Hyg. 102(4):314–318. 10.1016/j.trstmh.2008.01.020 18321548
Marin O, Hasui K, Remondegui C, Sato E, Aye MM, Takenouchi N, Izumo S, Tajima K. 2002. Adult T-cell leukemia/lymphoma in Jujuy, north-west Argentina. Pathol Int. 52(5-6):348–357. 10.1046/j.1440-1827.2002.01356.x 12100517
Matsumoto S, Yamasaki K, Tsuji K, Shirahama S. 2008. Human T lymphotropic virus type 1 infection and gastric cancer development in Japan. J Infect Dis. 198(1):10–15. 10.1086/588733 18544011
Matsuoka M. 2005. Human T-cell leukemia virus type I (HTLV-I) infection and the onset of adult T-cell leukemia (ATL). Retrovirology. 2:27. 10.1186/1742-4690-2-27 15854229
Matsuoka M, Jeang KT. 2007. Human T-cell leukaemia virus type 1 (HTLV-1) infectivity and cellular transformation. Nat Rev Cancer. 7(4):270–280. 10.1038/nrc2111 17384582
Matsuoka M, Yasunaga J. 2013. Human T-cell leukemia virus type 1: Replication, proliferation and propagation by Tax and HTLV-1 bZIP factor. Curr Opin Virol. 3(6):684–691. 10.1016/j.coviro.2013.08.010 24060211
Matutes E. 2007. Adult T-cell leukaemia/lymphoma. J Clin Pathol. 60(12):1373–1377. 10.1136/jcp.2007.052456 18042693
McKendall RR. 2014. Neurologic disease due to HTLV-1 infection. Handb Clin Neurol. 123:507–530. 10.1016/B978-0-444-53488-0.00024-9 25015502
Mesri EA, Feitelson MA, Munger K. 2014. Human viral oncogenesis: A cancer hallmarks analysis. Cell Host Microbe. 15(3):266–282. 10.1016/j.chom.2014.02.011 24629334
Moles R, Nicot C. 2015. The emerging role of miRNAs in HTLV-1 infection and ATLL pathogenesis. Viruses. 7(7):4047–4074. 10.3390/v7072805 26205403
Moore PS, Chang Y. 2010. Why do viruses cause cancer? Highlights of the first century of human tumour virology. Nat Rev Cancer. 10(12):878–889. 10.1038/nrc2961 21102637
Moore PS, Chang Y. 2014. The conundrum of causality in tumor virology: The cases of KSHV and MCV. Semin Cancer Biol. 26:4–12. 10.1016/j.semcancer.2013.11.001 24304907
Mortreux F, Gabet AS, Wattel E. 2003. Molecular and cellular aspects of HTLV-1 associated leukemogenesis in vivo. Leukemia. 17(1):26–38. 10.1038/sj.leu.2402777 12529656
Moulés V, Pomier C, Sibon D, Gabet AS, Reichert M, Kerkhofs P, Willems L, Mortreux F, Wattel E. 2005. Fate of premalignant clones during the asymptomatic phase preceding lymphoid malignancy. Cancer Res. 65(4):1234–1243. 10.1158/0008-5472.CAN-04-1834 15735007
Murphy EL, Figueroa JP, Gibbs WN, Holding-Cobham M, Cranston B, Malley K, Bodner AJ, Alexander SS, Blattner WA. 1991. Human T-lymphotropic virus type I (HTLV-I) seroprevalence in Jamaica. I. Demographic determinants. Am J Epidemiol. 133(11):1114–1124. 10.1093/oxfordjournals.aje.a115824 2035515
Murphy EL, Fridey J, Smith JW, Engstrom J, Sacher RA, Miller K, Gibble J, Stevens J, Thomson R, Hansma D, et al. 1997 a. HTLV-associated myelopathy in a cohort of HTLV-I and HTLV-II-infected blood donors. The REDS investigators. Neurology. 48(2):315–320. 10.1212/WNL.48.2.315 9040713
Murphy EL, Glynn SA, Fridey J, Sacher RA, Smith JW, Wright DJ, Newman B, Gibble JW, Ameti DI, Nass CC, et al. 1997 b. Increased prevalence of infectious diseases and other adverse outcomes in human T lymphotropic virus types I- and II-infected blood donors. Retrovirus Epidemiology Donor Study (REDS) Study Group. J Infect Dis. 176(6):1468–1475. 10.1086/514143 9395356
Murphy EL, Hanchard B, Figueroa JP, Gibbs WN, Lofters WS, Campbell M, Goedert JJ, Blattner WA. 1989. Modelling the risk of adult T-cell leukemia/lymphoma in persons infected with human T-lymphotropic virus type I. Int J Cancer. 43(2):250–253. 10.1002/ijc.2910430214 2917802
Murphy EL, Watanabe K, Nass CC, Ownby H, Williams A, Nemo G. 1999. Evidence among blood donors for a 30-year-old epidemic of human T lymphotropic virus type II infection in the United States. J Infect Dis. 180(6):1777–1783. 10.1086/315139 10558931
National Toxicology Program (NTP). 2015. Handbook for preparing the report on carcinogens monographs. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, Division of the National Toxicoogy Program, Office of the Report on Carcinogens. https://ntp.niehs.nih.gov/ntp/roc/handbook/roc_handbook_508.pdf.
Okayama A, Maruyama T, Tachibana N, Hayashi K, Kitamura T, Mueller N, Tsubouchi H. 1995. Increased prevalence of HTLV-I infection in patients with hepatocellular carcinoma associated with hepatitis C virus. Jpn J Cancer Res. 86(1):1–4. 10.1111/j.1349-7006.1995.tb02979.x 7737899
Okayama A, Stuver S, Matsuoka M, et al. 2004. Role of HTLV-1 proviral DNA load and clonality in the development of adult T-cell leukemia/lymphoma in asymptomatic carriers. Int J Cancer. 110:621–625. 10.1002/ijc.20144 15122598
Pancake BA, Wassef EH, Zucker-Franklin D. 1996. Demonstration of antibodies to human T-cell lymphotropic virus-I tax in patients with the cutaneous T-cell lymphoma, mycosis fungoides, who are seronegative for antibodies to the structural proteins of the virus. Blood. 88(8):3004–3009. 10.1182/blood.V88.8.3004.bloodjournal8883004 8874198
Plumelle Y, Gonin C, Edouard A, Bucher BJ, Thomas L, Brebion A, Panelatti G. 1997. Effect of Strongyloides stercoralis infection and eosinophilia on age at onset and prognosis of adult T-cell leukemia. Am J Clin Pathol. 107(1):81–87. 10.1093/ajcp/107.1.81 8980372
Poiesz BJ, Papsidero LD, Ehrlich G, Sherman M, Dube S, Poiesz M, Dillon K, Ruscetti FW, Slamon D, Fang C, et al. 2001. Prevalence of HTLV-I-associated T-cell lymphoma. Am J Hematol. 66(1):32–38. 10.1002/1096-8652(200101)66:1<32::AID-AJH1004>3.0.CO;2-3 11426489
Poiesz BJ, Ruscetti FW, Gazdar AF, Bunn PA, Minna JD, Gallo RC. 1980. Detection and isolation of type C retrovirus particles from fresh and cultured lymphocytes of a patient with cutaneous T-cell lymphoma. Proc Natl Acad Sci USA. 77(12):7415–7419. 10.1073/pnas.77.12.7415 6261256
Poiesz BJ, Ruscetti FW, Reitz MS, Kalyanaraman VS, Gallo RC. 1981. Isolation of a new type C retrovirus (HTLV) in primary uncultured cells of a patient with Sézary T-cell leukaemia. Nature. 294(5838):268–271. 10.1038/294268a0 6272125
Population Reference Bureau (PRB). 2012. 2012 world population data sheet. Washington, DC. https://www.prb.org/pdf12/2012-population-data-sheet_eng.pdf. [Accessed: August 26, 2015]
Pozzatti R, Vogel J, Jay G. 1990. The human T-lymphotropic virus type I tax gene can cooperate with the ras oncogene to induce neoplastic transformation of cells. Mol Cell Biol. 10(1):413–417. 2403646
Rahman S, Quann K, Pandya D, Singh S, Khan ZK, Jain P. 2012. HTLV-1 Tax mediated downregulation of miRNAs associated with chromatin remodeling factors in T cells with stably integrated viral promoter. PLoS One. 7(4):e34490. 10.1371/journal.pone.0034490 22496815
Ramanan P, Deziel PJ, Norby SM, Yao JD, Garza I, Razonable RR. 2014. Donor-transmitted HTLV-1-associated myelopathy in a kidney transplant recipient—case report and literature review. Am J Transplant. 14(10):2417–2421. 10.1111/ajt.12849 25138148
Rothman KJ, Greenland S. 2005. Causation and causal inference in epidemiology. Am J Public Health. 95 Suppl 1:S144–S150. 10.2105/AJPH.2004.059204 16030331
Sabino EC, Zrein M, Taborda CP, Otani MM, Ribeiro-Dos-Santos G, Sáez-Alquézar A. 1999. Evaluation of the INNO-LIA HTLV I/II assay for confirmation of human T-cell leukemia virus-reactive sera in blood bank donations. J Clin Microbiol. 37(5):1324–1328. 10.1128/JCM.37.5.1324-1328.1999 10203479
Sakata H, Iwakiri R, Koyama T, Yoshida T, Okamoto K, Miyazaki K, Mizuguchi TM, Kudo S, Tokunaga O, Fujimoto K. 2001. Human T-cell lymphotropic virus-associated primary gastric lymphoma. Dig Dis Sci. 46(7):1381–1386. 10.1023/A:1010667232366 11478487
Sampey GC, Van Duyne R, Currer R, Das R, Narayanan A, Kashanchi F. 2012. Complex role of microRNAs in HTLV-1 infections. Front Genet. 3:295. 10.3389/fgene.2012.00295 23251140
Satoh M, Toma H, Sugahara K, Etoh K, Shiroma Y, Kiyuna S, Takara M, Matsuoka M, Yamaguchi K, Nakada K, et al. 2002. Involvement of IL-2/IL-2R system activation by parasite antigen in polyclonal expansion of CD4(+)25(+) HTLV-1-infected T-cells in human carriers of both HTLV-1 and S. stercoralis. Oncogene. 21(16):2466–2475. 10.1038/sj.onc.1205329 11971181
Satou Y, Yasunaga J, Yoshida M, Matsuoka M. 2006. HTLV-I basic leucine zipper factor gene mRNA supports proliferation of adult T cell leukemia cells. Proc Natl Acad Sci USA. 103(3):720–725. 10.1073/pnas.0507631103 16407133
Schäfer G, Blumenthal MJ, Katz AA. 2015. Interaction of human tumor viruses with host cell surface receptors and cell entry. Viruses. 7(5):2592–2617. 10.3390/v7052592 26008702
Shimada-Hiratsuka M, Fukayama M, Hayashi Y, et al. 1997. Primary gastric T-cell lymphoma with and without human T-lymphotropic virus type 1. Cancer. 80:292–303. 10.1002/(SICI)1097-0142(19970715)80:2<292::AID-CNCR18>3.0.CO;2-P 9217043
Stienlauf S, Yahalom V, Shinar E, Sidi Y, Segal G, Schwartz E. 2013. Malignant diseases and mortality in blood donors infected with human T-lymphotropic virus type 1 in Israel. Int J Infect Dis. 17(11):e1022–e1024. 10.1016/j.ijid.2013.03.012 23642569
Tahaei SM, Mohebbi SR, Fatemi SR, Mohammadi P, Malek FN, Azimzadeh P, Almasi S, Mirsattari D, Zali MR. 2011. Low frequency of human T-cell lymphotropic virus 1 antibodies in Iranian gastric cancer patients in comparison to controls. Asian Pac J Cancer Prev. 12(9):2447–2450. 22296399
Takatsuki K, Matsuoka M, Yamaguchi K. 1977. Adult T-cell leukemia in Japan. In: Seno S, Takaku S, Irino S, editors. Topics in Hematology. Amsterdam: Excerpta Medica; p. 73–77.
Tanaka A, Takahashi C, Yamaoka S, Nosaka T, Maki M, Hatanaka M. 1990. Oncogenic transformation by the tax gene of human T-cell leukemia virus type I in vitro. Proc Natl Acad Sci USA. 87(3):1071–1075. 10.1073/pnas.87.3.1071 2300570
Tezuka K, Xun RZ, Tei MM, Ueno T, Tanaka M, Takenouchi N, Fujisawa J. 2014. An animal model of adult T-cell leukemia: Humanized mice with HTLV-1-specific immunity. Blood. 123(3):346–355. 10.1182/blood-2013-06-508861 24196073
Thomas A, Perzova R, Abbott L, Benz P, Poiesz MJ, Dube S, Loughran T, Ferrer J, Sheremata W, Glaser J, et al. 2010. LGL leukemia and HTLV. AIDS Res Hum Retroviruses. 26(1):33–40. 10.1089/aid.2009.0124 20047475
Tokudome S, Maeda Y, Fukada K, Teshima D, Asakura T, Sueoka E, Motomura Y, Kusumoto Y, Imamura Y, Kiyokawa T, et al. 1991. Follow-up of asymptomatic HTLV-I carriers among blood donors in Kyushu, Japan. Cancer Causes Control. 2(2):75–78. 10.1007/BF00053124 1873439
Uchiyama T, Yodoi J, Sagawa K, Takatsuki K, Uchino H. 1977. Adult T-cell leukemia: Clinical and hematologic features of 16 cases. Blood. 50(3):481–492. 10.1182/blood.V50.3.481.481 301762
U.S. Food and Drug Administration (FDA). 2015. Complete list of vaccines licensed for immunization and distribution in the U.S. Silver Spring, MD. https://www.fda.gov/BiologicsBloodVaccines/Vaccines/ApprovedProducts/ucm093833.htm. [Accessed: August 26, 2015]
Villaudy J, Wencker M, Gadot N, Gillet NA, Scoazec JY, Gazzolo L, Manz MG, Bangham CR, Dodon MD. 2011. HTLV-1 propels thymic human T cell development in “human immune system” Rag2-/- gamma c-/- mice. PLoS Pathog. 7(9):e1002231. 10.1371/journal.ppat.1002231 21909275
Weatherhead JE, Mejia R. 2014. Immune response to infection with Strongyloides stercoralis in patients with infection and hyperinfection. Curr Trop Med Rep. 1(4):229–233. 10.1007/s40475-014-0032-9
Williams AE, Fang CT, Slamon DJ, Poiesz BJ, Sandler SG, Darr WF, Shulman G, McGowan EI, Douglas DK, Bowman RJ, et al. 1988. Seroprevalence and epidemiological correlates of HTLV-I infection in U.S. blood donors. Science. 240(4852):643. 10.1126/science.2896386 2896386
Yamamoto JF, Goodman MT. 2008. Patterns of leukemia incidence in the United States by subtype and demographic characteristics, 1997-2002. Cancer Causes Control. 19(4):379–390. 10.1007/s10552-007-9097-2 18064533
Yao J, Wigdahl B. 2000. Human T cell lymphotropic virus type I genomic expression and impact on intracellular signaling pathways during neurodegenerative disease and leukemia. Front Biosci. 5:D138–D168. 10.2741/Yao 10702386
Yoshida M. 2001. Multiple viral strategies of HTLV-1 for dysregulation of cell growth control. Annu Rev Immunol. 19:475–496. 10.1146/annurev.immunol.19.1.475 11244044
Yoshida M, Miyoshi I, Hinuma Y. 1982. Isolation and characterization of retrovirus from cell lines of human adult T-cell leukemia and its implication in the disease. Proc Natl Acad Sci USA. 79(6):2031–2035. 10.1073/pnas.79.6.2031 6979048
Yoshida M, Seiki M, Yamaguchi K, Takatsuki K. 1984. Monoclonal integration of human T-cell leukemia provirus in all primary tumors of adult T-cell leukemia suggests causative role of human T-cell leukemia virus in the disease. Proc Natl Acad Sci USA. 81(8):2534–2537. 10.1073/pnas.81.8.2534 6326131
Yoshimitsu M, Kozako T, Arima N. 2013. Prevention of human T-cell lymphotropic virus infection and adult T-cell leukemia. T-Cell Leukemia — Characteristics, Treatment and Prevention. Rijeka, Croatia: InTech; p. 105–118.
Zane L, Jeang KT. 2014. HTLV-1 and leukemogenesis: Virus-cell interactions in the development of adult T-cell leukemia. Recent Results Cancer Res. 193:191–210. 10.1007/978-3-642-38965-8_11 24008300
Zhao T, Matsuoka M. 2012. HBZ and its roles in HTLV-1 oncogenesis. Front Microbiol. 3:247. 10.3389/fmicb.2012.00247 22787458
zur Hausen H. 1994. Molecular pathogenesis of cancer of the cervix and its causation by specific human papillomavirus types. Curr Top Microbiol Immunol. 186:131–156. 10.1007/978-3-642-78487-3_8 8205839
zur Hausen H. 2001. Oncogenic DNA viruses. Oncogene. 20(54):7820–7823. 10.1038/sj.onc.1204958 11753664
zur Hausen H, de Villiers EM. 2014. Cancer “causation” by infections—individual contributions and synergistic networks. Semin Oncol. 41(6):860–875. 10.1053/j.seminoncol.2014.10.003 25499643