# Appendix A Literature Search Strategy

The objective of the literature search approach is to identify published literature that is relevant for evaluating the potential carcinogenicity of the human T-lymphotropic virus (HTLV). As discussed in the Viruses Concept Document (https://ntp.niehs.nih.gov/ntp/roc/concept_docs/2014/virusesconcept_508.pdf), the monograph relies on the IARC monograph and studies published since the monograph (new studies). The literature search strategy was used to identify new human cancer studies and recent reviews of mechanistic data.

## A.1 General Approach

Database searching encompasses selecting databases and search terms and conducting the searches. Searches of several citation databases are generally conducted using search terms for the individual viruses of interest, combined with search terms for cancer and/or specific topics, including epidemiological and mechanistic studies. A critical step in the process involves consultation with an information specialist to develop relevant search terms. These terms are used to search bibliographic databases. IARC used literature found by searching PubMed for HTLV through 12/2008, so PubMed, Web of Science and Scopus were searched for new information about HTLV from >2008 to August 2015. Table A-1 highlights the general concepts searched with selected example terms. To review all the terms used, please refer to the full search strings below.

Table A-1 Major Topics Searched

Topics | Example Terms
Human T-lymphotropic virus type 1 | Human T-lymphotropic virus type 1 (Mesh), adult T-cell leukemia-lymphoma virus 1, human T-cell leukemia virus 1, HTLV
General cancer | Neoplasm(s), tumor(s), leukemia, cancer(s)
Study types Epidemiology terms | Case control, ecological studies, follow-up study cohort, epidemiologic studies (Mesh), epidemiology (Subheading)
Mechanistic terms | Mode of action, mechanism

The literature for HTLV was searched without using narrowing terms within the bibliographic databases. The results were then processed in EndNote to remove duplicates and conduct a second level of searching for the relevant major topics, before being transferred to DistillerSR for screening.

The bibliographic database search results (909) were processed in Endnote then imported into DistillerSR for first and second tier screening. Relevant studies found through the citations of review articles and other secondary searched were also included. Tagging in DistillerSR categorized the useful articles into Human Epidemiologic literature (77) or Mechanistic literature (269).

Figure A-1

Literature Processing Flow

## A.2 Search Strings for HTLV-1 Searches

[underlined: PubMed]: 2010–2015

“Human T-lymphotropic virus type 1”[MeSH] OR “Human T-lymphotropic virus type 1” OR “HTLV-1” OR “HTLV” OR “Human T-cell leukemia virus 1” OR “Adult T-cell leukemia-lymphoma virus 1”

Scopus and WOS: 2010–2015

“Human T-lymphotropic virus type 1” OR “HTLV-1” OR “HTLV” OR “Human T-cell leukemia virus 1” OR “Adult T-cell leukemia-lymphoma virus 1”

Endnote searching:

Cancer* OR Neoplas* OR Tumor* OR Lymphoma* OR Leukemia*

Epidemiol* OR Case report OR Case control OR Case series OR Case referent OR Cohort OR Registry

Mode of action OR Mechanism