# 5 Overall Cancer Hazard Evaluation and Preliminary Listing Recommendation

Human immunodeficiency virus type 1 (HIV-1) is known to be a human carcinogen based on sufficient evidence from studies in humans. This conclusion is based on epidemiological studies showing that HIV-1 increases the risk of Kaposi sarcoma, non-Hodgkin lymphoma, cervical cancer (see Table 5-1); Hodgkin lymphoma, invasive anal cancer, genital cancers (see Table 5-2); conjunctival cancer, non-melanoma and skin cancer(see Table 5-3) in humans, together with supporting evidence from mechanistic studies demonstrating the biological plausibility of its carcinogenicity in humans. Epidemiological studies also provide limited evidence of a causal association for cancers of the liver, lung, and oropharynx (see Table 5-2).

Table 5-1 Summary of the Evidence for AIDS-defining Cancers^a^

Cancer | Level of Evidence | Evidence and Viral Cofactors
Kaposi sarcoma | Sufficient | Epidemiological evidence Consistent evidence of increased risk. Statistically significant very high RRs reported in over 35 cohort studies from western countries. Increased risks ranged from 100s to 10,000s. Dose response with HIV-1 titers. Statistically significantly decreased RR in HAART era (0.19–0.92) vs. pre- or early HAART supports findings. Viral co-factor: KSHV All cases occur in KSHV-infected individuals. HIV-1 and KSHV (HIV-1 Tat protein enhances KSHV entry into cells).
Non-Hodgkin lymphoma | Sufficient | Epidemiological evidence Consistent evidence of increased risk. Statistically significant high RR in over 35 cohort studies. Increased risks 10 to ~300 fold in most studies. mRR = 77 (95% CI = 39–149) 5,295 cases from 6 studies (Grulich et al. 2007). Statistically significantly decreased RR in HAART era (30%–80%) vs. pre- or early HAART and associated decreased viral titers supports finding. Viral co-factor: EBV EBV infection in some but not all non-Hodgkin lymphoma subtypes.
Cervical cancer | Sufficient | Epidemiological evidence Consistent evidence of increased risk. Statistically significantly elevated RR found in most of at least 30 cohort studies. Increased risks 2–22 fold in most studies. mRR = 5.8 (95% CI = 3–11.3); 104 HIV-1-infected cases from 6 studies (Grulich et al. 2007). RR higher in people with AIDS (mostly ranged from ~3–50) compared to HIV-1-infected populations (mostly ranged from ~3–15). Viral co-factor: HPV Oncogenic HPV necessary.

AIDS = acquired immune deficiency syndrome; EBV = Epstein-Barr virus; HAART = highly active antiretroviral therapy; HIV = human immunodeficiency virus; HPV = human papillomavirus; KSHV = Kaposi sarcoma-associated herpesvirus; mRR = relative risk from a meta-analysis; RR = relative risk.

^a^ Numbers in epidemiological studies based on IARC (1996; 2012a).

Table 5-2 Summary of the Evidence for Non-AIDS-defining Cancers: Infection Related^a^

Cancer | Level of Evidence | Evidence and Viral Co-factors
Hodgkin lymphoma | Sufficient | Epidemiological evidence Consistent evidence of increased risk. Statistically significant RRs ranging from ~4–38 in over 40 large cohort studies. Elevated risks found among people with AIDS compared to people with HIV-1 without AIDS. mRR = 11 (95% CI = 8.4–14.4); 5,295 cases from 6 studies. (Grulich et al. 2007). mRR = 11 (95% CI = 8.5–15); 643 cases from 6 studies (Shiels et al. 2009). Viral co-factor: EBV 80%–100% of HIV-1-Hodgkin lymphoma cases co-infected with EBV.
Anal cancer | Sufficient | Epidemiological evidence Consistent evidence of increased risk. Statistically significant RR (mostly ranging from 10–100 with a few studies with risk ranging from 60–~350) found in at least 38 cohort studies. Risks higher among people with AIDS compared to HIV-1-infected individuals without AIDS. mRR = 28.8 (95% CI = 21.6–38.3); 303 cases from 6 studies (Grulich et al. 2007). mRR = 28 (95% CI = 21–35); 243 cases from 8 studies (Shiels et al. 2009). Viral co-factor: HPV Oncogenic HPV present.
Genital (vaginal/vulvar, penile) cancers | Sufficient | Epidemiological evidence [underlined: Vaginal/vulvar cancer:] Consistent evidence of increased risk in at least 7 cohort studies, most reporting statistically significant risks ranging from 5 to 27; one study had over 123 cases. RR lower for invasive cancer compared to in situ cancers, but still elevated (RR = ~5). mSIR = 9.4 (95% CI = 4.9–18) 25 cases; 4 studies (Shiels et al. 2009). Positive association with CD4 levels at AIDS onset. [underlined: Penile cancer]: Consistent evidence of increased risk in at least 6 cohort studies, most reporting statistically significant risks ranging from 4–28. RR lower for invasive cancer compared to in situ cancers, but still elevated (RR = ~5). mSIR = 6.8 (95% CI = 4.2–11); 16 cases; 3 studies (Shiels et al. 2009). Viral co-factor: HPV
Oral-related cancer | Limited | Epidemiological evidence Consistent evidence of modest increased risk across various groupings of oral-related cancers (e.g., oropharynx, oral cavity/pharyngeal, oral cavity) in at least 21 studies (most risks between 2 and 4) compared to general population based primarily on HIV cohort registry studies. mSIR = 2.3 (95% CI = 1.65–3.25); N = 238 HIV-1-infected cases from 4 studies (Grulich et al. 2007). Most studies do not account for disease heterogeneity (e.g., distinct tumor types or sites, HPV associated and HPV nonassociated), and potential confounders or unmeasured variations in sexual behaviors and other risk factors (e.g., smoking) across cohorts. Inconsistent evidence of the effect of immunosuppression and the effects of HAART on risk of oral-related cancer. Viral co-factor: HPV Oncogenic HPV necessary in some types of cancer.
Liver cancer | Limited | Epidemiological evidence Consistent evidence of increased risk (hepatocellular carcinoma). Most were statistically significant RRs (mostly ranging from 2–16) in at least 39 large cohort studies. Risks higher among people with AIDS compared to HIV-1-infected individuals without AIDS. mSIR = 5.2 (95% CI = 3.3–8.2); 133 cases from 7 studies (Grulich et al. 2007). mSIR = 5.6 (95% CI = 4.0–7.7); 171 cases from 11 studies studies (Shiels et al. 2009). Viral co-factor: HCV It is unclear whether HCV is a co-factor or confounder. Some studies have either not found an excess risk for liver cancer or have found a doubling of risk of HCC in men with cirrhosis and hepatitis C compared to those co-infected with HCV and HIV.

AIDS = acquired immunodeficiency syndrome; EBV = Epstein-Barr virus; HCC = hepatocellular carcinoma; HCV = hepatitis C virus; HIV = human immunodeficiency virus; mRR = relative risk from a meta-analysis; mSIR = standardized incidence ratio from a meta-analysis; RR = relative risk.

^a^ Numbers in epidemiology studies based on IARC (1996; 2012a), except for liver and genital cancers.

Table 5-3 Summary of the Evidence for Non-AIDS-defining Cancers: Not Infection Related^a^

Cancer | Level of Evidence | Epidemiological Evidence
Conjunctival cancer | Sufficient | Consistent evidence of increased risk. Statistically significant RR (mostly between 6 and 8) in 4 large cohort studies and in 4 case-control studies (150 cases). Potential co-factor: Ultraviolet radiation
Non-melanoma skin cancer | Sufficient | Consistent evidence of increased risk. At least 19 studies, most of which reported statistically significant RR (ranging between 1.5 and 6 with a few studies ranging up to 20) in over 15 cohorts. Risks found in HIV-1-infected and AIDS population. mRR = 2.76 (95% CI = 2.55–2.98); 6 cohorts. (Diagnosis verified via cancer registry.) Significant association with HIV-1 RNA in blood in one study.
Lung cancer | Limited | Consistent evidence for increased risk. At least 48 cohort studies, most of which reported statistically significant RRs (between 1.5 and 6). mRR = 2.7 (95% CI = 1.9–3.9); 7 studies, 1,016 cases (Grulich et al. 2007). mRR = 2.6 (95% CI = 2.1–3.1); 13 studies, 847 cases (Shiels et al. 2009). Smoking explains some but not all the excess risk; residual confounding may be present. 7/8 cohort studies that controlled for smoking or modeled bias from smoking found elevated risks for smoking; 6/7 were statistically significant. Mechanism not known; does not appear to be related to immunosuppression.

AIDS = acquired immune deficiency syndrome; HIV = human immunodeficiency virus; mRR = relative risk from a meta-analysis; RR = relative risk.

^a^ Numbers in epidemiology studies based on IARC (1996; 2012a) except for skin and lung cancers.

These cancer sites include both AIDS-defining and non-AIDS-defining cancers and include a broad spectrum of malignancies for which HIV-1-positive persons have an elevated risk over the general population. In addition, an estimated 70% of cancers in the HIV-1-positive population have a known infectious cause compared with only 12% in the HIV-1-negative population. The evidence from studies in humans establishing links for various cancer sites and supporting mechanisms are discussed below and organized according to the following groups: AIDS-defining cancers, non-AIDS-defining cancers that are infection related, and non-AIDS-defining cancers that are not believed to be infection related.

## 5.1 AIDS-defining Cancers

This section summarizes the preliminary level of evidence recommendations from studies in humans (Section 5.2.1) and supporting mechanistic data. (Section 5.2.2).

### 5.1.1 Level of Evidence from Studies in Humans

The preliminary level of evidence recommendations from studies in humans and the rationale for those recommendations for the three AIDS-defining cancers are provided in Table 5-1.

### 5.1.2 Mechanistic Evidence

The primary mode of action of HIV-1 is progressive depletion of CD4 T lymphocytes, which are responsible for helper functions in cell-mediated immunity (Clifford and Franceschi 2009). With Kaposi sarcoma and non-Hodgkin lymphoma, there is an increased cancer risk with decreases in CD4 T lymphocytes; however, the evidence with cervical carcinoma is less clear. Treatment with drugs (HAART) that specifically prevent HIV-1 replication and CD4 T-cell depletion diminishes the cancer risk for Kaposi sarcoma and non-Hodgkin lymphoma. Therefore, HIV-1 increases the risk of cancer primarily through immunodeficiency and reduced immune surveillance; therefore, increasing the risk of opportunistic infections, particularly by oncogenic viruses as seen with these malignancies.

## 5.2 Non-AIDS-defining Cancers That Are Thought to Be Infection Related

This section summarizes the preliminary level of evidence recommendations from studies in humans (Section 5.2.1) and supporting mechanistic data (Section 5.2.2).

### 5.2.1 Preliminary Level of Evidence Recommendation from Studies in Humans

The preliminary level of evidence recommendations from studies in humans and the rationale for those recommendations for the four non-AIDS-defining cancers related to infections are provided in Table 5-2.

### 5.2.2 Mechanistic Evidence

Non-AIDS-defining cancers that are thought to be infection related include a broad spectrum of cancers related to opportunistic cancers from co-infections with human papillomavirus (anogenital and oral-related cancers), Epstein-Barr virus (Hodgkin lymphoma), hepatitis B virus, or hepatitis C virus (liver cancer). In contrast to AIDS-defining malignancies, some non-AIDS-defining malignancies have increased in the post-HAART era and are largely attributed to increased survival and aging of the HIV-1-positive population. In addition, the risk of infection-related non-AIDS-defining cancers is also strongly associated with immunosuppression as measured by current CD4 cell count (Clifford and Franceschi 2009; Franceschi et al. 2008; Silverberg et al. 2007). The mechanistic data suggest that the increased incidence of infection-related non-AIDS-defining cancers in HIV-1-positive individuals could reflect a high prevalence of known cancer risk factors (e.g., infection with oncogenic viruses, tobacco use, alcohol, aging), an independent effect of HIV-1 on progression of cancer, or a biological interaction of HIV-1 with the known risk factors (Engels 2009).

## 5.3 Non-AIDS-defining Cancers: Not Known to Be Infection Related

This section summarizes the preliminary level of evidence recommendations from studies in humans (Section 5.3.1) and supporting mechanistic data (Section 5.3.2).

### 5.3.1 Preliminary Level of Evidence Recommendation from Studies in Humans

The preliminary level of evidence recommendations from studies in humans and the rationale for those recommendations for the three non-AIDS-defining cancers that are not linked to infections are summarized in Table 5-3.

### 5.3.2 Mechanistic Evidence

In addition to immunodeficiency, inflammation, and traditional risk factors (e.g., smoking, alcohol abuse, exposure to ultraviolet radiation, and age) may play a primary role or contribute to the excess of non-AIDS-defining cancers (Borges et al. 2013; Engels 2009; Shiels et al. 2011a; Silverberg and Abrams 2007). With conjunctival and non-melanoma skin cancers, exposure to ultraviolet radiation coupled with immunosuppression may have a role. A couple of studies have shown an association between HIV-1 infection and Merkel cell carcinoma, a rare type of skin cancer, and thus a viral component may be important for those specific types of skin cancer. Merkel cell carcinoma is associated with immunosuppression from HIV-1 or tissue transplants (Lanoy et al. 2010). In addition, case series studies on conjunctival cancer with HIV-1 have reported very low CD4 T-cell counts (~100/mm^3^). Mechanisms for lung cancer are not known but may involve interactions interaction of the effects of HIV-1 with tobacco use; lower levels of antioxidants in HIV-1-positive individuals; chronic lung damage, or amplification of the effects of other infectious agents but experimental support is limited. Finally, there is some limited evidence of decreased risk of these cancers post-HAART although toxicity and genotoxicity of drugs used in HAART therapy may also be a risk factor for these cancers (Borges et al. 2014).