# 4 Mechanisms and Other Relevant Data

It is clear that HIV-1-positive individuals are at an increased risk of developing cancer and that HIV-1 integrates its DNA into hundreds of sites in the host genome (Borges et al. 2013; Borges et al. 2014; IARC 2012a; Maldarelli et al. 2014). However, there is very little evidence that the transformed tumor cells harbor integrated HIV-1 proviruses, which generally rules out the known direct carcinogenic mechanism of insertional activation of proto-oncogenes (Borges et al. 2013; Craigie and Bushman 2012; IARC 1996; 2012a). Furthermore, HIV-1 infection alone does not induce cell transformation, and none of its encoded proteins are directly oncogenic (IARC 2012a). Most cancers associated with HIV-1 are infection related; therefore, HIV-1-related immune dysregulation is an important factor.

This section identifies some of the basic characteristics and risk factors associated with HIV-1-induced cancers (Section 4.1), reviews the experimental and biological evidence for the proposed modes of action and the evidence for cancer causation (Section 4.2), and provides a synthesis of the information (Section 4.2.3).

## 4.1 Characteristics and Risk Factors

Although immunosuppression is clearly associated with an increased risk of cancer in HIV-1-positive individuals, as well as in organ transplant patients (Bruyand et al. 2009; Engels et al. 2011; Grulich et al. 2007; Penn and Starzl 1973; Penn 1986; 1988; Shiels et al. 2011a), immunosuppression alone does not completely explain the incidence and spectrum of tumors observed in the HIV-1-positive populations pre- and post-HAART (see Section 3). Although HAART improves immune function and lowers HIV-1 viral load, it only partially normalizes the enhanced inflammation associated with HIV-1 (Borges et al. 2014). Further, while HAART therapy blocks HIV-1 infection of additional cells, it has no effect on infected cells and is a critical obstacle for curing HIV-1 infection (Maldarelli et al. 2014). Studies of HIV-1-infected populations show that after long-term HAART therapy, many of the infected cells that persist have undergone clonal expansion and were selected because they harbor integrated HIV-1 in specific genes that promote cell survival and expansion. Although, most studies have not shown evidence that HIV-1 integration contributes directly to cell transformation and malignancy, a few studies have reported that a small number of lymphomas harbor HIV-1 proviruses integrated at defined sites (Herndier et al. 1992; Shiramizu et al. 1994). Perhaps, prior attempts to detect HIV DNA in cancers examined only a small portion of the HIV-1 genome and missed HIV-1 proviruses with large deletions (proviruses that cause murine and avian tumors often contain large deletions) (Maldarelli et al. 2014). Thus, the mechanisms for HIV-1-induced cancer are complex and incompletely understood (Borges et al. 2013).

In a retrospective cohort study conducted in California (1996 to 2007) that included >20,000 HIV-1-infected and >200,000 HIV-1-uninfected adults, approximately 70% of cancers in the HIV-1-positive population had a known infectious cause compared with only 12% in the HIV-1-negative population (Silverberg et al. 2009). HIV-1 infection is thought to increase the risk of cancer primarily through immunosuppression and reduced immune surveillance (Silverberg et al. 2009; Silverberg et al. 2011). However, the data suggest that immunosuppression is not the only mechanism. Possible mechanisms or modes of action associated with AIDS-defining malignancies and non-AIDS-defining malignancies are briefly discussed in Sections 4.1.1 and 4.1.2, respectively.

### 4.1.1 AIDS-defining Malignancies

Oncogenic viral infections are usually kept under control by the host immune system; however, the risk of virus-associated malignancies dramatically increases in immunosuppressed populations (Engels et al. 2011; Shackelford and Pagano 2007; Shiels et al. 2011a). As noted in Section 3, co-infection with the oncogenic viruses Kaposi sarcoma-associated herpesvirus, Epstein-Barr virus, and oncogenic subtypes of human papillomavirus are associated with Kaposi sarcoma, non-Hodgkin lymphoma and cervical cancers, respectively. Overall, the data support a mechanism in which an HIV-1-impaired immune system cannot adequately suppress oncogenic viruses, resulting in an increased risk of infection-related cancer.

The declining incidence of HIV-1/AIDS combined with improved immune function from HAART therapy has significantly reduced the mortality of AIDS patients, predominantly due to a decrease in opportunistic infections, including at least a partial decrease in incidence rate and cases of some AIDS-defining malignancies and prolonged survival among HIV-1-positive individuals. As a consequence, the numbers of non-AIDS-defining malignancies have increased and are discussed in the following section.

### 4.1.2 Non-AIDS-defining Malignancies

Although non-AIDS-defining malignancies include numerous infection-related and infection-unrelated cancers, this evaluation focuses on several types that show a particularly strong association with HIV-1 infection (Hodgkin lymphoma, lung cancer, anogenital cancer, oral-related cancer, liver cancer, and non-melanoma skin cancers) (Bedimo et al. 2009; Engels 2009; Frisch et al. 2000; Patel et al. 2008; Shiels et al. 2011a; Silverberg et al. 2009; Vaccher et al. 2014). The risk for these cancer types in the HIV-1-positive population are substantial or increasing and account for about half of the non-AIDS-defining cancers reported in the United States (Shiels et al. 2011a). Immunodeficiency, inflammation, co-infections (e.g., hepatitis B and C viruses, human papillomaviruses, Epstein-Barr virus) and traditional risk factors (e.g., smoking, alcohol, age, ultraviolet radiation) are thought to play a significant role in the excess cancer risk (Engels 2009; Shiels et al. 2011a; Silverberg and Abrams 2007; Silverberg et al. 2011).

## 4.2 Mode of Action and Evidence for Cancer Causation

The primary mode of action of HIV-1 is progressive depletion of CD4+ T lymphocytes, which are responsible for helper functions in cell-mediated immunity (Clifford and Franceschi 2009). Therefore, HIV-1 increases the risk of cancer primarily through immunodeficiency and reduced immune surveillance, thus increasing the risk of opportunistic infections, particularly by oncogenic viruses.

Two primary lines of evidence support an indirect mechanistic link between HIV-1 infection and cancer. First, the pattern of increased risk for cancer in HIV-1/AIDS and immunosuppressed transplant recipients is similar and suggests that immune deficiency, rather than other cancer risk factors, is largely responsible (Grulich et al. 2007). Second, the vast majority of cancers in the HIV-1/AIDS population are infection related and are likely to become increasingly important complications of long-term HIV-1 infection (Grulich et al. 2007; Silverberg et al. 2009). However, evidence is emerging that HIV-1 viral load and direct oncogenic effects of HIV-1 contribute to the increased cancer risk in the HIV-1/AIDS population (Borges et al. 2014). Evidence for a direct oncogenic effect of HIV-1 includes studies that showed cumulative and/or current plasma HIV-1 RNA levels were independently associated with an increased risk of AIDS-defining malignancies or that HIV-1 Tat and Vpr proteins might have oncogenic effects via synergism with other oncogenic viruses through disruption of cell-cycle regulation, inhibition of tumor suppressor genes, promotion of chromosome instability, inhibition of DNA repair, and by promoting effects of exogenous carcinogens (Borges et al. 2014; Bruyand et al. 2009; Guiguet et al. 2009).

This section briefly reviews the experimental evidence for possible modes of action for AIDS-defining and non-AIDS-defining malignancies and the evidence for a causal association between HIV-1 and cancer.

### 4.2.1 AIDS-defining Malignancies

All three of the AIDS-defining malignancies are infection related with clear links to HIV-1-induced immunosuppression, especially for Kaposi sarcoma and non-Hodgkin lymphoma (Pinzone et al. 2015; Shiels et al. 2011a). However, immunosuppression is not the only factor because the risk of these cancers remains elevated even after HAART therapy.

#### Kaposi Sarcoma

These data strongly support HIV-1-induced immunosuppression and co-infection with Kaposi sarcoma-associated herpesevirus as the primary modes of action for Kaposi sarcoma (see also monograph for Kaposi sarcoma-associated herpesvirus). The primary evidence that HIV-1 is indirectly linked to Kaposi sarcoma is that the risk of developing Kaposi sarcoma is higher in people co-infected with HIV-1 and Kaposi sarcoma-associated herpesvirus compared to individuals infected with Kaposi sarcoma-associated herpesvirus only (see Section 3.2.3 and the monograph for Kaposi sarcoma-associated herpesvirus). Studies also show that HIV-1 and Kaposi sarcoma virus can enhance each other’s replication and that the HIV-1 Tat protein enhances Kaposi sarcoma virus entry into endothelial cells (IARC 2012a). Within the HIV-1-infected/AIDS population, many studies have shown that Kaposi sarcoma incidence has decreased in the post-HAART era; it increases with decreasing CD4+ cell count and increasing HIV-1 viral load (see Section 3). In addition, studies reporting CD4 and/or HIV-1 RNA levels in populations receiving HAART indicate that the decline in risk appears to be correlated with improvements in CD4 counts or decreases in viral titer (Castilho et al. 2015; Hleyhel et al. 2013; Patel et al. 2014). Further, chronic immunosuppressive therapy is associated with an increased risk of developing Kaposi sarcoma in organ transplant recipients (Engels et al. 2011).

HAART therapy may reduce the incidence of Kaposi sarcoma indirectly through improved immune surveillance, or directly by inhibiting tumor development (Sgadari et al. 2003; Silverberg and Abrams 2007). For example, protease inhibitors used in HAART inhibit Kaposi sarcoma-associated herpesevirus replication and possess anti-angiogenic and other anti-tumor properties that can impair growth and persistence of Kaposi sarcoma (Gantt and Casper 2011; Gantt et al. 2014). Although antiviral therapy initially resulted in a rapid and substantial reduction in the incidence rate and number of Kaposi sarcoma cases, they remain significantly elevated above the general population rate and are no longer declining (IARC 2012a; Shiels et al. 2011b).

#### Non-Hodgkin Lymphoma

Non-Hodgkin lymphoma risk is increased in immunosuppressed populations and has been recognized as an AIDS-defining clinical condition since 1985 (IARC 2012a). As with Kaposi sarcoma, the primary evidence that HIV-1 is an indirect causal factor of non-Hodgkin lymphoma is the increased incidence of this disease in the HIV-1/AIDS population. Most cases of non-Hodgkin lymphoma are of the B-cell phenotype and are frequently associated with Epstein-Barr virus infection (IARC 2012a).

HIV-1 contributes to lymphomagenesis through two indirect mechanisms: (1) impaired immunosurveillance and loss of immunoregulatory control against Epstein-Barr virus and (2) promotion of chronic B-cell activation due to HIV-1-mediated immune dysfunction (Petrara et al. 2013). Chronic B-cell activation is a well-documented indirect consequence of HIV-1 infection that is driven by abnormal production of B-cell stimulatory cytokines (e.g., IL-6, IL-10, IFN-α, and TNF), miR-21, and chronic antigenic stimulation (Gloghini et al. 2013; Petrara et al. 2013; Sekar et al. 2014). Several studies have shown that certain B-cell stimulatory cytokines and other markers of immune activation (e.g., CXCL13, C-reactive protein, soluble CD23, CD27, and CD30) are elevated several years before the diagnosis of systemic AIDS-associated non-Hodgkin lymphoma (Hussain et al. 2013; Sekar et al. 2014).

In addition to indirect mechanisms, there is growing evidence that HIV-1 virions can contribute to B-cell activation and malignant transformation via direct interaction with B cells (Gloghini et al. 2013). The potential relevance of HIV virions in the development of AIDS-associated non-Hodgkin lymphoma is supported by evidence showing that the cumulative duration of HIV-1 viremia is predictive of lymphoma development (Zoufaly et al. 2009). HIV-1 Tat expression in lymphoid tissue of transgenic mice induced B-cell lymphoma and production of lymphoma-associated cytokines (Kundu et al. 1999). HIV-1 envelope glycoprotein gp120 activates B cells and induces class switch combinations via up-regulation of activation-induced cytidine deaminase (AID) (Epeldegui et al. 2010; He et al. 2006). AID is a DNA-modifying enzyme that is normally expressed exclusively in germinal center B cells and is believed to play a central role in the development of B-cell non-Hodgkin lymphoma via immunoglobulin heavy chain gene (IgH) class switch recombination and somatic hypermutation (Epeldegui et al. 2007; Epeldegui et al. 2010). CD40 ligand (CD40L or CD154), an immune stimulatory molecule expressed by activated T cells, is also incorporated into HIV-1 virions and stimulates B cells via the interaction of CD40L with CD40 resulting in expression of the AID gene, elevated cytokine secretion, as well as CD71 (a marker of cellular activation) and CD10 (a marker for immature germinal center B cells) (Epeldegui et al. 2010). Thus, AID-expressing B cells have an activated germinal center phenotype and HIV virions can induce AID expression in B cells by direct CD40L:CD40 stimulation without the requirement for infection. AID also increases the frequency of the c-myc:IgH translocation via errors in class switch recombination (a hallmark of Burkitt lymphoma) and induces DNA double-strand breaks in Ig genes and other loci, thus, leading to genomic instability (Epeldegui et al. 2007; Epeldegui et al. 2010). Thus AID over-expression results from chronic B-cell hyperactivation associated with HIV-1 infection and/or direct induction by HIV-1 virions (Epeldegui et al. 2010; He et al. 2006). AID expression in peripheral blood mononuclear cells was markedly elevated in subjects who later developed AIDS-non-Hodgkin lymphoma compared to AIDS and HIV-1-negative controls (Epeldegui et al. 2007). AID expression also differs according to non-Hodgkin lymphoma subtype (see Section 3.3.4 for discussion of subtypes). The highest levels were measured in those who developed Burkitt lymphoma while AID over-expression was not seen in subjects who developed central nervous system (CNS) lymphoma.

As discussed in Section 3.3.4, several subtypes of non-Hodgkin lymphoma have been strongly associated with HIV-1/AIDS. These include primary brain lymphoma, large-cell immunoblastic lymphoma, and Burkitt lymphoma (Eltom et al. 2002; Engels 2007; Gloghini et al. 2013). Incidences of primary brain lymphoma and diffuse large B-cell immunoblastic lymphoma show a strong correlation with the severity of immune deficiency and are rarely seen when CD4+ cell counts are maintained at relatively normal levels (IARC 2012a). In contrast, Burkitt lymphoma can occur at any level of immune deficiency. Epstein-Barr virus is present in virtually all AIDS-related cases of primary brain lymphoma, 40% of large B-cell lymphoma cases, and 30% of Burkitt lymphoma cases. In people with HIV-1, Epstein-Barr viral loads are increased from the early stages of HIV-1 infection (Piriou et al. 2004). Fan et al. (2005) reported that high plasma Epstein-Barr viral load was found in people with Epstein-Barr virus-positive but not Epstein-Barr virus-negative AIDS lymphoma, and viral loads fell with successful therapy.

The relationships between AIDS-defining cancers and CD4+ cell counts and/or HIV-1 RNA levels in populations receiving HAART are shown by both the apparent correlation between the decline in non-Hodgkin lymphoma and improvements in CD4+ counts or decreases in viral titer (Castilho et al. 2015; Hleyhel et al. 2013) or by the increasing risk of non-Hodgkin lymphoma as the CD4+ cell count falls and viral replication rises (Clifford and Franceschi 2009; Guiguet et al. 2009; Silverberg and Abrams 2007; Silverberg et al. 2011). However, response to HAART differs among the lymphoma subtypes (Epeldegui et al. 2007). (See Section 3.3 for a discussion of cancer risk related to HAART). Mechanistic differences may partially explain the variable responses of the non-Hodgkin lymphoma subtypes to HAART. Virtually all CNS lymphomas are Epstein-Barr virus positive, have a low frequency of c-myc:IgH translocations, occur in people with low levels of CD4+ T cells, and are associated with the loss of immunoregulatory control of Epstein-Barr virus-infected B cells (Martínez-Maza and Breen 2002). However, less than half of AIDS-associated Burkitt lymphoma cases are EBV positive, are not correlated with CD4 cell counts, and are characterized by chronic B-cell hyperactivation and c-myc:IgH translocations. These data support HIV-1-induced immunosuppression, co-infection with Epstein-Barr virus, and chronic B-cell activation as likely modes of action contributing to non-Hodgkin lymphoma in the HIV-positive population (also see monograph for Epstein-Barr virus).

#### Cervical Cancer

Cervical cancer was recognized as an AIDS-defining cancer in 1993 and HIV is an indirect causal factor; the principal risk factor for cervical cancer is human papillomavirus. HIV-1 and human papillomavirus are both sexually transmitted; therefore, co-infection is common and HIV-1 increases the probability that human papillomavirus infection will persist and induce cervical cancer (Clifford and Franceschi 2009; IARC 2012a). Prior human papillomavirus infection may also increase the probability of HIV-1 infection (see review by (Einstein and Phaëton 2010)).

The relationship of cervical cancer with HIV-1-related immunosuppression is difficult to establish because the associations with HAART and CD4+ levels are unclear and may depend on the time period when CD4+ was measured (Clifford and Franceschi 2009, see Section 3.5.1). Several studies have reported that the overall risk for in situ cervical cancer is significantly increased in AIDS patients. Frisch et al. (2000) reported that relative risk for in situ cervical cancer increased during a 10-year period spanning AIDS onset (5 years before and 5 years after the date of AIDS onset), which suggests that advancing immunosuppression may lead to gradual loss of control over human papillomavirus-related infection. It is uncertain if other risk factors for cervical cancer (e.g., iatrogenic immune suppression, autoimmune disease, end-stage renal disease, chronic inflammation, oral contraceptive use, smoking, poor diet) interact with HIV-1 infection to increase cancer risk (Dugué et al. 2013; Fernandes et al. 2015).

Although immunosuppression is important, it is not an essential factor in the development of cervical cancer (Clarke and Chetty 2002; Dugué et al. 2013). The data suggest that HIV-1 alters the natural history of human papillomavirus, resulting in decreased regression rates and rapid progression to high-grade lesions and an aggressive phenotype (Clarke and Chetty 2002). The more aggressive behavior of HIV-1-positive cervical cancers has been attributed to progression through the microsatellite instability pathway rather than through loss of heterozygosity associated with HIV-1-negative cervical cancer. Further, HIV-1 proteins are thought to enhance the effectiveness of human papillomavirus proteins and may contribute to cell-cycle disruption. Advanced stages of HIV-1 infection correlate with cumulative human papillomavirus prevalence and increased rates of progression of cervical disease (see e.g. Abraham et al. 2013; Chaturvedi et al. 2009; Singh et al. 2009).

### 4.2.2 Non-AIDS-defining Malignancies

Due to improvements in HIV-1 therapy that have prolonged survival and decreased the incidences of AIDS-defining malignancies, non-AIDS-defining malignancies represent a growing fraction of the overall cancer burden in HIV-1-positive people (Engels 2009; Kesselring et al. 2011; Reekie et al. 2010; Shiels et al. 2009). However, the evidence is limited for specific modes of action by which HIV-1 infection causes these malignancies. HIV-1-induced immunodeficiency is likely a key mode of action as evidenced by the fact that many of the non-AIDS-defining malignancies are infection related. Furthermore, the short-term risk of infection-related non-AIDS malignancies is strongly associated with current CD4 cell count (Achhra et al. 2014; Kesselring et al. 2011). In particular, three of the most prevalent non-AIDS-defining cancers are associated with oncogenic viruses: Hodgkin lymphoma (Epstein-Barr virus), anogenital and oral-related cancer (human papillomavirus), and liver cancer (hepatitis B and hepatitis C viruses) (Engels 2009). Risks for these cancers are also elevated among organ transplant patients and provides further support for immunosuppression in their etiology (Grulich et al. 2007).

It is also likely that the HIV-1-positive population is disproportionately infected with oncogenic viruses. Although no data suggest that non-AIDS-defining malignancies are pathologically distinct from their counterparts observed in the general population, they tend to occur at twice the rate in the HIV-1-positive population (Shiels et al. 2009; Vaccher et al. 2014). HIV-1 infection also activates biomarkers of inflammation (IL-6, C-reactive protein) and coagulation (D-dimer) that are associated with an increased risk of both infection-related and infection-unrelated cancer (Borges et al. 2013; Neuhaus et al. 2010). Plasma levels of these biomarkers remained elevated even after HIV-1 RNA levels were suppressed with antiretroviral therapy. The strongest association was found for plasma levels of IL-6. Chronic inflammation as well as HIV-1-specific and generalized responses to infection contribute to chronic and aberrant activation of the immune system and are key driving forces in the loss of CD4+ cells, progression to AIDS, and other complications including cancer (Ipp and Zemlin 2013; Ipp et al. 2014). Thus, the increased incidence in HIV-1-positive individuals could reflect an independent effect of HIV-1 on progression of cancer or a biological interaction of HIV-1 with the known risk factors (Engels 2009). This section reviews mechanistic data for the following non-AIDS-defining malignancies: Hodgkin lymphoma, lung cancer, anogenital and oral-related cancer, liver cancer, and non-melanoma skin cancers.

#### Hodgkin Lymphoma

Several lines of evidence (e.g., excess risk in patients with congenital immunodeficiencies or iatrogenic immunosuppression, and spontaneous remission in some patients when immunosuppressive therapy was discontinued) indicate that the excess risk of Hodgkin lymphoma among HIV-1/AIDS is directly related to immunosuppression. Further, Epstein-Barr virus is more prevalent among Hodgkin lymphoma cases that are HIV-1 positive compared with those that are HIV-1 negative and suggests that loss of immune control of latent Epstein-Barr virus infection is the underlying mode of action (IARC 1997; 2012b). Most Hodgkin lymphoma cases in HIV-1/AIDS patients are strongly associated with Epstein-Barr virus (i.e., mixed cellularity or lymphocyte-depleted forms) while the nodular sclerosis form predominates in the general population (Clifford and Franceschi 2009).

Biggar et al. (2006) analyzed Hodgkin lymphoma incidence rates in relation to CD4+ counts and found some evidence that incidence was lower with severe immunosuppression than with moderate immunosuppression. These data suggest that the association between CD4+ count at the time of AIDS onset and Hodgkin lymphoma risk has an “inverted U” shape (i.e., risk increased with a decline in CD4+ count to 225 to 249 cells/mm^3^ but then risk declines as the CD4+ count declines further). Thus, a possible explanation for the increase in Hodgkin lymphoma risk since the advent of HAART therapy (see Section 3.4) is that treatment of severely immunodeficient cases could raise CD4+ counts to a level that puts them at greatest risk of developing Hodgkin lymphoma (immune reconstitution syndrome). However, more recent studies that looked at CD4+ count as a predictor of Hodgkin lymphoma risk reported no evidence that Hodgkin lymphoma incidence decreased at CD4+ counts less than 200 cells/mm^3^ or that risk was increased in the setting of improved immunity (Clifford and Franceschi 2009; Fontas et al. 2009; Reekie et al. 2010). These studies reported increased risk with declining CD4+ count; however, the differences were not significant in another study (Clifford and Franceschi 2009). Thus, the relationship between Hodgkin lymphoma risk and the degree of HIV-1-related immunodeficiency is perhaps more complex and not as strong as observed for Kaposi sarcoma or non-Hodgkin lymphoma.

#### Lung Cancer

Lung cancer is the most common non-AIDS-defining malignancy in the HIV-1-positive population in developed countries with an elevated risk of all major lung cancer subtypes (i.e., adenocarcinoma, squamous-cell carcinoma, and small-cell carcinoma) although adenocarcinoma is the most common (Engels 2009; Kirk et al. 2007; Ruiz 2010). The role of HIV-1 viral load and immunodeficiency in lung cancer is uncertain. Neither viral load nor CD4+ cell count was strongly associated with lung cancer risk in some studies (Chaturvedi et al. 2007; Engels et al. 2006b; Engels 2009; Kirk et al. 2007; Ruiz 2010), while other studies reported an inverse relationship of CD4+ count and lung cancer incidence (Guiguet et al. 2009; Reekie et al. 2010; Silverberg et al. 2011). Even with HAART treatment, HIV-1 still increases inflammatory mediators, deregulates cell proliferation and apoptosis, and induces oxidative stress in the lung (Almodovar 2014) and the increased risk of lung cancer has not decreased substantially with HAART (Clifford et al. 2005; Engels et al. 2006b; Engels 2009; Kirk et al. 2007). Two potential HIV-1-related immunologic mechanisms associated with lung cancer risk include repeated lung infections and chronic pulmonary inflammation (Engels et al. 2008; Ruiz 2010). The pro-tumorigenic function of several proinflammatory cytokines (e.g., TNFα, IL-6, IL-8) as regulators of tumor-associated inflammation are well established (Grivennikov and Karin 2011; Pine et al. 2011).

The HIV-1-infected population is prone to respiratory infections that could increase the risk of lung cancer (Almodovar 2014). Other potential mechanisms have been suggested; however, experimental support is limited for all of them. These include interaction of the effects of HIV-1 (e.g., expansion of the pool of alveolar macrophages, abnormally high levels of proinflammatory cytokines, and chronic inflammation of lower respiratory tract) with tobacco use; lower levels of antioxidants in HIV-1-positive individuals; or amplification of the effects of other infectious agents (Engels et al. 2006b). There is limited experimental evidence that HIV-1 tat gene product can modulate growth-related genes in human lung epithelial cells; although, amplification of HIV-1 sequences in lung carcinoma tissues has not been demonstrated (el-Solh et al. 1997; Kirk et al. 2007; Wistuba et al. 1998). However, Wistuba et al. (1998) reported that microsatellite alterations were significantly increased in HIV-1-associated lung carcinomas compared to lung carcinomas in HIV-1-indeterminate subjects and reflected widespread genomic instability.

#### Anogenital and Oral-Related Cancers

The primary cause of anal cancer is persistent infection with oncogenic subtypes of human papillomavirus; however, the role of HIV-1-related immunosuppression in promoting anal cancer development has been more difficult to establish. Overall, the risk of invasive anal cancer appears to be increasing in the post-HAART era (see Section 3.5.2).

The risks of anal intraepithelial neoplasia and anal cancer increase with decreasing CD4+ count among HIV-1-positive individuals (Chaturvedi et al. (2009); Hessol et al. (2009); also see reviews by Pernot et al. (2014); Tong et al. (2014); Zaleski and Turiansky (2010)). It is possible that as HIV-1-induced immunosuppression progresses (as measured by lower CD4+ cell counts), attenuation of human papillomavirus-specific immunity results in the development of anal intraepithelial neoplasia I followed by a sustained high-level expression of human papillomavirus proteins and genomic instability. Consequently, genomic instability could be the driving force toward progression of anal intraepithelial neoplasia I lesions to anal intraepithelial neoplasia II, anal intraepithelial neoplasia III, and finally to cancer. HAART therapy would not be expected to affect the natural history of anal intraepithelial neoplasia II or anal intraepithelial neoplasia III. In support of this model, Frisch et al. (2000) reported that the overall risk for in situ anogenital cancer was significantly increased in AIDS patients and the relative risk increased during a 10-year period spanning AIDS onset (5 years before and 5 years after the date of AIDS onset). (A similar pattern was observed for in situ cervical cancer). The overall risk for invasive anogenital cancers was also significantly elevated in AIDS patients; however, the risk changed little during the 10 years spanning AIDS onset. Increasing relative risk for in situ cancers spanning the time of AIDS onset suggests that advancing immunosuppression leads to gradual loss of control over human papillomavirus infection while the lack of a similar increase for invasive human papillomavirus-associated cancer suggests that late-stage cancer invasion is not greatly influenced by immune status. In addition, Meys et al. (2010) proposed that persistent or emergent human papillomavirus disease in the HIV-1-positive population might represent persistent or modulated immunodysregulation after HAART and could be a form of immune reconstitution-associated disease or immune restoration inflammatory syndrome.

A high percentage of HIV-1-infected infected individuals are co-infected with human papillomavirus and have an increased risk of developing many human papillomavirus-associated cancers, including oral-related cancers (Gillison 2009; Park et al. 2016). Molecular and epidemiological data show that cancers that arise from the lingual and palatine tonsils within the oropharynx show the strongest association with human papillomavirus. HIV-1 appears to affect the natural history of human papillomavirus infection by increasing the risk of both incident infection and prevalent infection compared to HIV-1-negative individuals (Beachler et al. 2012; Beachler et al. 2015). HIV-1 Tat and gp120 proteins have been reported to disrupt the tight junction in the oral-related mucosa and may facilitate human papillomavirus infection. Further, as noted above for cervical cancer, some HIV-1 proteins (e.g., Tat, rev) are thought to enhance the effectiveness of human papillomavirus proteins (e.g., E6, E7) and may contribute to cell-cycle disruption and a more aggressive phenotype (Clarke and Chetty 2002).

Although the effects of immunosuppression on the risk of oral-related cancers is not completely understood, the available data suggest that immunosuppression contributes to increased persistence or progression of oral human papillomavirus infection (Beachler et al. 2012). Oral-related cancers are elevated among chronically immunosuppressed populations including HIV-1-infected individuals and solid organ transplant patients (Beachler and DʼSouza 2013; Giagkou et al. 2016); however, some studies report higher risk with lower CD4 counts or higher HIV-1 viral load (Beachler et al. 2015; Engels et al. 2008; Silverberg et al. 2011) while others do not (Chaturvedi et al. 2009; Clifford et al. 2005). The role of HAART on the risk of oral-related cancer has also been inconsistent, with some studies reporting no differences and others reporting modest decreases in risk; however, many of these results are prone to confounding by indication since those receiving HAART are likely to be more immunosuppressed, although the recent practice in high income countries is to provide HAART to those with higher CD4 cell counts (Beachler et al. 2014).

#### Liver Cancer

The role of HIV-1-associated immunosuppression in liver cancer is not well understood but immunosuppression is likely an important factor modulating the hepatotropic virus driven progression of liver disease, including cancer (Mallet et al. 2011). Hepatocellular carcinoma and other liver diseases are among the primary causes of non-AIDS-related death in people infected with HIV-1, and there is significantly elevated risk of severe liver disease in persons who are co-infected with HIV-1 and hepatitis C virus compared to persons infected with hepatitis C virus alone (Graham et al. 2001; Mallet et al. 2011). In addition, the course of hepatitis C virus infection is more aggressive, the prognosis is poorer, and the efficacy of antiviral therapy is reduced in HIV-1-positive compared to HIV-1 negative populations (Gelu-Simeon et al. 2014; Nunnari et al. 2012; Sahasrabuddhe et al. 2012). HIV-1/hepatitis C virus-co-infected people have very weak CD4 and CD8 responses, and even after the CD4+ cell count recoveries following HAART, these responses are not restored (Gelu-Simeon et al. 2014). The role of HAART on hepatocellular carcinoma risk has not been clearly established with most studies reporting a slightly higher incidence in the HAART era (see Section 3.6.3). Although HAART therapy would be expected to improve immune control of hepatitis B virus or hepatitis C virus infection, the increase in liver cancer may be at least partially explained because increased survival of HIV-1-infected individuals also prolongs the duration of chronic liver disease (Sahasrabuddhe et al. 2012). Although hepatitis C virus or hepatitis B virus co-infection is common within the HIV-infected population, and is highly prevalent among people that acquired HIV-1 through blood transfusions or injection drug use (see Section 3.6.4), it is unclear whether HIV-1 infection directly increases the likelihood of hepatocellular carcinoma in viral hepatitis (Nunnari et al. 2012).

In addition to immunosuppression, other general mechanisms include increased inflammation and fibrosis in the liver of HIV-1/hepatitis C virus-co-infected compared to hepatitis C virus-monoinfected people (Gelu-Simeon et al. 2014). One mechanism contributing to increased inflammation is the accumulation of cytotoxic CD8+ T cells in the liver. There is also some evidence that the HIV-1 viral proteins Tat and gp120 may play a role via promotion of type I collagen and proinflammatory cytokines that activate hepatic stellate cells and promote fibrosis (Gelu-Simeon et al. 2014; Nunnari et al. 2012). Other risk factors for chronic liver disease and liver cancer that are more common among HIV-1-infected populations than the general population include excessive alcohol consumption, obesity, diabetes, and non-alcoholic steatohepatitis (Sahasrabuddhe et al. 2012).

HAART is also known to have some direct hepatotoxic effects, which are amplified among HIV-1-positive patients chronically infected with hepatitis B or C virus (Sulkowski et al. 2000). Lipodystrophy syndrome, which is associated with certain HAART regimens, may be accompanied by insulin resistance, increasing the risk for nonalcoholic steatohepatitis and, consequently, for cirrhosis and hepatocellular carcinoma (Bongiovanni and Tordato 2007; Feeney and Mallon 2011; Joshi et al. 2011).

#### Non-melanoma Skin Cancers

Although many cancer registries do not include detail on non-melanoma skin cancer subtypes, the available data indicate that HIV-1-positive individuals have an increased risk of all subtypes of non-melanoma skin cancer. Some data suggest that immunosuppression may alter the phenotype of non-melanoma skin cancer to a more aggressive squamous-cell skin cancer (Engels 2009). HIV-1-induced immunodeficiency could possibly increase the risk for basal-cell and squamous-cell carcinoma by reduced immunosurveillance for malignant cells.

Merkel cell carcinoma is primarily attributed to Merkel cell polyomavirus and HIV-1-induced immunodeficiency increases the risk (see Merkel cell polyomavirus monograph at https://ntp.niehs.nih.gov/go/797227).

#### Conjunctival Cancers

Mechanisms for HIV-1-induced conjunctival cancers in combination with solar ultraviolet radiation are not completely understood.

### 4.2.3 Synthesis

Although the mechanisms for HIV-1-induced cancer are not completely understood, most AIDS-defining and non-AIDS-defining malignancies have a known infectious cause and are similar to the patterns observed in immunosuppressed transplant recipients. Therefore, the data support an indirect mechanistic link between HIV-1 infection and cancer (i.e., failure to suppress infection by oncogenic viruses and/or impaired immune surveillance of transformed cells). However, there is increasing evidence that direct oncogenic effects of HIV-1 may contribute to the increased cancer risk in the HIV-1/AIDS population. While it is clear that HIV integration can lead to clonal expansion and persistence of HIV-1-infected cells, its relationship to cancer is unclear and warrants further investigation.

The primary causes of the three AIDS-defining malignancies (Kaposi sarcoma, non-Hodgkin lymphoma, and invasive cervical carcinoma) are co-infection with the oncogenic viruses: Kaposi sarcoma-associated virus, Epstein-Barr virus, and oncogenic subtypes of human papillomavirus. Overall, the data support a mechanism in which an HIV-1-impaired immune system cannot adequately suppress or clear oncogenic viruses, resulting in an increased risk of infection-related cancer. Although HAART has dramatically decreased the incidences of Kaposi sarcoma and non-Hodgkin lymphoma, these malignancies remain elevated in the HIV-1-positive population. While the incidence rates of cervical cancer in AIDS patients in the United States have declined, the number of cases has continued to increase (due primarily to an increased number of women in the AIDS population) with little evidence that HAART decreases the risk. Thus, it is clear that immunosuppression alone does not completely explain the incidence and spectrum of tumors observed in the HIV-1-positive populations pre- and post-HAART. In addition to an indirect effect of HIV-1 on cancer incidence through immune dysregulation, chronic B-cell activation, and activated inflammatory pathways, HAART toxicity may play a role in the increased risk.

Although non-AIDS-defining malignancies include a broad spectrum of infection-related and infection-unrelated cancers, Hodgkin lymphoma, lung, anogenital, and liver cancers account for about half of the non-AIDS-defining cancers reported in the United States. In addition to these cancers, risk factors and mechanistic data for non-melanoma skin cancer and oral-related cancers were also reviewed. In contrast to AIDS-defining malignancies, non-AIDS-defining malignancies have increased in the post-HAART era and are largely attributed to growth and aging of the HIV-1-positive population. Immunodeficiency, inflammation, co-infections with oncogenic viruses (e.g., Epstein-Barr virus, hepatitis B virus, hepatitis C virus, and human papillomavirus), and traditional risk factors (e.g., smoking, alcohol abuse, and age) play a primary role or contribute to the excess of non-AIDS-defining malignancies.