# 3 Human Cancer Studies

## Introduction

Infection with HIV-1 is associated with the death of T cells (CD-4) and severe immune suppression, which after several years in untreated individuals typically progresses to acquired immunodeficiency syndrome (AIDS), a range of immune-related opportunistic infections and related diseases (CDC 1985; CDC 1992). In addition, association of HIV-1 infection with a number of cancer endpoints, mostly those associated with co-infection with other viruses, have been investigated. The advent of highly active antiretroviral therapies (HAART) (usually defined as prescription of at least three antiretroviral drugs, including a protease inhibitor or a non-nucleoside reverse transcriptase inhibitor) has resulted in reductions in HIV-1 viral load and partial to complete recovery of immune function in treated patients.

The NTP used the body of knowledge published on HIV-1 in the IARC (1996; 2012a) monographs (which included studies published up to 2008) as the resource as well as any key cohort studies published after 2008 to develop its cancer assessment, which is made independently of IARC’s conclusions. Key studies were those cohort studies that provide new information. Where available, IARC data tables of the effect estimates have informed the cancer hazard assessment, with links to these tables made available in the text.

The NTP focused on those cancer sites evaluated in the IARC monographs. Many of the cancers—Kaposi sarcoma, non-Hodgkin lymphoma, Hodgkin lymphoma, cervical cancer, conjunctival cancer, and anal cancer—have relatively large databases, thus, NTP primarily used the studies included in the IARC monograph for its assessment, supplementing with any new information on key issues and briefly noting whether the recent studies are consistent with the studies reviewed by IARC. For other cancer sites, for which IARC identified weaknesses in the database, including genital, lip, head and neck, liver, lung, and non-melanoma skin cancers, NTP provided a more comprehensive review update of cohort studies or cancer site-specific studies published since 2008.

In the cohort and case-control studies reviewed below, HIV-1 exposure is detected primarily via serological measures and/or measures of HIV-1 RNA according to standard case definition guidelines developed by bodies such as the Centers for Disease Control (CDC) and UNAIDS for surveillance of HIV-1. These guidelines have generally been adopted worldwide (with some variations for resource-poor countries), which may rely primarily on serological rather than RNA-based detection methods. (See Section 1 for more details on HIV-1 detection methods.) AIDS is defined as a spectrum of one or more diseases specified in case definition guidelines developed by the CDC and other bodies (CDC 2014c; CDC 2015b).

The evaluation of the human cancer hazard associated with HIV-1 is divided into five parts. First, a summary of the approach for selection of the studies is provided (Section 3.1). Next, the cancer hazard evaluation for each of the 11 cancer endpoint is presented (Sections 3.2 to 3.7,), cancer burden from all cancer is discussed in Section 3.8, followed by the potential carcinogenicity of HAART and treatments for opportunistic infections (Section 3.9). An integration and summary of the evidence across HIV-1-related cancer endpoints are provided in Section 3.10.

## 3.1 Selection of the Relevant Literature

A literature search of major databases, citations, and other authoritative sources for literature from 2009 through August 2015 was conducted. The literature search strategy (including the databases and search terms, and other sources for identifying literature) and procedures for selecting the literature (systematic screening procedures and inclusion/exclusion criteria) are described in Appendix A.

For the evaluation of the cancer endpoints identified above, the initial search strategy was restricted to review articles identified from 2009 on, and new epidemiological studies on specific cancer sites identified in these reviews were obtained. Since most of the key cohort studies in the IARC review evaluating HIV-1 infection and cancer were published in 2008 and before, primary literature for cohort studies and meta-analyses published from 2009 to August 2015 was also identified and screened. Based on this search, 21 cohorts or record-linkage studies that reported risk estimates for at least three cancer sites were identified (summarized in Table 3-1, below), as well as additional studies focusing specifically on individual cancers. For Kaposi sarcoma, non-Hodgkin lymphoma, Hodgkin lymphoma, cervical cancer, conjunctival cancer, and anal cancer, the newly identified studies were reviewed for consistency with findings reported in IARC. Summary tables for these endpoints report only relative risks from studies included in the IARC tables (see below for links to specific IARC tables), and do not include relative risks from the newer studies. For non-melanoma skin cancer, oral-related cancers, and cancers of the vagina, penis, liver, and lung summary tables were constructed based on the totality of the literature from IARC together with the most recently identified cohorts.

Table 3-1 HIV-1/AIDS Cohorts 2009–2015 Reporting SIR/RR on Multiple (≥3) Cancer Endpoints^a^

Reference/ Country | Study Design | # with HIV or AIDS in Cohort | Dates | Cancer Endpoints | Comments
Powles et al. (2009) UK | Prospective cancer registry PWAH | 11,112 | 1983–2007 | HL, anal, liver, lung, head/neck | Incl. HAART comparisons
Silverberg et al. (2011) USA | Prospective cancer registry PWAH | 20,775 | 1996–2008 | KS, NHL, HL, anal, liver, lung, oropharynx | Kaiser enrollees vs. 215,158 HIV-1-negative enrollees
Chaturvedi et al. (2009) USA | Prospective cancer registry PWA | 500,000 | 1990–2002 | cervical, anal, genital | Incl. HAART comparisons
van Leeuwen et al. (2009) Australia | Retrospective cancer registry PWAH | 20,230 | 1982–2004 | KS, NHL, HL, anal, liver, lung, oropharynx | Incl. HAART comparisons
Bedimo et al. (2009) USA | Prospective cohort PWAH | 32,942 | 1997–2004 | KS, NHL, HL, cervical, anal, liver, lung | U.S. Veterans hospital-based vs. 64,996 HIV-1-negative veterans Incl. HAART comparisons
Seaberg et al. (2010) USA | Prospective cancer registry PWAH | 3,505 PWAH MSM | 1984–2007 | KS, NHL, HL, anal, testes, liver, lung, NMSK, oropharynx | Incl. HAART comparisons
Simard et al. (2010) USA | Prospective cancer registry PWA | 263,250 | 1990–2006 | KS, NHL, HL, cervical, anal, genital, liver, lung, oropharynx | Incl. HAART comparisons
Franceschi et al. (2010) Switzerland | Prospective cancer registry PWAH | 9,429 | 1985–2006 | KS, NHL, HL, cervical, anal, testes, liver, lung, NMSK | Incl. HAART comparisons
Vogel et al. (2011) Germany | Prospective cancer registry | 1,476 PWAH | 1996–2009 | KS, NHL, HL, cervical, anal, liver, lung, oropharynx | Incl. HAART comparisons
Zhang et al. (2011) China | Retrospective clinical chart review | 3,554 | 2004–2008 | NHL, cervical, liver, lung | Hospital-based
Simard et al. (2012) USA | U.S. HIV/AIDS Cancer Match Study cancer registry children (0–14 yr) with AIDS | 5,850 | 1980–2007 | KS, NHL, HL, cervical, liver, lung | Subcohort of cohort reported in Simard et al. (2010) Incl. HAART comparisons
Chao et al. (2012) USA | Prospective cancer registry linkage | 12,872 | 1996–2008 | KS, NHL, HL, anal, lung | Subcohort of Kaiser enrollees (see Silverberg et al. 2011); selected endpoints + risk factors
Hleyhel et al. (2013; 2014) France | Prospective cancer registry PWAH | 99,000 84,504 | 1992–2009 1997–2009 | KS, NHL, cervical (2013) HL, anal, liver, lung (2014) | 2013 study incl. HAART comparisons
Albini et al. (2013)/Calabresi et al. (2013) Italy | Retrospective cancer registry PWAH | 5, 090 | 1999–2009 | Albini: testes, lung, NMSK Calabresi: KS, NHL, HL, cervical, anal, genital, liver, lung, NMSK, ororpharynx
Franzetti et al. (2013) Italy | Retrospective cancer registry PWH | 5,924 | 1985–2011 | HL, anal, genital, liver, lung oropharynx
Park et al. (2014) USA | Prospective PWAH VA and SEER cancer registries | 38,123 | 1996–2008 | KS, NHL, HL, cervical, anal, liver, lung, oropharynx | Incl. HAART comparisons
Akarolo-Anthony et al. (2014) Nigeria | Retrospective cancer registry PWAH | 17,826 | 2005–2012 | KS, cervical, anal, liver, NMSK, eye | Cancer registry linkage only from 2009–2012
Chen et al. (2014) Taiwan | Retrospective national insurance database PWAH | 15,269 | 1998–2009 | KS, NHL, HL, cervical, anal, testes, liver, lung, NMSK, oropharynx
Raffetti et al. (2015) Italy | Retrospective PWAH | 16,268 | 1986–2012 | KS, NHL, HL, cervical, anal, genital, liver, lung, oropharynx | Hospital-based Incl. HAART comparisons
Castilho et al. (2015) USA, Brazil | Retrospective PWAH | 2,925 Brazil 3,927 USA | 1998–2010 | KS, NHL, HL, cervical, anal, testes, liver, lung NMSK, oropharynx | Hospital-based Incl. HAART comparisons
Coghill et al. (2015) USA | 6 States in HIV-1/AIDS Cancer Match registry mortality study PWAH | 6,459 HIV-1-positive cancer cases vs. 1,816,461 HIV-1-negative cancer cases | 1996–2010 | HL, cervical, anal, liver, lung, oropharynx

AIDS = acquired immunodeficiency syndrome; HIV-1 = human immunodeficiency virus type 1; HL = Hodgkin lymphoma; KS = Kaposi sarcoma; IRR = incidence rate ratio; HAART = highly active antiretroviral therapy; HL = Hodgkin lymphoma; MSM = men who have sex with men; NHL = non-Hodgkin lymphoma; NMSK = non-melanoma skin cancer; PWA = people with AIDS; PWAH = people with AIDS or HIV; RR = relative risk; SIR = standardized incidence ratio; USA = United States of America.

^a^ Cancer endpoints included in the current review; some studies reported additional endpoints.

^b^ Cohorts M+F unless stated (note that in most cohorts, women were approximately 10% to 25% of the total cohort, except Akarolo-Anthony et al. (2014), where women were 65% of the cohort).

This review also includes cohort studies comparing the incidence of these cancer endpoints in a range of HIV-1-infected populations before and after the advent of widespread use of HAART in the mid- to late 1990s (usually defined as prescription of at least three antiretroviral drugs, including a protease inhibitor or a non-nucleoside reverse transcriptase inhibitor) because these studies can provide evidence to evaluate a causal relationship between HIV-1 infection and cancer risk.

## 3.2 Cancer Hazard Evaluation: Kaposi Sarcoma

Kaposi sarcoma-associated herpesvirus (KSHV) is necessary for the development of Kaposi sarcoma (see monograph on KSHV). Studies evaluating Kaposi sarcoma include cohort and case-control studies of HIV-1-infected or AIDS patients (status of Kaposi sarcoma unknown), cohort and case-control studies of known infection and HIV-1-infected populations that evaluated the effect of HAART on Kaposi sarcoma incidence.

### 3.2.1 Background Information

Kaposi sarcoma occurs in four epidemiological types (Iscovich et al. 2000):

1. Endemic Kaposi sarcoma, which is found mainly in regions of sub-Saharan Africa where the KSHV seroprevalence rate is approximately 25% to 50%
2. Classic Kaposi sarcoma, which occurs among certain southern Mediterranean populations with KSHV seroprevalence rates of 10% to 20%
3. Iatrogenic Kaposi sarcoma, which is observed mainly among organ transplant recipients who have KSHV infection
4. Epidemic or HIV-1/AIDS-related Kaposi sarcoma, which occurs among HIV-1-positive or AIDS populations

In the United States, the incidence of Kaposi sarcoma was 0.23 per 100,000 individuals prior to the HIV-1/AIDS epidemic starting in the early 1980s, peaking at approximately 5 per 100,000 by the early 1990s (and ~125 per 100,000 in San Francisco), prior to the advent of HAART. In the HAART era, the incidence of Kaposi sarcoma incidence has continued a steady decline leveling off at a plateau 0.5 per 100,000 (4.0 per 100,000 in San Francisco) in the United States SEER data 2013.

### 3.2.2 Cohort and Case-control Studies

In small studies from the early 1980s reviewed by IARC (1996), the relative risk of Kaposi sarcoma increased among “never married” men in comparison to the 1970s by between 19 and >5,000 (Bernstein et al. 1989; Biggar et al. 1987; Biggar et al. 1989; Rabkin et al. 1991; Rabkin and Yellin 1994) and risks were correlated with a decrease in CD4 counts (Dore et al. 1996; Lundgren et al. 1995; Muñoz et al. 1993; Veugelers et al. 1995).

IARC (2012a) reviewed a total of 23 HIV-1/AIDS cohort studies including one meta-analysis that reported standardized incidence ratios (SIR) or risk ratios (RR). Twenty-two of the studies were from Europe and the United States and one was from Uganda. The cohorts ranged from approximately 1,600 to 376,000 members and included a total of almost 25,500 cases of Kaposi sarcoma (see IARC 2012a monograph for details of study methods and findings). Findings across these studies that reported risk estimates (SIR or RR) are summarized in Table 3-2. The majority of the cohort studies were cancer registry linkage studies that reported age- and sex-adjusted SIRs. The studies varied in the calendar year in which patients were enrolled, with some studies reporting effect estimates of HIV-1-positive and/or AIDS patients prior to HAART and other studies enrolling patients from both pre- and post-HAART era, and some studies evaluating the impact of HAART on the effect estimate (discussed below). Advantages of the database were the large size of the cohorts and large numbers of exposed cases.

Table 3-2 Summary of HIV-1/AIDS Cohort Studies of Kaposi Sarcoma

| AIDS | HIV-1 Positive^a^ | AIDS or HIV-1 Positive
RR/SIR | 258–72,700^b^ | 192–5,600 ^a^ | 109–3,640 ^c^
Cohort size | 1,659–375,933 | 1,950–54,780 | 2,574–491,048
Number of cases | 6–7,028 | 6–3,267 | 17–5,936
Number of studies | 8 | 8 | 6

Source: IARC (2012a), Table 2.1 and Table 2.2.

^a^ Subjects with Kaposi sarcoma in the cohorts would have AIDS as this cancer is an AIDS-defining disease.

^b^ All lower 95% CI > 1.0.

^b\c^Mbulaiteye et al. (2006) not included as estimates were outliers.

The studies in Europe and the United States found strong and consistent evidence of an association of HIV-1 infection or AIDS and Kaposi sarcoma with very high and statistically significant SIRs ranging from 109 to 72,700, depending in part on the stage of HIV-1 infection (with those developing AIDS generally at higher risk for Kaposi sarcoma) and the calendar period over which cases were identified. Based on studies with a total of 444,000 members and 494 cases, Grulich et al. (2007) reported an age- and sex-adjusted meta-SIR = 3640 over the period 1980 to 2002. A much lower SIR (~6) was found in the only study from Africa (Uganda) (Mbulaiteye et al. 2006) based on 105 cases found among a cohort of HIV-1-positive people or people with AIDS enrolled from 1988 to 2002. However, higher risks (ORs ranged from 47 to 91) were observed for HIV-1 infection and Kaposi sarcoma in two hospital-based case-control studies from Uganda (Newton et al. 2001) and South Africa (Stein et al. 2008); the former study included children (see IARC (2012a), Table 2.3). The risk of Kaposi sarcoma varies considerably with HIV-1 transmission group and is highest among men who have sex with men (IARC 1996; IARC 2012a): for example Beral et al. (1990) reported that among 88,739 AIDS patients in the United States, 13,616 (15%) developed Kaposi sarcoma, ranging from 21% in “homosexual or bisexual” men down to 3% in “heterosexual” men, 3% in transfusion recipients, 2% in intravenous drug users, 1% in hemophiliacs, and 1% in children infected by perinatal transmission. Similar patterns have been found in other countries with epidemic forms of Kaposi sarcoma (Beral et al. 1990).

Findings (most risks ranging from 100 to 1000s) from 16 cohort studies published after the IARC review (Akarolo-Anthony et al. 2014; Bedimo et al. 2009; Calabresi et al. 2013; Castilho et al. 2015; Chao et al. 2012; Chen et al. 2014; Franceschi et al. 2010; Hleyhel et al. 2013; Park et al. 2014; Raffetti et al. 2015; Seaberg et al. 2010; Silverberg et al. 2011; Simard et al. 2010; Simard et al. 2012; van Leeuwen et al. 2009; Vogel et al. 2011) were consistent (data not shown) with the findings from the earlier studies.

The major co-factor for Kaposi sarcoma is Kaposi sarcoma-associated herpesvirus, which is present in all cancer cases. Numerous studies have found strong evidence for an increased risk of Kaposi sarcoma among HIV-1-positive and Kaposi sarcoma-associated herpesvirus-infected populations; relative risks ranged from 1 to 30 for the cohort studies and 1 to 1,683 for the case-control studies (see Tables 3-1 and 3-2 in the Kaposi sarcoma-associated herpesvirus monograph).

### 3.2.3 Relationship with HAART

Calendar-period analyses or prospective cohort analyses, predominantly using cancer-registry linkage study designs of populations compared over pre-HAART (prior to approximately 1996), early HAART (from approximately 1996 to 2002) and established HAART (approximately 2002 and later) periods, can provide indirect evidence of an association between HIV-1 infection rates or titers and changes in Kaposi sarcoma incidence over time. (Note, however, that HAART was not widely available in many resource-poor countries such as southern Africa until the 2000s).

Five cohort studies reported SIRs or relative risks for Kaposi sarcoma decreased sharply over two or three time periods, representing pre-, early, and established HAART periods (Engels et al. 2006a; Franceschi et al. 2010; Hleyhel et al. 2013; Patel et al. 2008; van Leeuwen et al. 2009, see Figure 1) (see Figure 3-1). In addition, 10 studies reported incidence rates and/or differences in relative risks from the pre-/early to late HAART periods. Statistically significant decreases in relative risks were reported, ranging from 0.19 to 0.92 in studies comparing pre- to early HAART periods (Bedimo et al. 2009; Carrieri et al. 2003; Grulich et al. 2001; ICHIVC 2000; Ives et al. 2001) and from 0.11 to 0.2 in more recent studies comparing pre-HAART with early to established HAART periods (Franceschi et al. 2008; Seaberg et al. 2010; Simard et al. 2010). Relative risks also significantly decreased by 70% when comparing post-treatment CD4 levels of <50 cells/μL (RR = 1.0) to CD4 levels of ≥500 cells/μL (RR = 0.3). A number of other cohort studies (Clifford et al. 2005; Franceschi et al. 2008; Mbulaiteye et al. 2003; Serraino et al. 2005; Silverberg et al. 2011) also report dose-response relationships between low CD4 counts and increased risks of Kaposi sarcoma. Silverberg et al. (2011) reported a statistically significant trend between HIV-1 RNA levels and risk of Kaposi sarcoma both between HIV-1-positive and HIV-1-negative groups (P < 0.001) and within HIV-1-positive groups (RR = 3.8, 95% CI = 3.0 to 4.8) for ≥10,000 copies of HIV RNA/mL vs. 1.2 (95% CI = 0.8 to 1.7) for 501 to 9,999 copies/mL.

Figure 3-1

Cohort Studies of Kaposi Sarcoma Incidence in HIV-1/AIDS Populations from Pre-HAART (1980 to 1996) to HAART (1996 and Later) Periods

Overall, these cohort studies indicate rapid and substantial decreases in Kaposi sarcoma incidence rates of up to 90% among HIV-1-positive populations from the pre- or early HAART to the established-HAART period in a number of (mostly U.S. and European) countries. However, incidence rates of Kaposi sarcoma among HIV-1-positive populations remain approximately 20- to 300-fold higher than general population rates, even in the established HAART era (e.g. Hleyhel et al. 2013; Patel et al. 2014; van Leeuwen et al. 2009).

## 3.3 Cancer Hazard Evaluation: Non-Hodgkin Lymphoma

### 3.3.1 Background Information

In the United States, non-Hodgkin lymphoma, consisting of predominantly B-cell subtypes, is relatively common, with an estimated annual incidence rate of 20/100,000 and a 5-year survival rate of 70% (NCI 2015h). Approximately 4% of people with AIDS have NHL at diagnosis and at least the same proportion develop NHL during the course of illness (IARC 1996; Medscape 2016). Among HIV-infected individuals non-Hodgkin lymphoma manifests late in the progression of the infection and is most common in persons with very low CD4 counts.

Three types of aggressive B-cell lymphomas have been evaluated among HIV-1-positive/AIDS populations:

- Primary central nervous system diffuse large B-cell lymphoma (a relatively rare form of non-Hodgkin lymphoma with a current incidence rate of approximately 0.5 per 100,000 in the United States), which appears mainly among severely immunosuppressed people
- Diffuse large B-cell immunoblastic lymphoma, which is also associated with severe immunosuppression (both are uncommon when CD4 levels are close to normal (IARC (2012a)); see also review by Kaplan (2012))
- Burkitt lymphoma, which occurs at various stages of immune deficiency (IARC 1996; 2012a; Kaplan 2012)

In addition, T-cell lymphomas have also been evaluated among HIV-1-positive groups (IARC 2012a), but they constitute less than 5% of all cases of NHL among HIV-1-positive individuals.

### 3.3.2 Cohort and Case-control Studies

An association between HIV-1/AIDS and non-Hodgkin lymphoma incidence was first observed in cancer registry-based descriptive epidemiology studies in populations with high mortality from AIDS (Biggar et al. (1989); Harnly et al. (1988); Kristal et al. (1988); Rabkin and Yellin (1994); Ross et al. (1985), cited in IARC (1996)); these were followed by cancer registry and AIDS registry linkage studies (Coté et al. 1991; Reynolds et al. 1993) reporting 91- to 140-fold increases in non-Hodgkin lymphoma among AIDS patients compared with general population rates. Case series/cohort studies also reported increases in non-Hodgkin lymphoma risk with decreasing CD4 counts (Moore et al. (1991); Muñoz et al. (1993); Pluda et al. (1990); Pluda et al. (1993); Rabkin et al. (1992), cited in IARC (1996)).

IARC (2012a) reviewed 39 cohort studies, 21 of which reported SIRs or RRs, including the meta-analysis by Grulich et al. (2007) and 6 case-control studies, of which 3 reported SIRs or RRs (see IARC monograph for details of study methods and findings). Almost all the cohort studies were conducted in the United States or Europe and were large, involving from approximately 2,500 to over 375,000 people registered with AIDS or HIV-1 infection, and, studies that reported risks included a total of approximately 14,500 cases of non-Hodgkin lymphoma. These studies reported a wide range of SIRs or relative risks of approximately 25 to 3,600 for combined non-Hodgkin lymphoma among AIDS patients and approximately 4 to 79 among HIV-1-positive populations, depending in part on the time period over which the studies were conducted (see Table 3-1, Table 3-3). Overall, most risk estimates were between 10 and 300. One cohort study among a HIV-1-positive Ugandan population (Mbulaiteye et al. 2006) reported a lower, but statistically significant SIR of 3.6 (95% CI = 1.2 to 8.4). Eight case-control studies were reviewed by IARC (2012a), of which three (from Africa) reported risks. Statistically significant odds ratios ranging from approximately 6 to 12 were reported (Mutalima et al. 2008; Newton et al. 2001; Stein et al. 2008). The meta-analysis of over 444,000 HIV-1/AIDS patients in the United States, Europe, and Australia (Grulich et al. 2007) reported an age- and sex-adjusted meta-SIR for non-Hodgkin lymphoma of 76.7 (95% CI = 39.4 to 149, 5,295 cases) over the period 1980 to 2002.

Table 3-3 Summary of HIV-1/AIDS Cohort Studies of Non-Hodgkin Lymphoma

| AIDS | HIV-1 Positive^a^ | AIDS or HIV-1 Positive
RR/SIR | 24.6–3,600 | 3.6–79.4 | 72.8–3,640
Cohort size | 1,659–375,933 | 2,566–57,350 | 2,574–444,172
No. cases | 52–2,852 | 5–675 | 82–3,344
No. of studies | 8 | 8 | 5

Source: IARC (2012a), Table 2.4 and Table 2.5.

All lower 95% CI > 1.0.

^a^ Subjects with non-Hodgkin lymphoma in these cohorts would have AIDS as this cancer is an AIDS-defining disease.

Findings (most risks between 8 and 45 with risks up to 100 for cancers developing in the pre-HAART era) from 16 cohort studies published after the 2008 review (Albini et al. 2013; Bedimo et al. 2009; Castilho et al. 2015; Chao et al. 2012; Chen et al. 2014; Franceschi et al. 2010; Hleyhel et al. 2013; Park et al. 2014; Raffetti et al. 2015; Seaberg et al. 2010; Silverberg et al. 2011; Simard et al. 2010; Simard et al. 2012; van Leeuwen et al. 2009; Vogel et al. 2011; Zhang et al. 2011) were consistent with the findings from the earlier studies (data not shown).

### 3.3.3 Relationship with HAART

Reported SIRs or relative risks for non-Hodgkin lymphoma declined from approximately 134 to 7 among AIDS or combined AIDS/HIV-1 populations (Dal Maso et al. 2009; Engels et al. 2006a; Engels et al. 2008; Franceschi et al. 2010; Galceran et al. 2007; Hleyhel et al. 2013) and from 97 to 6.5 among HIV-1-positive populations (Engels et al. 2008; Patel et al. 2008) from the pre-/early HAART era to the established HAART era (see Figure 3-2, also see review by Engels et al. (2010)).

Figure 3-2

Cohort Studies of Non-Hodgkin Lymphoma Incidence in HIV-1/AIDS Populations from Pre-HAART (1980 to 1996) to HAART (1996 and Later) Periods

Studies reporting changes in relative risks (rather than absolute risk) indicate declines of approximately 30% to 80% from the pre-HAART to early HAART period and from 70% to 80% from the pre-/early HAART to the established HAART era (Bedimo et al. 2009; Bhaskaran et al. 2004; ICHIVC 2000; Seaberg et al. 2010; Simard et al. 2010). AIDS patients appear to have experienced a greater decrease in risk than HIV-1-positive patients.

In two French/Italian studies comparing treated with non-treated groups in the same study population, the relative risk of non-Hodgkin lymphoma was 0.2 among treated vs. untreated patients (Carrieri et al. 2003); similarly, the SIR was approximately half as large (SIR = 35) among treated patients as that among untreated patients (SIR = 72) (Serraino et al. 2007).

In prospective studies reporting on the course of non-Hodgkin lymphoma risk among individual patients, the administration of HAART appears to result in a decrease in risk within months of starting treatment (Kirk et al. 2007; Polesel et al. 2008).

Despite a clear decline in the HAART era, the overall risk of non-Hodgkin lymphoma among people with AIDS and HIV-1 remains on average 10- to 15-fold higher than that of the general population (see e.g. Engels et al. 2008; Franceschi et al. 2010; Hleyhel et al. 2013; Patel et al. 2008; van Leeuwen et al. 2009), and it is now the most common HIV-1/AIDS-related cancer in the United States, partly as a result of declines in other HIV-1-related cancers such as Kaposi sarcoma (Robbins et al. 2015).

### 3.3.4 Non-Hodgkin Lymphoma Subtypes

Primary central nervous system diffuse large B-cell lymphoma occurs several thousand times more frequently in HIV-1-positive populations than in the general population and is associated with severe immunosuppression (Coté et al. 1996; Engels et al. 2006a). Diffuse large B-cell immunoblastic lymphoma is also associated with severe immunosuppression and occurs at several hundred times the general population rate (Engels and Goedert 2005; Engels et al. 2006a). Burkitt lymphoma, as noted above, occurs at varying stages of immunosuppression and at 50 to 100 times the general population rate. As reviewed in the accompanying Kaposi sarcoma-associated herpesvirus monograph, HIV-1 infection is associated with an increased risk of two rare forms of lymphoma, primary effusion lymphoma, and multicentric Castleman disease. Finally, a 15-fold increase in T-cell lymphoma has been identified in HIV-1-positive patients (Biggar et al. 2001).

There is evidence from studies reporting non-Hodgkin lymphoma subtypes that both diffuse large B-cell primary central nervous system lymphoma and diffuse large B-cell immunoblastic lymphoma have declined substantially, but Burkitt lymphoma and low to intermediate grade diffuse large B-cell lymphoma incidence do not appear to have declined (Diamond et al. 2006; IARC 2012a; Kaplan 2012). The ICHIVC (2000) study of almost 48,000 HIV-1-positive people reported decreases of approximately 50% in diffuse B-cell primary central nervous system lymphoma and immunoblastic lymphoma, but no change in Burkitt lymphoma, during the HAART era; a similar pattern was observed in the Swiss HIV-1 cohort (Polesel et al. 2008). Over three periods reflecting pre-HAART era, early-HAART era, and late-HAART era, Engels et al. (2006a) also reported a 30% decline in diffuse large B-cell lymphomas (SIRs of 98, 64, and 30, respectively), with a 43% decline in immunoblastic lymphoma (SIRs of 141, 95, and 60, respectively) and a 20% decline in primary central nervous system lymphoma (SIRs of 5,000, 4,850, and 1,020, respectively), but no decrease in Burkitt lymphoma (SIRs of 57, 53, and 50, respectively).

### 3.3.5 Cofactors

Some specific subtypes of non-Hodgkin lymphoma among HIV-1-positive populations have been associated with Epstein-Barr virus in some but not all cases (see e.g.`, review by (Carbone et al. 2009)). Epstein-Barr virus is found in almost all cases of HIV-1-associated primary central nervous system lymphoma, approximately 40% of cases of large-cell immunoblastic lymphoma, and approximately 30% of cases of Burkitt lymphoma (Gloghini et al. (2013); Grulich et al. (2007); IARC (2012a); Stefan et al. (2011) see also accompanying monograph on Epstein-Barr virus). In addition, increasing Epstein-Barr virus titers have been reported among HIV-1-positive people following HIV-1 infection, with decreases in Epstein-Barr virus titers observed among HIV-1-positive patients successfully treated with HAART (IARC 2012a). Apart from Kaposi sarcoma-associated herpesvirus-related lymphomas (reviewed in the accompanying monograph on Kaposi sarcoma-associated herpesvirus), the risks of which are also increased in HIV-1-positive and Epstein-Barr virus-positive populations, associations of non-Hodgkin lymphoma with other oncoviruses have not been clearly demonstrated (IARC 2012a) and one study found reported hepatitis B virus antibodies in 78% of HIV-1-positive patients with non-Hodgkin lymphoma (Burbelo et al. 2012). Hepatitis B and C infections occur more frequently among HIV-1-positive populations (Nunnari et al. 2012) and are risk factors for non-Hodgkin lymphoma; IARC concluded that there is sufficient evidence for hepatitis C and limited evidence for hepatitis B virus and non-Hodgkin lymphoma from studies in IARC (2012a). However, a role of hepatitis B and C viruses in non-Hodgkin lymphoma risk in the presence of HIV-1 infection has not been elucidated.

Co-infection with human T-cell lymphotropic virus type 1 has been found to be in the range of 5% to 27% in populations highly endemic for human T-cell lymphotropic virus type 1 (Araujo et al. 2002; Dezzutti and Lal 1999). While there are case reports of adult T-cell leukemia/lymphoma in patients infected with both HIV-1 and human T-cell lymphotropic virus type 1, there does not appear to be an increased incidence of adult T-cell leukemia/lymphoma in co-infected persons (Dhasmana and Taylor 2014).

Other risk factors impact non-Hodgkin lymphoma risk, depending on the subtype, including other causes of immune suppression (transplants or specific autoimmune diseases and allergies), as well as some environmental and occupational exposures. Smoking and alcohol consumption, however, are not strongly associated with non-Hodgkin lymphoma risk. Data are insufficient to evaluate whether such factors directly interact with HIV-1 infection to increase risk and/or act as confounders in studies comparing non-Hodgkin lymphoma cancer risk among HIV-1-positive vs. HIV-1-negative populations.

## 3.4 Cancer Hazard Evaluation: Hodgkin Lymphoma

### 3.4.1 Background Information

In the United States, Hodgkin lymphoma occurs relatively infrequently, with an estimated annual incidence rate of 2.7/100,000 and a 5-year survival rate of approximately 86% (NCI 2015f, 2008-2012 data). The age-specific risk for Hodgkin lymphoma is bimodal, with peaks among the young and the elderly and lowest risks among 40- to 59-year-olds (Goedert and Bower 2012). There are four major histological types: nodular sclerosis, mixed cellularity, lymphocyte rich, and lymphocyte depleted.

### 3.4.2 Cohort and Case-control Studies

IARC (1996) described a series of five case series and descriptive studies in which Hodgkin lymphoma was first reported in HIV-1-infected persons, indicating a preponderance of mixed cellularity and lymphocyte depletion as histological subtypes. Early cohort studies reported increases in Hodgkin lymphoma in some AIDS patients (Hessol et al. 1992; Rabkin et al. 1992; Reynolds et al. 1993) but not in all studies (Lyter et al. 1995; Ragni et al. 1993).

IARC (2012a) (see IARC monograph tables for details on study methods and findings) reviewed 23 cohort studies of HIV-1 infection and/or AIDS patients, including a meta-analysis by Grulich et al. (2007), and 1 case-control study of Hodgkin lymphoma conducted in the United States, Europe, and Africa that reported SIRs or RRs, (see IARC monograph for study methods and findings) (Table 3-4). The individual cohort studies were large, with study populations ranging from approximately 1,200 to over 375,000 people with AIDS or HIV-1 infection, and represent approximately 2,280 cases of Hodgkin lymphoma. These studies, conducted in the United States, Europe, and Australia, reported statistically significant increases in risk ranging from approximately 4 to 38 among HIV-1-positive/AIDS patients vs. HIV-1-negative populations. One case-control study was identified; Stein et al. (2008) reported an odds ratio (OR) of 1.6 (95% CI = 1.0 to 2.7) among 30 cases of Hodgkin lymphoma with HIV-1 infection in a South African hospital-based study. Based on 444,172 HIV-1-positive/AIDS patients and 802 cases, Grulich et al. (2007) reported an age- and sex-adjusted meta-SIR = 11.3 (95% CI = 8.4 to 14.4) for the period 1980 to 2002.

Table 3-4 Summary of HIV-1/AIDS Cohort Studies of Hodgkin Lymphoma

| AIDS | HIV-1 Positive | AIDS or HIV-1 Positive
RR/SIR | 7.6–28.4^a^ | 5.6–38^a^ | 3.6–20.7^a^
Cohort size | 1,659–375,933 | 1,255–57,350 | 2,574–444,172
No. cases | 6–173 | 2–38 | 2–802
No. of studies | 7 | 9 | 7

Source: IARC (2012a), Table 2.7 and Table 2.8.

^a^ All lower 95% CI > 1.0 except Allardice et al. (2003).

Findings from 18 cohort studies published after 2008 (Bedimo et al. 2009; Calabresi et al. 2013; Castilho et al. 2015; Chao et al. 2012; Chen et al. 2014; Coghill et al. 2015; Franceschi et al. 2010; Franzetti et al. 2013; Hleyhel et al. 2014; Park et al. 2014; Powles et al. 2009; Raffetti et al. 2015; Seaberg et al. 2010; Silverberg et al. 2011; Simard et al. 2010; Simard et al. 2012; van Leeuwen et al. 2009; Vogel et al. 2011) were consistent with the findings (most risks between 4 and 38) from the earlier studies (data not shown). In addition, Shiels et al. (2009) reported a meta-SIR of 11 (95% CI = 8.8 to 15) based on 643 cases (note that 6 of the total of 13 studies included by Shiels et al. (2009) overlap with those of Grulich et al. (2007), although not all reported data for every cancer endpoint).

There is some variation in the histological type of Hodgkin lymphoma (Biggar et al. 2006; Carbone et al. 2009; Frisch et al. 2001; Mounier et al. 2010; Rapezzi et al. 2001; Serraino et al. 1993). According to a meta-analysis of 17 studies by Rapezzi et al. (2001), the risk for mixed cellularity (RR = 3.2, 95% CI = 2.6 to 3.8) and lymphocyte-depleted subtypes (RR = 6.3, 95% CI = 4.5 to 8.8) is statistically significantly higher in HIV-1-positive patients than in HIV-1-negative populations, whereas lymphocyte predominance and nodular sclerosis types were not statistically significantly different in the two groups. The relative proportions of subtypes may also be altered among HAART-treated populations who develop Hodgkin lymphoma (Carbone et al. 2009).

### 3.4.3 Relationship with HAART

The risk of Hodgkin lymphoma has increased during the HAART era, although part of this increase may be attributable to the aging of surviving HIV-1/AIDS populations. SIRs in the pre-HAART era (up to 1995 to 1996) ranged from 5 to 23; by the later HAART period (approximately 2000 onward), SIRs had generally increased, ranging from 13 to 32 (see Figure 3-3). Relative risks following the advent of HAART ranged from 0.75 to 2.7, depending in part on the periods being compared (Bedimo et al. 2009; Engels et al. 2008; ICHIVC 2000; Seaberg et al. 2010; Simard et al. 2010). In addition, an earlier study by Clifford et al. (2005) reporting on a Swiss HIV-1/AIDS cohort from 1985 to 2005, found a doubling of risk among HAART-treated patients (SIR = 36) vs. those untreated prior to cancer diagnosis (SIR = 11), whereas Bohlius et al. (2011), reporting on a combined cohort of approximately 40,170 HIV-1-positive patients from 16 European cohorts (1998 to 2006), found no difference in risk between HAART and non-HAART-treated patients (hazard ratio = 1.0). Some recent studies of current HAART use and Hodgkin lymphoma risk suggest that the risk might have partly leveled off (see reviews by Carbone et al. 2009; Goedert and Bower 2012; Kaplan 2012). Nevertheless, the risk of Hodgkin lymphoma appears to have remained 5- to 25-fold higher among people with HIV-1/AIDS than in the general population.

Figure 3-3

Cohort Studies of Hodgkin Lymphoma Incidence in HIV-1/AIDS Populations from Pre-HAART (1980 to 1996) to HAART (1996 and Later) Periods

The level of risk was not related to baseline or nadir CD4 levels, but declined significantly with the most recently measured CD4 level [>350 cells/μL vs. <50 cells/μL: RR = 0.2 (95% CI = 0.1 to 0.6)] (Bohlius et al. 2011).

### 3.4.4 Cofactors

Hodgkin lymphoma is strongly associated with Epstein-Barr virus infection (see accompanying monograph on Epstein-Barr virus), and in HIV-1-positive people, up to 80% to 100% of tissues have been reported to be infected with Epstein-Barr virus (Glaser et al. 2003), compared with less than 50% among HIV-1-negative Hodgkin lymphoma cases (Biggar et al. 2006); see also review by (Carbone et al. 2009; Goedert and Bower 2012; Sissolak et al. 2010). HIV-1-Hodgkin lymphoma appears to be an Epstein-Barr virus-related lymphoma expressing Epstein-Barr virus-encoded latent membrane protein 1 (LMP-1) (IARC (2012a); also see Carbone et al. (2009); Mounier et al. (2010)).

## 3.5 Cancer Hazard Evaluation: Human Papillomavirus-related Cancers

Three main cancer types are associated with exposure to both HIV-1 and human papillomavirus: cervical cancer (see Section 3.5.1), invasive anal cancer (see Section 3.5.2), and genital cancers (see Section 3.5.3).

### 3.5.1 Cervical Cancer

#### Background Information

Cervical cancer incidence rates in the United States have fallen steadily from 14.8 to 6.7 per 100,000 from 1975 to 2012 (NCI 2015b); however, they remain high in developing countries, e.g., in sub-Saharan Africa, where the incidence is approximately 31 per 10,000 women (Louie et al. 2009), in part due to a lack of screening, sexually transmitted infection (STI) prevention, or human papillomavirus vaccination programs.

#### Cohort and Case-control Studies

A total of 17 cohort studies including the meta-analysis by Grulich et al. (2007) and 2 case-control studies of cervical cancer reporting SIR or RR were reviewed by IARC (2012a). The populations in the cohort studies were large, ranging from approximately 1,659 to 375,933 women with HIV-1/AIDS and including 977 cases of cervical cancer (one study by Patel et al. (2008) did not state the number of cases). The two case-control studies of people with HIV-1 in Africa, from Uganda (Newton et al. 2001) and South Africa (Stein et al. 2008), both reported non-statistically significant relative risks of 1.6, based on 257 exposed cases.

The cohort studies of cervical cancer reviewed by IARC reported risks ranging from 1 to over 40 among HIV-1-positive women vs. HIV-1-negative women, with most excess risks in developed countries of between 3 and 22 (Table 3-5), depending on factors such as availability of human papillomavirus screening, human papillomavirus vaccination and treatment programs, availability of HAART, and competing causes of death (IARC 2012a). A meta-analysis of seven of these cohorts by Grulich et al. (2007) reported an age- and sex-adjusted meta-SIR = 5.8 (95% CI = 3.0 to 11.3) for the period 1980 to 2002 based on 104 cases.

Table 3-5 Summary of HIV-1/AIDS Cohort Studies of Cervical Cancer

| AIDS | HIV-1 Positive^a^ | AIDS or HIV-1 Positive
RR/SIR | 2.9–51^a^ | 1.0–14.6^a^ | 1.7–21.8^b^
Cohort size | 1,659–375,933 | 2,141–57,350 | 2,574–444,172
No. cases | 9–84 | 2–137 | 1–355
No. of studies | 5 | 7 | 5

Source: IARC (2012a), Table 2.10 and Table 2.11.

^a^ Subjects with cervical cancer in these cohorts would have AIDS as this cancer is an AIDS-defining disease.

^b^ All lower 95% CI > 1.0, with the exception of Goedert et al. (1998), Allardice et al. (2003), Newnham et al. (2005).

Findings from the 15 cohort studies published after 2008 (Akarolo-Anthony et al. 2014; Bedimo et al. 2009; Calabresi et al. 2013; Castilho et al. 2015; Chaturvedi et al. 2009; Chen et al. 2014; Coghill et al. 2015; Franceschi et al. 2010; Hleyhel et al. 2013; Park et al. 2014; Raffetti et al. 2015; Simard et al. 2010; Simard et al. 2012; Vogel et al. 2011; Zhang et al. 2011) were consistent with the findings (risks mostly between 2 and 18) from the earlier studies (data not shown).

#### Relationship with HAART

The effect of HAART on the risk of cervical cancer is not clear. HAART appeared to have little impact on decreasing the risk of cervical cancer in HIV-infected women based on reviews of studies comparing rates from the pre-HAART era to the early HAART era (Adler 2010; Denslow et al. 2014; IARC 2012a; Palefsky 2009). Large cohort studies have reported no change or statistically insignificant decreases or increases in SIR/RRs in the range of 0.8 To 1.9 from the pre-HAART to HAART periods (Biggar et al. 2007; Chaturvedi et al. 2009; ICHIVC 2000; Serraino et al. 2007; Simard et al. 2010).

Some studies have reported that patients with a higher CD4+ cell count and receiving HAART had a lower risk of cervical cancer (Abraham et al. 2013; Guiguet et al. 2009; Leitao et al. 2008; Patel et al. 2008), while others report no apparent association with CD4+ cell counts (Biggar et al. 2007; Chaturvedi et al. 2009; Frisch et al. 2000). Chaturvedi et al. (2009) hypothesized that high cervical cancer mortality in the pre-HAART era may have masked the association of immunosuppression with cervical cancer, and that prolonged survival with incomplete immunocompetence among those with very low CD4+ counts at diagnosis provided time for cancer to develop. Many of the studies that reported no significant effect of HAART on the risk of cervical cancer were registry studies that used aggregate data and did not compare risk at the individual level and could not account for the increased life expectancy of HIV-1 patients receiving HAART (Dugué et al. 2013; Gravitt and Kirk 2010).

Current invasive cervical cancer risks among HIV-1-infected women generally remain elevated compared with general population rates and among people treated with HAART (Patel et al. 2014).

#### Cofactors

Human papillomavirus is considered necessary for the development of cervical cancer, and the risk is substantially increased in the presence of HIV-1 infection (IARC (2007; 2012a); NTP (2014a) and reviews by Bosch et al. (2002); Crosbie et al. (2013)). Almost all cervical cancers are caused by human papillomavirus (CDC 2015c). While most human papillomavirus infections are transient, a causal relationship between persistent human papillomavirus infection involving certain genital mucosal types and the development of cervical cancer has been well established in virtually all populations around the world that have been studied. Both human papillomavirus and HIV-1 are sexually transmitted, and the two infections frequently occur together (IARC 2012a). The primary evidence for an indirect effect of HIV-1 infection for cervical cancer is that HIV-1-positive women from various populations are more likely to be human papillomavirus positive than HIV-1-negative women, and more likely to have persistent and multiple infections, and more likely to have one or more of the human papillomavirus genotypes that are considered to be high risk for progression to invasive cervical cancer (IARC (2012a); NTP (2003) see also, e.g., Desruisseau et al. (2009) and reviews by De Vuyst et al. (2013), Denny et al. (2012), Adler (2010)). Abnormal cervical cytology as a result of HPV infection and an increased risk of progression of cervical lesions has been associated with low CD4+ counts in multiple studies (Denslow et al. 2014).

Other risk factors may impact cervical cancer risk, including other causes of immune suppression (transplants or autoimmune disease), end-stage renal disease, chronic inflammation, oral contraceptive use, and, most strongly, smoking (see e.g., reviews by (Dugué et al. 2013; Fernandes et al. 2015; Gadducci et al. 2011)).

### 3.5.2 Cancer Evaluation: Invasive Anal Cancer

#### Background Information

In the United States, anal cancer is rare, accounting for 0.4% of all incident cancers. The annual incidence rate is approximately 1.8 per 100,000, based on 2008 to 2012 SEER rates. However, over the past 10 years, anal cancer incidence rates have been increasing on average 2.2% per year, and the risk in men is approaching the risk in women (1.5/100,000 in men and 2.0/100,000 women per year based on 2008 to 2012 cases), which is largely attributed to increased rates of HIV (NCI 2015e).

#### Cohort and Case-control Studies of Invasive Anal Cancer

IARC (1996) reviewed two early U.S. cancer registry linkage studies of AIDS patients in which an SIR of 3.5 (95% CI = 1.3 to 7.5) was reported for anorectal cancer by Reynolds et al. (1993) and relative risks of 84.1 (95% CI = 46.4 to 152) among men having sex with men, and 37.7 (95% CI = 9.4 to 151) among other men were reported for anal cancer by Melbye et al. (1994).

A total of 17 cohort studies reporting SIR or RR were reviewed by IARC (2012a), representing approximately 1,670 cases. No case-control studies were identified by IARC. The cohort studies reported substantial increases in anal cancer among HIV-1-positive men, particularly men having sex with men, but increases in risk were also reported among HIV-1-positive women, compared to HIV-1-negative groups or the general population (IARC 2012a). In addition, cases may occur at a younger age among HIV-1-positive compared with HIV-1-negative populations (IARC 2012a). These cohort studies conducted in the United States, Europe, or Australia, including the meta-analysis by Grulich et al. (2007), were reviewed by IARC, which reported a range of SIRs or RRs from approximately 6.8 to 222, with most studies reporting risk between 10 and 39 (IARC 2012a) (see Table 3-6). Twenty-one studies conducted since the IARC review confirmed these findings with most studies reporting higher risk estimates ranging from 20 to over 100. Shiels et al. (2009) reported a meta-SIR of 28 (95% CI = 21 to 35), based on 253 cases. In addition, Machalek et al. (2012) conducted a meta-analysis of 53 studies of anal cancer among men who have sex with men and reported an approximately 9-fold higher risk of anal cancer among HIV-1-positive compared with HIV-1-negative men. The risk of anal cancer was also increased among HIV-1-negative men who have sex with men compared with the general population (Machalek et al. 2012).

Table 3-6 Summary of HIV-1/AIDS Cohort Studies of Invasive Anal Cancer

| AIDS | HIV-1 Positive | AIDS or HIV-1 Positive
RR/SIR | 6.8–37.9^a^ | 9.2–222^a^ | 28.8–37.1^a^
Cohort size | 3,616–375,933 | 2,566–57,350 | 12,104–444,172
No. cases | 1–214 | 5–61 | 6–303
No. of studies | 6 | 7 | 4

Source: IARC (2012a), Table 2.13 and Table 2.14.

^a^ All lower 95% CI > 1.0 except Grulich et al. (2007).

#### Relationship with HAART

The risk of anal cancer in the HAART era appears to be increased. An early U.K. clinical study of HAART-treated vs. untreated patients (Bower et al. 2004) reported a doubling of risk from approximately 0.4 to 0.9 cases per 1,000 person-years. Four studies reported increases in anal cancer risk from the pre- to the early or established HAART era ranging from 1.5 to 274, with most between 1.5 and 6 (Diamond et al. 2005; ICHIVC 2000; Seaberg et al. 2010; Simard et al. 2010), and studies by Piketty et al. (2008), Patel et al. (2008), and Hessol et al. (2007) reported increased risks in the HAART era. However, record-linkage registry studies of HIV-1/AIDS cases in the United States(Engels et al. 2006a; Engels et al. 2008; Hessol et al. 2007), Switzerland (Clifford et al. 2005) and Australia (van Leeuwen et al. 2009) reported inconsistent changes in SIRs over two to three time periods between the pre-and established HAART era. In the largest study of human papillomavirus-associated cancers Chaturvedi et al. (2009) found that the incidence of invasive anal cancer was 104% higher in the HAART era than in the pre-HAART era (RR = 2.03, 95% CI = 1.54 to 2.68), and that low CD4 counts at diagnosis during the HAART era were associated with significantly increased anal cancer incidence. Such observed increases in anal cancer incidence may be due to the fact that mortality among individuals with a low CD4 T-cell count during the pre-HAART era may have masked an association between immunosuppression and the risk of human papillomavirus-related invasive anal cancer; the increased survival during the HAART era may provide adequate time for progression of premalignant lesions to invasive cancers (Chaturvedi et al. 2009).

Overall, current risks of anal cancer among HIV-1-positive populations, particularly among men who have sex with men, remain 30 to 140 times higher than general population rates (Franceschi et al. 2010; Powles et al. 2009; van Leeuwen et al. 2009).

#### Cofactors

Approximately 91% of anal cancers are considered to be human papillomavirus-associated (CDC 2015c). Human papillomavirus infection of the anal canal is highly prevalent among both HIV-1-positive people and transplant recipients, and is also observed in the large majority of invasive anal cancer cases in both men and women (Hessol et al. 2009; IARC 2012a). Anal cancer and anal intraepithelial neoplasia incidence is highest among HIV-1-positive men who have sex with men where anal human papillomavirus infection is almost universal, chronic, and characterized by multiple human papillomavirus subtypes; however, human papillomavirus infection and anal cancer are also more common in HIV-1-positive women than HIV-1-negative women (Engels 2009). A high percentage of HIV-1-infected individuals co-infected with human papillomavirus also have an increased risk of developing many human papillomavirus-associated cancers, including oropharyngeal cancers (Gillison 2009; Park et al. 2016). Other risk factors for precancerous anal intraepithelial neoplasias and subsequent risk of invasive anal cancer, which include a history of receptive anal intercourse, genital warts, and smoking (Coutlée et al. 2012; Hessol et al. 2009; Stanley et al. 2012) are correlated with the risk of both human papillomavirus and HIV-1 infection; however, the degree of interaction between these factors and the risk of anal cancer in HIV-1-positive populations is not clear.

### 3.5.3 Genital Cancers

#### Background Information

Genital cancers include vaginal/vulvar cancer in women and penile cancer in men. In the United States based on age-adjusted data from SEER 2008 to 2012, the number of new cases of vulvar cancer was 2.4 per 100,000 women per year, and accounts for 0.3% of all incident cancers (NCI 2015d); the incidence of vaginal cancer is 0.7 per 100,000 women per year (CDC 2016); the incidence of penile cancer is 0.8 per 100,000 men per year (CDC 2016).

#### Cohort and Case-control Studies

The available database on HIV-1 infection and human papillomavirus-related genital cancers has expanded since the IARC (2012a) review. The working group considered the database to be limited as it was based primarily on a meta-analysis of only two studies of vaginal/vulvar cancer (mRR = 6.5, 95% CI = 4.1 to 10.2) and three studies of penile cancer (mRR = 4.4, 95% CI = 2.8 to 7.1), each with relatively few (less than 25) infected cases (Grulich et al. 2007). (Two of the studies in the analysis for each cancer might have been on overlapping populations.) A subsequent meta-analysis (Shiels et al. 2009), which included some of the same studies, reported similar risks for both cancer endpoints (mRRs = 9.4, 95% CI = 4.9 to 18, 25 infected cases from four studies on vaginal/vulvar cancer and 6.8, 95% CI = 4.2 to 11, 16 infected cases from 3 studies on penile cancer) based on relatively few infected cases.

Since the 2009 meta-analysis, four additional cohort studies conducted in the United States and Europe that reported risk estimates for vaginal/vulvar cancer (totaling over 150 cases) and four studies for penile cancer (totaling over 65 cases) among HIV-1-infected individuals or people with AIDS were identified (Park et al. (2014) for penile only, Franzetti et al. (2013) for vaginal/vulvar only and Raffetti et al. (2015), Simard et al. (2010), Chaturvedi et al. (2009) for both cancer sites). (Two studies may report on overlapping populations and overlap with earlier studies). In general, these studies have more infected cases than the earlier studies. All studies, most of which used the general population as the comparison group, found statistically significantly increased SIRs (mostly ranging from 4 to 28) for both cancers. A study of HIV-1-infected and uninfected veterans found a statistically significant elevated incidence rate ratio (IRR) for penile cancer (Park et al. 2014). A summary of the findings across all studies (prior to and after the 2009 meta-analysis) are provided in Table 3-7.

Table 3-7 Summary of HIV-1/AIDS Cohort Studies of Genital Cancers

| Penile | Vulva/vagina
RR/SIR (range) | 4–28 | 5–27^a^
No. cases/study | 1–29 (in situ) | 1–123 (in situ)
No. of studies^b^ | 6 | 7

Source: Long et al. (2008), Mbulaiteye et al. (2006), Newnham et al. (2005), Patel et al. (2008), Chaturvedi et al. (2009), Dal Maso et al. (2009), Simard et al. (2010), Park et al. (2014), Franzetti et al. (2013), Raffetti et al. (2015). Does not include Engels et al. (2006a) and Frisch et al. (2001) since those population are thought to have been updated by Simard et al. 2010.

^a^ RR of 69 based on one case; 5 is based on invasive cancer only.

^b^ Two studies (Chaturvedi et al. 2009; Simard et al. 2010) might be of overlapping populations.

Approximately 75% of vaginal cancers, 69% of vulvar cancers, and 63% of penile cancers are considered to be human papillomavirus associated (CDC 2012). Two studies evaluated cancer risk among people with AIDS in the United States with potentially overlapping populations (Chaturvedi et al. 2009; Simard et al. 2010), one of which conducted a detailed analysis of human papillomavirus-related tumors (Chaturvedi et al. 2009) primarily related to indicators of immunosuppression. For each cancer type, higher risks were found for in situ cancer (~20-fold) compared with invasive cancer (~5-fold) and in general, similar risk estimates were found across the different HIV-1 risk groups (such as injection drug users, heterosexual, unknown, and men having sex with men for penile cancer), which may help rule out potential confounding from lifestyle behaviors.

Simard et al. (2010) reported higher risk in the HAART era compared with pre-HAART for both cancer types. Both studies of people with AIDS found evidence to suggest that the risk of genital cancers is higher at longer time periods after AIDS onset compared to shorter time periods with the strongest association with vaginal/vulvar cancer although the time period after AIDS onset differed between the two studies. In addition, the risk of vaginal/vulvar cancer increased during the time period 5 years prior to AIDS onset to 5 years after AIDS onset. Among women who developed AIDS during the HAART era, low CD4 counts at AIDS onset was associated with the risk of developing in situ and invasive cancer of the vagina or vulva 28 to 60 months after AIDS onset. These findings are consistent with a link between prolonged HIV-related immunosuppression, which would allow increased risks from co-infection with human oncogenic papillomaviruses—the major co-factor. Other concerns are similar to those mentioned for anal and cervical cancer.

### 3.5.4 Oral-related Cancers

#### Background Information

Oral-related cancers include both oropharyngeal cancers (cancers of the soft palate and uvula, tonsils, posterior pharyngeal wall and the base of the tongue), and oral cavity cancers (cancers of the lips, floor of the mouth, buccal mucosa, gingiva, hard palate, and the mobile part of the tongue). In the United States based on age-adjusted data from 2008 to 2012, the number of new cases of oral-related cancers combined was 11.0 per 100,000 men and women per year, and represent 2.8% of all new cancers per year (NCI 2015g).

#### Cohort and Case-control Studies of Oral-related Cancer

The IARC (2012a) monograph on HIV-1 infection and oral-related cancers provided limited information about the risks, including reference to one meta-analysis based on five studies of the risk of lip cancer and of oral cavity/pharyngeal cancers in HIV-1/AIDS-positive individuals showing increased risks of cancer (mSIR = 2.80, 95% CI = 1.91 to 4.11, and mSIR = 2.32, 95% CI = 1.65 to 3.25, respectively) (Grulich et al. 2007). A meta-analysis conducted by Shiels et al. (2009), including some of the same studies reported by Grulich et al. (2007), published after the IARC monograph, reported meta-SIRs for lip and oral cavity/pharynx together (mSIR = 2.2, 95% CI = 1.0 to 4.7) based on 84 cases. Shiels et al. (2009), also included separate estimates for oropharyngeal cancer (mSIR = 1.9, 95% CI = 1.4 to 2.6) based on 108 cases.

Since the IARC (2012a) review and the meta-analysis by Shiels et al. (2009), the available database on HIV-1 infection and oral-related cancers has expanded considerably. Approximately 13 new cohort studies have reported estimates for oral-related cancers (Calabresi et al. 2013; Castilho et al. 2015; Chaturvedi et al. 2009; Chen et al. 2014; Coghill et al. 2015; Franzetti et al. 2013; Park et al. 2014; Raffetti et al. 2015; Seaberg et al. 2010; Silverberg et al. 2011; Simard et al. 2010; van Leeuwen et al. 2009; Vogel et al. 2011).

Overall, estimates of oral-related cancers among HIV-1 infected individuals were available from 21 studies including both those reviewed in IARC and new studies published since the IARC (2012a) review. Risks (SIR/RRs) reported in these studies ranged from 1.1 to 5.3, with most studies reporting risks in the range of 2 to 4. SIR/RR estimates from two studies which were conducted outside of these geographic areas reported elevated risks of tongue/tonsil cancers in the range of 11 to 22. Due to small numbers of these relatively rare tumors, studies often report estimates for combined cancer sites, and/or for specific oral-related cancer sites (see Table 3-8): oral cavity and oropharyngeal cancers combined, oropharyngeal cancers, tongue and/or tonsil cancers, and oral cavity cancers (lip and/or oral cavity).

Table 3-8 Summary of Studies of HIV-1/AIDS Cohort of Oral-related Cancers^a^

| Oral Cavity/Pharyngeal Cancers | Oropharyngeal Cancers | Tongue and/or Tonsil Cancer | Oral Cavity Cancer
RR/SIR (range) | 1.1–4.1 | 1.1–5.4 | 1.7–22.1 | 1.1–8.5
No. cases/study | 2–260 | 2–108 | 2–54 | 4–30
No. of studies^b^ | 14 | 7 | 7 | 7

Source: Calabresi et al. (2013); Castilho et al. (2015); Chaturvedi et al. (2009); Chen et al. (2014); Clifford et al. (2005); Coghill et al. (2015); Engels et al. (2008); Franzetti et al. (2013); Frisch et al. (2001); Grulich et al. (2002); Grulich et al. (2007); IARC (2012a); Newnham et al. (2005); Park et al. (2014); Raffetti et al. (2015); Seaberg et al. (2010); Shiels et al. (2009); Silverberg et al. (2011); Simard et al. (2010); van Leeuwen et al. (2009); Vogel et al. (2011).

^a^ Several studies report more than one anatomical site or site grouping.

#### Cofactors

Population-level incidence of human papillomavirus-positive oropharyngeal cancers has increased by 225% (95% CI = 208% to 242%) from 1988 to 2004 (from 0.8 per 100,000 to 2.6 per 100,000), and incidence for human papillomavirus-negative cancers declined by 50% (95% CI = 47% to 53%; from 2.0 per 100,000 to 1.0 per 100,000) (Chaturvedi et al. 2011). In a systematic review of the prevalence of human papillomavirus in oropharyngeal squamous-cell sarcoma worldwide which sought to determine whether human papillomavirus is driving the increase in incidence of oropharyngeal cancers, Stein et al. (2015) reported that prevalence of human papillomavirus-positive oropharyngeal squamous-cell sarcoma in North America increased in the 1990s, rose dramatically from 2000 to 2004 and plateaued at about 65% through approximately 2012.

HIV-1-infected individuals are known to have a high prevalence of co-infection with HPV16 (Beachler et al. 2012; Kreimer et al. 2004), an established cause of oropharyngeal and oral cavity carcinomas (IARC 2007). Among HIV-1 infected persons compared to the general population in the United States, multiple investigations show that they have a higher oral human papillomavirus DNA prevalence (20% to 45%), and a higher oncogenic oral human papillomavirus DNA prevalence (12% to 26%) than a sample of the U.S. population (Gillison 2009).

This heterogeneity of disease, the unmeasured heterogeneity of risk factors, and the potentially distinct etiologic pathways for oral-related cancer subtypes complicate the interpretation of these modest risks. Many reports combine oropharyngeal and oral cavity cancer, or report on the broader category of head and neck cancers.

It has been hypothesized that human papillomavirus-associated cancers and human papillomavirus-non associated cancers have distinct risk factor profiles: sexual behavior, particularly increased numbers of oral sexual partners, is a risk factor for human papillomavirus and human papillomavirus-associated cancers; while human papillomavirus-non-associated cancers are more likely to be associated with tobacco and alcohol use, which are also elevated among HIV-1-infected individuals (Gillison et al. 2008). Registry studies have not been able to precisely distinguish between human papillomavirus-associated and human papillomavirus-non-associated cancer. Furthermore, it is likely that risk factors such as common sexual behaviors, the proportion of men who have sex with men and heterosexuals in a cohort, and other behavioral risk factors related to human papillomavirus-related oral-related cancers, vary across cohorts (Kreimer et al. 2013; Pickard et al. 2012). Unlike HPV1-associated cancers (e.g., cervical or anal cancer), oral transmission of human papillomavirus from males to males has decreased compared with oral transmission from females to males, which may also help explain the modest increase in risk measured in the HIV/AIDS cohorts which are largely men who have sex with men (Beachler and DʼSouza 2013). In addition, Chaturvedi et al. (2009) found higher risks of oropharyngeal cancer among heterosexual men compared to men who have sex with men. These data are consistent with the male predominance of human papillomavirus-related cancers and their increase in men compared with women as the prevalence of heterosexual men is much greater than that of men who have sex with men (Gillison et al. 2015).

The role of tobacco and alcohol in combination with HIV-1 and human papillomavirus infections has not been widely investigated. However, Silverberg et al. (2011), in a study estimating the risk of oral cavity and pharynx cancers in HIV-1-positive and negative individuals, controlled for smoking which resulted in a reduction in the SIR from 1.9 to 1.4. Also, the interrelationship of risk factors among HIV-1-infected individuals was recently explored in a natural history study of human papillomavirus among HIV-1-positive and HIV-1-negative individuals, which found that oral human papillomavirus acquisition appears to be increased by oral sex and by the severity of immunosuppression as measured by CD4 counts, while the risk of oral human papillomavirus persistence, necessary for carcinogenesis, is likely to be increased by older age, male sex, and cigarette smoking (Beachler et al. 2014).

## 3.6 Cancer Hazard Evaluation: Hepatocellular Carcinoma

### 3.6.1 Background Information

Liver cancer is relatively uncommon in the United States; the annual number of combined liver and intrahepatic bile duct cancers was an estimated 8 per 100,000 in 2015 (NCI 2015a). Hepatocellular carcinoma is the most common form of liver cancer, occurring among 5 to 10 per 100,000 population in the United States (Altekruse et al. 2014), with several recognized and overlapping risk factors, including alcohol abuse, non-alcoholic steatohepatitis, intravenous drug use, cirrhosis, diabetes, and hepatitis B and C virus infection. HIV-1 infection has been reported to be associated with an increase in intrahepatic apoptosis, activation and fibrosis, and gastrointestinal permeability (Crane et al. 2012).

### 3.6.2 Cohort and Case-control Studies

Eighteen cohort, one nested case-control, and two case-control studies reporting risks were reviewed by IARC (2012a); since 2009, 21 additional cohort studies were identified (excluding prospective patient series). Studies reviewed by IARC (2012a) reported increases in the risk of hepatocellular carcinoma compared with the general population among U.S., European, or Australian populations of between approximately 1.9 and 50, with most estimates between 2 and 16 (see IARC Table 2.23). Studies published from 2009 through August 2015 reported risks ranging from approximately 2 to 31 with most between 2 and 11; 2 studies reported no observed cases. In addition, the meta-analyses by Grulich et al. (2007) (7 studies) and by Shiels et al. (2009) (11 studies), reported meta-SIR for hepatocellular carcinoma of 5.2 (95% CI = 3.3 to 8.2) based on 133 cases, and 5.6 (95% CI = 4.0 to 7.7) based on 171 cases, respectively (see summary Table 3-9).

Table 3-9 Summary of HIV-1/AIDS Cohort Studies of Hepatocellular Carcinoma

| AIDS | HIV-1 Positive | AIDS or HIV-1 Positive
RR/SIR* | 3.3–4.5 | 1.0–16.5 | 1.7–11
Cohort size | 1,659–375,933 | 2,566–84,504 | 1,476–615,150
No. cases | 1–95 | 2–174 | 2–366
No. of studies | 9 | 11 | 19

Source: IARC (1996), IARC (2012a), Table 2.23 and studies since IARC (2012a): Bedimo et al. (2009); Castilho et al. (2015); Chen et al. (2014); Coghill et al. (2015); Franceschi et al. (2010); Franzetti et al. (2013); Hleyhel et al. (2014); Kramer et al. (2015); McDonald et al. (2009); Park et al. (2014); Powles et al. (2009); Raffetti et al. (2015); Sahasrabuddhe et al. (2012); Seaberg et al. (2010); Shiels et al. (2009); Silverberg et al. (2011); Simard et al. (2010); Simard et al. (2012); van Leeuwen et al. (2009); Vogel et al. (2011); Zhang et al. (2011). References not reporting SIR or RR and outliers (Akarolo-Anthony et al. 2014) were excluded. Findings of studies conducted among populations of hepatitis C virus positives or which also adjusted for hepatitis C virus in models are discussed in the text: Di Benedetto et al. (2014); Kramer et al. (2015); McDonald et al. (2009); McGinnis et al. (2006); Sahasrabuddhe et al. (2012); Vogel et al. (2011). The Deng et al. (2009) meta-analysis examined hepatitis C virus patients with and without HIV-1.

* All lower 95% CI > 1.0 except Coghill et al. (2015); Dal Maso et al. (2003); Grulich (1999); Grulich et al. (2002); Mbulaiteye et al. (2006); Serraino et al. (2000).

Shiels et al. (2009) included seven studies of liver cancer among patients with AIDS and without AIDS in their meta-analysis and reported that the risk of hepatocellular carcinoma among patients with AIDS was 6.5 (95% CI = 3.6 to 12), while the risk among patients without AIDS was 3.9 (95% CI = 2.6 to 5.6), supporting the association between decreased immune function and increased risk of liver cancer.

### 3.6.3 Relationship with HAART

The role of HAART on hepatocellular carcinoma risk has yet to be clearly established. Calendar-period analyses indicate that hepatocellular carcinoma risk has increased in the HAART era (Curry 2013; Hessol et al. 2007; Sahasrabuddhe et al. 2012). In the Shiels et al. (2009) meta-analysis, the SIR for liver cancer in the HAART era was slightly higher than in the pre-HAART era (ratio of SIRs: 1.25, 95% CI = 0.49 to 3.24). Merchante et al. (2013) reported that the incidence of hepatocellular carcinoma among HIV-1/hepatitis C virus-positive patients increased from 0.2 to 2.8 per 1,000 person-years (based on 82 cases of hepatocellular carcinoma) from the early to established HAART era (2000 to 2009). Observed increases may at least partly be due to increased survival or possible changes in alcohol consumption, hepatitis B or C virus infection rates, or other risk factors for hepatocellular carcinoma (Curry 2013; Hessol et al. 2007; IARC 2012a). In contrast to this, some follow-up studies of individual HIV-1-infected patients reported either a lack of association (e.g., Serraino et al. 2007), or a reduction in relative risk among HAART-treated patients (Hessol et al. 2007) or since the advent of HAART (Limketkai et al. 2012).

Several studies have found the risk of hepatocellular carcinoma to be associated with the degree of immunosuppression at HIV-1 diagnosis, as measured by CD4 cell count (Engels et al. 2008) (Kramer et al. 2015; Silverberg et al. 2011; Vogel et al. 2011), suggesting a role for HIV-1-induced immunosuppression. However, observations of low CD4 counts with liver cancer are sensitive to the timing of the count either at AIDS diagnosis or at enrollment; one study evaluating time-dependent measures of CD4 found that liver cancer was unrelated to longer exposure to CD4 counts of <200 cells/μL (Kesselring et al. 2011), while another study (Guiguet et al. 2009) measuring recent low CD4 count found that this metric was the best predictor of liver cancer incidence.

### 3.6.4 Cofactors

Hepatocellular carcinoma is causally linked to both hepatitis B virus and hepatitis C virus infection (see IARC 2012a; NTP 2014b; NTP 2014c). Overall, approximately 25% of HIV-1-positive people in the United States and also in Europe are estimated to be co-infected with hepatitis C virus and 9% with hepatitis B virus (Nunnari et al. 2012). Hepatitis C virus infection is highly prevalent among groups with parenterally acquired HIV-1 infection, notably hemophiliacs and injection drug users (between 80% and 95%) and substantially less (3% to 15%) among other groups, i.e., non-injection drug-using men who have sex with men and other men and women (Clifford et al. 2008; Engels et al. 2002a).

Concerns remain as to the extent to which these viruses are cofactors or confounders of observed associations between HIV-1 infection and hepatocellular cancer, and the extent to which observed increases in risk of hepatocellular carcinoma among HIV-1-infected populations is attributable to co-infection with hepatitis B or C virus. Few studies have measured the seroprevalence of hepatitis B or C virus among HIV-1/AIDS individuals, but several cohort studies have reported a lack of association between HIV-1 status and the risk of hepatocellular carcinoma among hepatitis C virus-infected patients (Henderson et al. (2010); Kramer et al. (2005) as reviewed by Deng et al. (2009); Tradati et al. (1998)) or after adjustment for hepatitis C virus infection (McGinnis et al. 2006). Di Benedetto et al. (2014) observed that hepatitis C infection alone was associated with a higher incidence of hepatocellular carcinoma than among hepatitis C virus and HIV-1 co-infected patients (incidence ratio 1.97).

## 3.7 Cancer Hazard Evaluation: Cancers Not Known to Be Associated with Other Viruses

Three main cancer types which are not known to be associated with other viruses are evaluated below: non-melanoma skin cancer (see Section 3.7.1), conjunctival cancer (see Section 3.7.2), and lung cancers (see Section 3.7.3).

### 3.7.1 Non-melanoma Skin Cancer

#### Background Information

Non-melanoma skin cancer is the most common cancer in the United States; with 3.5 million new cases per year, the incidence rate exceeds that of all other cancers combined (ACS 2015). Two primary subtypes have been identified: squamous-cell carcinoma and basal-cell carcinoma (the most common form). While most forms of in situ non-melanoma skin cancer are readily treatable and are not included in cancer statistics, an estimated 2,000 deaths per year in the United States have been attributed to this form of cancer (in contrast to melanoma with 9,000 deaths per year (ACS 2015).

A rare form of basal-cell carcinoma, Merkel cell carcinoma, has been identified in association with the recently identified Merkel cell polyomavirus since 2008 and is associated with approximately 80% of these cancers (see accompanying monograph on Merkel cell polyomavirus). One cohort study of AIDS patients prior to this date (Engels et al. 2002b) specifically identified Merkel cell carcinoma in this population, and reported a relative risk of 13.4 (95% CI = 4.9 to 29.1) based on six cases. The proportion of basal-cell carcinomas previously observed in studies of HIV-1-infected populations that are attributable to Merkel cell carcinoma and Merkel cell polyomavirus co-infection has not been clearly established to date.

#### Cohort and Case-control Studies

Eight cohort studies and one case-control study of non-melanoma skin cancer in HIV-1-positive populations were reviewed by IARC (2012a). The cohort studies, all from the United States or Europe, reported risks ranging from 2.8 to 20, based on 130 cases. Since the IARC review (2012a), eight cohort studies and two additional meta-analyses were identified (Shiels et al. 2009; Zhao et al. 2015), with two of the cohort studies having been published prior to the IARC publication (Cooksley et al. 1999; Grulich et al. 2002). Most of the reported risks in the cohort studies ranged from 1.5 to 6 but were up to 20 in a few studies (see Table 3-10). There is some overlap of studies included in the three meta-analyses, with meta-SIR values ranging from 2.8 to 4.1 based on a total of 851 cases. The most recent meta-analyses by Zhao et al. (2015) was limited to the six studies published between 2003 and 2013 that only collected data on cancer incidence through cancer registries to ensure unbiased comparisons of the incidence rates from the cohorts with the general population. All the studies in this meta-analysis reported statistically significant risk estimates and the meta-risk was 2.76 (95% CI = 2.55 to 2.98) based on 570 cases. In addition, a case-control study from South Africa (Stein et al. (2008), reviewed by IARC (2012a)) reported a statistically significant odds ratio of 2.6 among 15 exposed cases.

Table 3-10 Summary of HIV-1/AIDS Cohort Studies of Non-melanoma Skin Cancer^a^

| AIDS | HIV-1 Positive | AIDS or HIV-1 Positive
RR/SIR* | 13.4 | 1.75–19.6 | 1.5–14.9
Cohort size | 309,365 | 2,238–33,190 | 2,574–497,142
No. of cases | 6 | 3–70 | 2–570
No. of studies | 1 | 6 | 12

Source: IARC (1996), IARC (2012a), Table 2.17 and studies since IARC (2012a): Albini et al. (2013); Chen et al. (2014); Crum-Cianflone et al. (2015); Franceschi et al. (2010); Grulich et al. (2002); Lanoy et al. (2009); Shiels et al. (2009); Silverberg et al. (2013); Zhao et al. (2015) meta-analyses. References not reporting SIR or RR were excluded.

* All lower 95% CI > 1.0 except Dal Maso et al. (2003), RR = 1.5 (0.8–2.5); and Lanoy et al. (2010), RR = 2.3 (0.94–5.67) for Merkel cell carcinoma.

^a^ Includes non-melanoma skin cancer, not otherwise specified, except for Engels et al. (2002b) study of Merkel cell carcinoma; Lanoy et al. (2009) study of Merkel cell carcinoma (NS), sebaceous carcinoma, and appendageal carcinoma; and Silverberg et al. 2013 study of basal-cell and squamous-cell carcinomas.

#### Relationship with HAART

Crum-Cianflone et al. (2015), based on a substudy of 2,238 HIV-1-infected adults within the U.S. Military HIV Natural History Study (NHS) who initiated HAART between 1996 and 2012, found that viremia was associated with non-melanoma skin cancers (time-updated HIV-1 RNA, per log_10_ copies/mL, hazard ratio [HR] = 1.75 [95% CI = 1.42 to 2.14]). This finding provides some evidence of the link between HIV-1viremia and non-melanoma skin cancers and lends support to control of viremia in limiting the risk of cancer among HIV-1 patients after HAART initiation. This is consistent with the finding of a statistically significant trend (P < 0.001) that was observed with decreasing recent CD4 counts in a cohort study of HIV-1-positive and 36,821 HIV-1-negative patients in the United States (Silverberg et al. 2013).

In contrast to transplant recipients, in whom substantial increases in predominantly squamous-cell carcinoma of the skin have been reported, basal-cell carcinomas appear to predominate (Bedimo et al. 2009).

The meta-analysis by Zhao et al. (2015) reported similar risk estimates for studies in the pre-HAART era (2.11, 95% CI = 1.44 to 3.2, 3 studies) and the post-HAART era (2.01, 95% CI = 1.33 to 3.04, 4 studies).

#### Cofactors

Since the last IARC review (2012a) and shortly after the discovery of Merkel cell polyomavirus, two cohort studies and one case-control study have been identified that reported increased risks of Merkel cell carcinoma among HIV-1-positive populations (Izikson et al. 2011; Lanoy et al. 2009; Lanoy et al. 2010) and also diminished survival of Merkel cell carcinoma patients (Paulson et al. 2013). There is limited evidence to date as to whether infection with HIV-1 increases the risk of Merkel cell polyomavirus infection (Fukumoto et al. 2013; Tolstov et al. 2011; Wieland and Kreuter 2011; Wieland et al. 2011), however, and no studies have been identified to date that have measured Merkel cell polyomavirus among HIV-1-positive Merkel cell carcinoma cases, with the exception of one case study (Li et al. 2013). Merkel cell carcinoma is primarily attributed to Merkel cell polyomavirus and HIV-1-induced immunodeficiency increases the risk (see Merkel cell polyomavirus monograph at https://ntp.niehs.nih.gov/go/797227).

The elevated risk of non-melanoma skin cancer in the HIV-1-positive population is largely limited to Caucasians and suggests that exposure to solar ultraviolet radiation is an important co-factor in the general population.

### 3.7.2 Conjunctival Cancer

#### Background

Squamous-cell carcinoma of the conjunctiva is a rare cancer of the ocular surface with an incidence rate that varies geographically from 0.02 to 3.5 per 100,000 depending on the latitude of the population studied (Sun et al. 1997; Yang and Foster 1997). The incidence of squamous-cell carcinoma of the conjunctiva has been estimated to be 8.4 per 10^6^ based on an analysis of the U.S. NIH-AARP Diet and Health study (Emmanuel et al. 2012).

#### Cohort and Case-control Studies

Three early case-control studies from Africa (Ateenyi-Agaba 1995; Kestelyn et al. 1990; Newton et al. 1995), reviewed by IARC (1996), reported statistically significant increases in risk of conjunctival cancer among HIV-1-positive cases of 8 to 13. Four cohort and two additional case-control studies were reviewed by IARC (2012a) (see summary Table 3-11), and two meta-analyses were identified since 2008. Case-control studies in African countries, reviewed by IARC (2012a) and based on a total of 158 cases, reported increased relative risks of 12 to 24 for conjunctival cancer in HIV-1-positive populations (Ateenyi-Agaba (1995); Kestelyn et al. (1990); Newton et al. (2001); Waddell et al. (1996); see IARC (2012a), Table 2.20), although one cohort study in Uganda involving 6 cases of conjunctival cancer reported a lower rate (SIR = 4.0, 95% CI = 1.5 to 8.7) SIR = 4.0, 95% CI = 1.5-8.7 (Mbulaiteye et al. 2006). In addition, three large cancer registry linkage studies of people with AIDS or HIV-1 in the United States (Frisch et al. 2000; Goedert and Coté 1995; Guech-Ongey et al. 2008) reported very similar age-, sex-, year- and/or race-adjusted relative risks of approximately 12 to 15, based on a total of 26 cases, rates that were almost identical to those observed in the African studies cited above. Incidence rates appear to have increased substantially around the period that the HIV-1 epidemic spread in these countries (IARC 2012a). In two meta-analyses conducted among studies up to 2013, Carreira et al. (2013) reported a meta-relative risk for ocular surface squamous-cell carcinoma of 8.1 (95% CI = 5.3 to 12.3), and Gichuhi et al. (2013) reported a meta-odds ratio of 6.2 (95% CI = 4.8 to 7.9) in association with HIV-1 infection. There are few data on the effects of antiretroviral treatment: one case study reported a regression of this cancer in a woman commensurate with beginning HAART and improved CD4 counts (Holkar et al. 2005), but a subsequent study in the United States (Guech-Ongey et al. 2008) reported a similar 12-fold increase in risk in both the pre-and post-HAART period.

Table 3-11 Summary of HIV-1/AIDS Cohort Studies of Conjunctival Cancer

| AIDS | HIV-1 Positive | AIDS or HIV-1 Positive
RR/SIR | 13–15 | _ | 4–12
Cohort size | 50,050–309,365 | _ | 12,607–491,048
No. cases | 4–7 | | 6–15
No. of studies | 2 | | 2

Source: IARC (2012a), Table 2.19 and Table 2.20.

All lower CI > 1.0.

#### Cofactors

The risk of squamous-cell carcinoma of the conjunctiva is higher in males and in whites and is correlated to ultraviolet radiation (Sun et al. 1997; Yang and Foster 1997); however, the interaction of ultraviolet light with HIV-1 status is unclear (IARC 2012a). In Africa, the incidence is rising rapidly in conjunction with the rising HIV/AIDS pandemic and is affecting young persons (around 35 years of age) and women; it is suggested that this increase is related to the co-existence of the HIV-1/AIDS pandemic, high human papillomavirus exposure, and solar radiation in the region. In the United States, squamous-cell carcinoma of the conjunctiva risk in persons with HIV-1/AIDS is higher in persons aged ≥50 years, of Hispanic ethnicity and who resided in the southern low altitude states (Guech-Ongey et al. 2008). Squamous-cell carcinoma of the conjunctiva has also been shown to be elevated in persons post kidney transplant, implicating immunosuppression (Vajdic et al. 2007).

Human papillomavirus infections of the conjunctiva of the eye are more common than previously appreciated (Angeletti et al. 2008; Ateenyi-Agaba et al. 2006; Mincione et al. 1992; Reszec and Sulkowski 2005; Tabrizi et al. 1997; Waddell et al. 2003).

No definitive role for co-infection with human papillomavirus of the mucosal type has been identified, but a role for co-infection with human papillomavirus of cutaneous types has been reported (Gichuhi et al. 2014). An approximately 3-fold increase in risk was associated with this human papillomavirus subtype in a meta-analysis (Carrieri et al. 2003). Smoking, allergies, vitamin A deficiency, and other risk factors do not appear to affect risk among HIV-1-positive populations (Gichuhi et al. 2013), but data are limited.

HAART does not appear to reduce the incidence of squamous-cell carcinoma of the conjunctiva (Guech-Ongey et al. 2008). SIRs in the pre- and post-HAART eras were similar at 12.0 (95% CI = 5.5 to 22.8) and 12.6 (95% CI = 4.6 to 27.4), respectively (P = 0.79). Holkar et al. (2005) reported, however, one case of ART causing tumor regression in an otherwise inoperable case.

### 3.7.3 Lung Cancer

In the United States, lung cancer incidence accounts for approximately 13% of new cancers, at an incidence rate of approximately 59 per 100,000, based on 2008 to 2012 rates (NCI 2015c). Lung cancer has a latency of approximately 20 years or longer and is now the leading cause of death among HIV-1-positive populations in the United States, accounting for almost 30% of cancer deaths.

#### Overview of Epidemiological Studies

Twenty-two cohort studies and one case-control study were reviewed by IARC (2012a) (excluding two small clinical follow-up studies). Since the IARC report, 24 additional cohort studies and 1 meta-analysis were identified. None of the studies reviewed by IARC controlled for smoking; but several cohorts since that time have considered smoking in their analyses. Table 3-12 includes both studies that have and have not controlled for smoking; studies that controlled for smoking are discussed in Table 3-13.

Table 3-12 Summary of HIV-1/AIDS Cohort Studies of Lung Cancer

| AIDS | HIV-1 Positive | AIDS or HIV-1 Positive
RR/SIR* | 1.63–3.9 | 1.28–8.9 | 1.1–15.9
Cohort size | 1,659–397,927 | 871–84,504 | 2,086–625,716
No. cases | 4–531 | 3–517 | 4–1,016
No. of studies | 9 | 18 | 21

Source: IARC (1996), IARC (2012a), Table 2.21, and studies since IARC (2012a): Albini et al. (2013); Bedimo et al. (2009); Castilho et al. (2015); Coghill et al. (2015); Crothers et al. (2011); Franceschi et al. (2010); Franzetti et al. (2013); Hleyhel et al. (2014); Levine et al. (2010); Park et al. (2014); Powles et al. (2009); (Raffetti et al. 2015); Seaberg et al. (2010); Sigel et al. (2012); Silverberg et al. (2011); Simard et al. (2010); van Leeuwen et al. (2009); Vogel et al. (2011).

* All lower 95% CI > 1.0 except Goedert et al. (1998), Grulich et al. (2002), Serraino et al. (2007), van Leeuwen et al. (2009), Silverberg et al. (2011), and Castilho et al. (2015) for Brazil subcohort.

Studies not reporting SIR or RR or which were outliers were excluded.

Table 3-13 Summary of HIV-1 Cohort Studies and Lung Cancer That Adjusted for Smoking

Reference Location | Design/Population/ Enrollment Dates | Smoking Methods
Phelps et al. (2001) USA | Prospective cohort: Incidence HIV-1-infected and HIV-1 uninfected women (with HIV-1 risk behavior) multicenter 1993–1995 | Similar smoking history in HIV-1+ and HIV-1– populations (>80%) Controlled for smoking use. CD4 counts, age
Engels et al. (2002b) Baltimore, USA | Retrospective cohort: Incidence Single clinic (Moore Clinic HIV-1); comparison Detroit 1989–2003 | Smoking data available for 1/3 of cohort Indirect adjustment by dividing the observed SIR by a bias factor Also calculated risk estimates using extreme scenarios (100% smoking and double RR for lung cancer and smoking)
Chaturvedi et al. (2007) | HIV-1/AIDS cancer match study: Incidence 1980–2002 | Modeling assuming 80% or 60% smokers
Kirk et al. (2007) | Prospective cohort: Mortality ALIVE cohort; HIV-1-infected (without AIDS) and HIV-1 injection drug users 1988–2000 | Smoking habits similar in HIV-1-infected and non-infected subjects (>80%) Adjusted for pack-yr/day; also conducted analysis or cumulative pack-yr.
Shiels et al. (2010) | Prospective cohort: Incidence ALIVE cohort (same as Kirk et al. 2007) 1988–2000 | Adjusted for average packs/day
Silverberg et al. (2011) | Health delivery system HIV-1 and non-HIV-1: Incidence 1980–2000 | Tobacco use higher in HIV-1-positive (42.5%) than non-HIV-1-infected subjects Adjusted for smoking at baseline (ever tobacco use), and alcohol/drug abuse, sex, age, race, overweight, calendar year and region
Sigel et al. (2012) | Veterans aging cohort/HIV-1 and non-HIV-1 infected: Incidence 1997–2008 | Smoking habits in HIV-1-infected (48%) and non-infected (46%) people were significantly different. Smoking status, adjusted for age, COPD, and bacterial pneumonia Sensitivity analysis overestimates smokers, i.e., all HIV-1 former and never smokers as current smokers and also stratified analysis by smoking status
Hessol et al. (2015) | WIHS (women) and MAC (men) USA; both HIV-1 and non-HIV-1 subjects: Incidence 1994–1995; 2001–2002 WIHS 1984–1985; 1987–1991; 2001–2003 MAC | Smoking pack-yr, Also adjusted for age, race, history of injection drug use, education level, BMI, and history of asthma, calendar time, HAART use, and prior clinical AIDS diagnosis

BMI = body mass index; COPD = chronic obstructive pulmonary disease; MAC = Multicenter AIDS Cohort Study; RR = relative risk; WIHS = Women Interagency HIV Study.

Most of the studies were conducted in the United States or Europe, spanning both the pre-and post-HAART era; together, the 48 studies reported SIRs or RRs ranging from 1.1 to 15.9, with most risks between 1.5 and 6. In a meta-analysis of cohorts in six countries by Grulich et al. (2007), the lung cancer risk among HIV-1-positive populations was 2.7 (95% CI = 1.9 to 3.9, 1,016 cases). A similar risk estimate (2.6, 95% CI = 2.1 to 3.1) was found in a 2009 meta-analysis of 13 studies (847 cases). This analysis also found higher risk in women (SIR = 3.8, 95% CI = 2.5 to 5.9, 6 studies) compared to men (SIR = 1.9, 95% CI = 1.4 to 2.7, 7 studies).

The effect of HAART on lung cancer rates appears to be limited, according to evidence from studies of individually treated patient populations. In the 2009 meta-analysis, SIRs were regressed based on HAART era, AIDS status, and sex. Statistically significant SIRs were found for both the pre-HAART era (SIR = 2.0; 95% CI = 1.2 to 3.3) and HAART era (SIR = 3.5, 95% CI = 2.6 to 4.6) although somewhat higher for the HAART era. Risks were also higher among patients with AIDS (SIR = 5.1, 95% CI = 4.0 to 6.4, 5 studies) compared with those without AIDS (SIR = 1.5, 95% CI = 0.82 to 2.6, 5 studies) and in women (SIR = 3.8, 95% CI = 2.5 to 5.9, 6 studies) compared to men (SIR = 1.9, 95% CI = 1.4 to 2.7, 7 studies).

A relationship between nadir CD4 or viral load and lung cancer risk has been reported in some studies but not others (Lambert et al. 2013; Winstone et al. 2013) (see Section 4 for a discussion on the relationship between immunosuppression, CD4 cells, and lung cancer).

#### Evaluation of Potential Confounding from Smoking

Many of the cohort or record-linkage studies calculated risk estimates (SIR) using expected numbers from the general population and did not have information on adjust for smoking. Because smoking is two to three times more prevalent among HIV-1-positive people (40% to 70%) compared with the general population in Western countries (~20% to 40%), there are concerns that the increases observed for lung cancer and HIV-1 infection could be explained by smoking. However, there are some differences between the profile of lung cancer observed in the HIV-1-positive population compared with cases in the general population; that is, lung cancer in the HIV-1-positive population is more frequently diagnosed when locally advanced or metastatic, diagnosed at a younger age, more aggressive with higher rates of relapse, and has a decreased progression-free survival time (Ruiz 2010). Although all major lung cancer subtypes are elevated, lung adenocarcinoma is the most prevalent subtype observed in the HIV-1-positive population (34% to ~50%) while small-cell carcinomas, which have a stronger association with smoking (Chaturvedi et al. 2007; Engels et al. 2006b; Lubin and Blot 1984), are observed in fewer cases (6% to ~9%) (Chaturvedi et al. 2007; Engels et al. 2006b).

The most informative studies for evaluating the relationship between HIV-1 and smoking are eight cohort studies (several published after the IARC review) that have calculated risk estimates in models that adjusted for or modeled smoking habits, using hypothetical smoking scenarios. The collective evidence from these studies is that smoking does not explain all the excess risk among HIV-1-positive people or people with AIDS, suggesting that HIV-1 might be an independent risk factor for lung cancer. Table 3-13 provides details on these studies and Figure 3-4 shows the risk estimates from these studies.

Figure 3-4

Relative Risks for Lung Cancer from Studies Adjusting for Smoking

Note: the forest plot does not contain the study by Chaturvedi et al. (2007) because that publication did not report risk estimates for the entire cohort.

Two studies modeled smoking bias using data from large cohorts. Chaturvedi et al. (2007), evaluated data from lung cancers among people with AIDS from the HIV/AIDS Cancer Match Study in the United States, and found statistically significant predicted lung cancer risks for men 59 years or younger and women 49 years or younger but not among older age groups in models assuming 80% and 60% smoking; no predicted risk estimates were reported for the entire cohort. Engels et al. (2006a) also found statistically significant risks for lung cancer after indirectly adjusting for smoking using a smoking bias factor based on smoking data for a subset of the HIV-1 cohort from a large urban clinic. The findings remain robust in analyses assuming extreme scenarios, 100% smoking and double the risk of lung cancer from smoking. However, in the absence of individual smoking data, residual confounding from smoking cannot be completely ruled out.

The remaining six studies calculated lung cancer risk using HIV-1-uninfected subjects as the comparison group and adjusted for smoking using data on individual smoking behaviors. In smoking-adjusted analyses, five of the six studies found elevated risks for lung cancer, four of which were statistically significant elevated risks for lung, providing limited evidence for an association between HIV-1 infection and lung cancer. The fifth study, which reported a statistically non-significant increase in smoking-adjusted lung cancer risk, had inadequate statistical power because of small numbers of HIV-1 infected cases (Phelps et al. 2001). The strength of the evidence is based on these factors: (1) three studies adjusted for smoking using quantitative measures of smoking (i.e., the amount smoked per day or over time), which is considered to be more informative (i.e., greater confidence in ruling out residual confounding) than analyses using qualitative smoking data (e.g., smoking status or ever use of tobacco) (Hessol et al. 2015; Kirk et al. 2007; Shiels et al. 2011a); (2) studies were conducted in different populations, e.g., men and women veterans, injection drug users (see Table 3-13); (3) studies included both incidence and mortality data (Kirk et al. 2007; Shiels et al. 2011a); (4) one study had large numbers of HIV-1-infected cases (Sigel et al. 2012); and (5) in a study that conducted a sensitivity analysis overestimating smoking status (i.e., assumed all HIV-1 infected persons were smokers), the relative risk remained significant, albeit attenuated (IRR = 1.2, 95% CI = 1.1 to 1.4), and an elevated risk, which approached significance, was found among non-smokers (Sigel et al. 2012).

The limitations of this database include the fact that the number of studies is limited and there are relatively small numbers of cases in most studies; two studies evaluated mortality and incidence in the same cohort (ALIVE Cohort). Silverberg et al. (2011) found only a small, statistically non-significant, smoking-adjusted RR in a cohort of HIV-1-infected and uninfected patients based on insurance data, suggesting that smoking may explain the excess risk. Advantages of this study are the large number of subjects; however, in the analyses for adjusting for smoking, baseline ever use of tobacco was somewhat limited and the study adjusted for variables that have not been clearly linked to lung cancer risk (e.g., overweight and alcohol use). In addition, the study found statistically significant smoking-adjusted RRs (~2-fold) among subjects with the highest HIV-1 RNA titer (>10,000 copies/mL) or lowest CD4 cells levels (≤ 200 cells/μL). Overall, provides some limited support for the conclusion that the excess lung cancer risk among HIV-1-infected populations is not entirely explained by smoking.

AIDS-related pneumonia has been investigated as a risk factor for lung damage and lung cancer with unclear findings. The combined analysis of the Women’s Interagency HIV Study (WIHS) and the Multicenter AIDS Cohort Study (MACS) cohorts found the highest risk of lung cancer among HIV-1 patients with AIDS-related pneumonia damage. This finding was observed throughout the full follow-up period, as well as when the analysis was restricted to the HAART era, suggesting that the HIV-1-related pulmonary damage and inflammation may be responsible for the excess lung cancer. A nested case-control study within the HIV-1 cohort did not find an association with history of AIDS and pulmonary disease after adjusting for smoking; all cases and controls in the study were HIV-1 positive in this study (Clifford et al. 2012).

## 3.8 Cancer Burden from HIV from All Cancers

As mentioned in the introduction, the NTP evaluation was based on the body of evidence from an authoritative evaluation by IARC (2012a), and thus the NTP evaluation was focused on those cancer endpoints that IARC considered in its evaluation. There is evidence that HIV-1/AIDS-infected individuals have higher cancer incidence for many cancer endpoints compared with the general public (Robbins et al. 2015), and the estimated number of cases of non-AIDS-defining cancers in the United States has increased by approximately 3-fold from the pre-HAART era (1991 to 1995) to the post-HAART era (2001 to 2005) as the population of HIV-1-infected individuals expands and ages (Shiels et al. 2011a). An important part of the cancer burden (approximately 29% in 34 U.S. states) occurs in people with HIV-1 only. In a large meta-analysis, the risk of developing a non-AIDS-defining cancer was 2-fold greater in HIV-1-positive individuals compared with the general population and was greater in men than in women; however, no substantial differences were observed by HAART era (Shiels et al. 2009).

Due largely to HAART therapy, non-AIDS-defining malignancies now account for more morbidity and mortality than AIDS-defining malignancies (Silverberg and Abrams 2007). The risks for Hodgkin lymphoma, lung cancer, anogenital cancer, oral-related cancer, liver cancer, and non-melanoma skin cancers in the HIV-1-positive population are substantial or increasing and account for about half of the non-AIDS-defining cancers reported in the United States (Shiels et al. 2011a). However, it is not clear for some endpoints whether the increases in these cancers are related to HIV-1 infection or other behaviors or confounders that might be more common in HIV-1-infected individuals compared with the general public.

The 2009 meta-analysis by Shiels et al. (2009) of non-AIDS-defining cancer and HIV-1 infection or AIDS also found statistically significant increases in risk for cancer endpoints not evaluated in the monograph (such as melanoma, kidney, stomach, brain, testes, oropharynx, leukemia, and multiple myeloma (now called plasma-cell myeloma), which were all based on more than 70 cases and at least three studies) in addition to the sites evaluated in the monograph. Further, newer cohort studies published since 2009 (those listed in Table 3-1) appear to have a pattern of findings consistent with those reported by Shiels et al. (2009). Risk estimates for most cancer endpoints were between 1.0 and 2.0; little was known about potential confounders and there was evidence of heterogeneity across studies. A subsequent meta-analysis found a statistically significant meta-risk for melanoma and HIV-1 infection or AIDS of 1.50 (95% CI = 1.12 to 2.01) among studies that controlled for ethnicity in the post-HAART era (Olsen et al. 2014).

Many of the newer cancer endpoints identified in the Shiels et al. (2009) analysis are ones that are not thought to be related to co-infection with other viruses, and several studies have calculated risk estimates for groups of cancers. For example, Albini et al. (2013) found that HIV-1-infected individuals had approximately twofold increased risk of non-AIDS-related cancers not related to viral infection compared with the general population. A study in Denmark found that HIV-1-infected individuals had almost threefold elevated risk collectively of smoking-related cancers (primarily lung and head and neck combined) after adjusting for smoking (Helleberg et al. 2015). However, the latter analysis combined specific cancers with increased and decreased risks, and in the Shiels et al. (2009) meta-analysis cancers with elevated risks (such as leukemia and multiple myeloma) were not included. An Italian study (Franzetti et al. 2013) has also found an increase in non-AIDS\-related cancers (as a group) as well as an increase in the spectrum of cancer endpoints.

Robbins et al. (2015) estimated that the excess cancer burden in the United States in 2010 (over 3,900 cases), of which 54% were AIDS-defining cancers (which were reviewed in the IARC 2012a monograph), and 46% were non-AIDS-defining, of which most were from lung, liver, and Hodgkin lymphoma (which are reviewed in this monograph). While it is beyond the scope of the monograph to evaluate all cancer endpoints potentially associated with HIV-1/AIDS infection, this evaluation considered endpoints thought to contribute to greater than 90% of the excess cancer risk.

## 3.9 HAART and Treatments for Opportunistic Infections

The number of antiretroviral drugs used to treat HIV-1 infection has increased substantially over the past 30 years. Few data are available pertaining to the potential carcinogenicity of these drugs or of a wide array of pharmaceutical and other therapies used in the treatment of specific opportunistic infections, particularly after long-term use. In studies in experimental animals, 3′-azido-3′-deoxythymidine has been shown to induce chromosomal damage, gene mutations, and cancer following direct or transplacental exposures (Witt et al. 2007). In addition, elevated frequencies of micronucleated red blood cells were found in human infants exposed in utero to 3′-azido-3′-deoxythymidine (Witt et al. 2007). NTP (2013b; 2013c) reported that 3′-azido-3′-deoxythymidine alone or in combination produced liver cancer in the male offspring. In a NTP in utero and postnatal cancer study, a mixture of 3′-azido-3′-deoxythymidine, lamivudine (also called 3TC), and nevirapine produced an increased incidence of subcutaneous skin neoplasms in male B6C3F_1_ offspring (NTP 2013a). IARC (2000) has classified zidovudine (also known as azidothymidine or AZT) and zalcitabine (also known as dideoxycytidine or DDC) as possibly carcinogenic to humans based on sufficient evidence in animals.

In human studies, a U.K. study of cancer outcomes among people with AIDS or HIV-1 reported an increase in non-AIDS-defining cancers, particularly Hodgkin lymphoma, among people with AIDS or HIV-1 treated with non-nucleoside reverse transcriptase inhibitors, which include nevirapine (Powles et al. 2009). However, Chao et al. (2012) reported no increased risk in non-AIDS-defining cancers among HIV-1-positive users of non-nucleoside reverse transcriptase inhibitors, although in this paper long-term use of protease inhibitors were linked with a marginally increased risk of anal cancer, but not with any other non-AIDS-defining cancers. Bruyand et al. (2015) found no increased risk of lung cancer among persons with HIV who smoked and used protease inhibitors. Thus, at this time, data are insufficient to conclude that either non-nucleoside reverse transcriptase inhibitors or protease inhibitors are associated with increased risk of non-AIDS-defining cancers in HIV-1-positive persons.

## 3.10 Summary and Integration across Cancer Endpoints

A large body of cohort studies, including some very large prospective cohorts of HIV-1-positive and AIDS patients followed up for cancer incidence from the early AIDS epidemic onwards, are available to evaluate the association of HIV-1 and cancer endpoints. A smaller number of case-control studies have also been conducted on specific cancer endpoints. Indirect evidence of the effect of HIV-1 on cancer risk can also be evaluated from studies comparing HAART to non-HAART-treated groups or pre- to established HAART era cohorts, but complicating factors include a higher prevalence of traditional cancer risk factors (e.g., smoking, alcohol use) among those infected with HIV-1; an increased age-related cancer incidence associated with the increased lifespan of the HIV-1-positive population treated with HAART; limited data on the mutagenicity or carcinogenicity of the multiple drugs used in HAART (i.e., conflicting data that some HAART agents or classes may be associated with cancer); differences or changes in screening practices for HIV-1-related disease; and limited data on the seroprevalence of oncogenic viruses in HIV-positive populations (Borges et al. 2013; Kesselring et al. 2011; Shiels et al. 2011a), which might account for some observed differences in risk over time. In addition, the time of starting and duration of antiretroviral treatment might affect cancer risk.

AIDS-defining malignancies are included in the broader category of AIDS-defining clinical conditions and include Kaposi sarcoma, non-Hodgkin lymphoma, and invasive cervical cancer (CDC 1985; 1992; Schneider et al. 2008). Non-AIDS-defining cancers include a broad spectrum of neoplasms for which HIV-1-positive persons have an elevated risk and for which HIV-1 infection may play an etiologic role (Engels 2009). These neoplasms represent an increasingly important source of morbidity and mortality in the HIV-1-positive population. Non-AIDS-defining cancers have been grouped according to whether they are “infection related” (or not) (Gopal et al. 2014; Patel et al. 2014). There are limitations to this classification scheme (Gopal et al. 2014), in large part due to etiologic heterogeneity within groups (for example, cervical cancer is classified as an AIDS-defining cancer while anal cancer is not, despite etiologic commonalities) and secondly because, while some oncoviruses (e.g., Kaposi-sarcoma-associated herpesvirus) are closely associated with specific cancers in HIV-1-infected populations, some (e.g., Epstein-Barr virus) are associated only with a proportion of specific cancer types. In addition, relatively few studies of HIV-1/AIDS populations have been conducted using valid and reliable panels of serological or pathological tests for other oncoviruses.

### 3.10.1 Infection-related Cancers including AIDS-defining Malignancies

Approximately 40% (95% CI = 39 to 42) of cancer cases occurring in HIV-infected people in the United States are attributable to infectious agents compared with 4% in the general U.S. population (de Martel et al. 2015). Kaposi sarcoma, non-Hodgkin lymphoma, and, especially in men, anal cancer are the most important of these. In contrast, in the general U.S. population, infection-related cancers are largely noncardia gastric, liver, and cervical cancers.

There is consistent evidence from a large body of cohort and case-control studies that HIV-1 substantially increases the risk of the three cancers classified as AIDS-defining: Kaposi sarcoma in Kaposi sarcoma-associated virus-infected populations (also see accompanying monograph on Kaposi sarcoma-associated virus); non-Hodgkin lymphoma, in particular primary central nervous system lymphoma, and Burkitt lymphoma, in some cases in association with Epstein-Barr virus (see also accompanying monograph on Epstein-Barr virus); and cervical cancer in human papillomavirus-infected populations.

In addition, there is consistent evidence that HIV-1 infection increases the risk of anal and other genital cancers in association with human papillomavirus co-infection, and Hodgkin lymphoma, associated with Epstein-Barr virus co-infection. While there is consistent evidence that HIV-1 infection increases the risk of hepatocellular carcinoma, concerns remain as to the extent to which hepatitis B or C virus is a co-factor or confounder of the observed associations. In most studies the seroprevalence of hepatitis B or C virus among HIV-1/AIDS individuals is not measured, but in those that have measured hepatitis C virus, individuals with hepatitis C virus and cirrhosis were twice as likely to develop hepatocellular carcinoma than those co-infected with hepatitis C virus and HIV-1.

Modest positive associations are found between HIV-1 and oral-related cancers; however, the heterogeneity of these cancers, as well as the unmeasured heterogeneity of risk factors, and potentially distinct etiologic pathways for oral-related cancer subtypes complicate the interpretation of these modest risks. However, based on limited evidence from natural history studies, HIV-1 may increase the risk of becoming infected with human papillomavirus or having a recurrence.

Since the widespread introduction of HAART, the spectrum and pattern of a number of cancers associated with HIV-1 infection has changed considerably (IARC 2012a).Although the estimated number of all AIDS-defining infection-related cancers decreased by approximately 3-fold following HAART therapy, the risk of Kaposi sarcoma (3,640-fold), non-Hodgkin lymphoma (77-fold), and cervical cancer (6-fold) remained significantly increased in AIDS patients compared with the general population (Shiels et al. 2011b). Among other, non-AIDS-defining infection-related cancers, up to a 3-fold upward trend in Hodgkin lymphoma has been observed over the HAART era and the patterns for cancer of the liver and anus are not clear.

A summary of the range of risks for selected cancers with other viruses as cofactors is presented in Table 3-14, below.

Table 3-14 Summary of Risk Estimates and Effects of HAART for Selected Viral-related Cancers in HIV-1-positive Populations

Cancer | Viral Co-factor | Prevalence in HIV-1-Associated Tumors (%) | Range of Relative Risks in HIV/AIDS vs. HIV-1-Negative Populations | Effect of HAART on Risk of Cancer
Cervix | HPV | 100 | 2–22 | ← →
Anus | HPV | >90 | 10–100 | ↑
Kaposi sarcoma | KSHV | 100 | 100–10,000s | ↓
NHL (all) | EBV/KSHV | Varies by subtype* | 10–300 | ↓overall but varies by subtype*
Hodgkin lymphoma (all) | EBV | >80 | 4–38 | ↑
Oral-related cancer | HPV | 65 | 2–4^a^ | ← →
Liver (HCC) | HBV/HCV | >90 | 2–16 | ← →

Columns 1–3 from Table 1 in Gopal et al. (2014); range of relative risks (excluding extreme outliers) and HAART effects are summarized from present monograph.

EBV = Epstein-Barr virus; HBV = hepatitis B virus; HCC = hepatocellular carcinoma; HCV = hepatitis C virus; HPV = human papillomavirus; KSHV = Kaposi sarcoma-associated herpesvirus; NHL = non-Hodgkin lymphoma. ↑ = risk increase in HAART era; ↓ = risk decrease in HAART era; ← → = no overall change or inconsistent change in risk in HAART era.

* For NHL subtypes, risks of diffuse large B-cell primary CNS lymphoma and immunoblastic lymphoma have decreased, but Burkitt lymphoma risk remains unchanged.

^a^ Some oral-related cancer sites including tonsil/tongue have been associated with risks in the range of 11 to 22.

### 3.10.2 Other Cancers Not Known to Be Infection Related

There is consistent evidence of a 6 to 8-fold increase in conjunctival cancer in HIV-1-positive populations, primarily in African countries, based on a limited number of studies; ambient ultraviolet light has been postulated as a co-factor. There is also consistent evidence for an association with lung cancer based on numerous studies showing statistically significant increases of 1.5 to 6 in lung cancer. Smoking prevalence is higher within the HIV-1 population and explains part of the risk; however, studies controlling for smoking or modeling smoking have found a 2-fold increase suggesting that smoking does not explain all the excess risk. Statistically significant increased risks of non-melanoma skin cancers among HIV-1-infected individuals have also been reported in numerous cohort studies. A meta-analysis (Zhao et al. 2015) on six studies, published between 2003 and 2013, that collected data on cancer incidence through cancer registries to ensure unbiased comparisons of the incidence rates from the cohorts and the general population, found a risk estimate of 2.76 (95% CI = 2.55 to 2.98).