# 2 Human Exposure

This section discusses transmission and prevalence (Section 2.1) and non-cancer diseases, prevention, and treatment for HIV-1 infection (Section 2.2).

## 2.1 Transmission and Prevalence

In infected people, blood, semen, and vaginal fluids contain measurable quantities of HIV-1; other body fluids, including saliva, urine, sweat, and tears, contain negligible amounts of HIV-1 (unless contaminated by blood) (IARC 1996; IARC 2012a). The transmission of HIV-1 infection occurs by direct blood-to-blood transmission or from blood or infected body fluids via mucous membranes into the bloodstream. Vertical transmission between HIV-1-infected mothers and neonates occurs in utero and via contamination of the neonate’s mucous membranes during the birth, and/or via infected breast milk during lactation. In infected women not treated with antiretroviral prophylaxis, an estimated 15% to 25% of infants may be born with HIV-1 infection; breastfeeding may increase that risk by another 5% to 20% (Newell and Thorne 2004). Horizontal transmission occurs primarily during sexual activity, i.e., oral, anal, and vaginal sex, in which HIV-1 in infected sexual fluids crosses mucous membranes to enter the bloodstream; and by direct blood-to-blood transmission, primarily via sharing of infected needles among injection drug users, or more rarely by percutaneous transmission via, e.g., needlestick injury, or via the transfusion of infected blood (depending on the availability of effective blood supply screening programs) (IARC 2012a). Non-sexual mucous membrane or non-intact skin contact with infected blood or body fluids in, e.g., occupational healthcare or first responder settings (e.g. CDC 1987; Ippolito et al. 1999; Leiss et al. 2006) may also increase exposure and the potential risk of HIV-1 transmission, although the actual risk of infection from percutaneous or mucous membrane exposure is estimated to be less than 1% (Cardo et al. 1997).

In resource-rich countries, the two primary behavioral risk factors for transmission are the practice of unprotected sex (i.e., particularly unprotected anal sex), and the sharing of drug needles. The relative importance of these factors varies widely geographically as a function of differences in sexual practices, prevalence of injecting drug use, screening practices for the transfusion blood supply and blood donors, and the extent and effectiveness of deployed education and prevention strategies.

However, other risk factors are salient for the two-thirds of adults with HIV-1 infection living in sub-Saharan countries (UNAIDS 2013b). Unlike resource-rich countries, well over half of those infected are women, largely as a result of the high rate of multiple partners among men, and the practice of polygyny (Reniers and Watkins 2010). In addition, in contrast to North America and Europe, mother-to-child transmission, perinatally or via breastfeeding, accounts for a high proportion of HIV-1 infections (IARC 1996; IARC 2012a; UN 2001); and unsafe medical practices (e.g., injection practices), may also account for a higher proportion of infections (e.g., (IARC 2012a; Zetola et al. 2009).

Other risk factors for HIV-1 infection globally include other sexually transmitted infections, e.g., chlamydia and gonorrhea, which can increase the risk of sexually transmitted HIV-1 infection, in part by causing inflammation or rupture of mucous membranes in the vagina, vulva, penis, or anus. However, treatment or prevention interventions for other sexually transmitted diseases do not always result in decreases in HIV-1 infection rates (see review by (Ng et al. 2011)). Other risk factors include circumcision, hormonal factors, and host immune and genetic factors (IARC 1996; IARC 2012a).

Approximately 37 million people worldwide are infected with HIV-1 and approximately 2 million were newly infected in 2013, a decline of about one-third in new infections from 2001 to 2012). There were an estimated 1.6 million AIDS-related deaths worldwide in 2012 (UNAIDS 2013c). Although subject to some uncertainty due to variations in HIV-1 screening and testing programs, the reported current prevalence and incidence of HIV-1 infection show considerable variation worldwide (Table 2-1).

Table 2-1 Global Prevalence and Incidence of HIV-1 Infection in 2014

Region | HIV-1 Prevalence | HIV-1 Incidence | Adult Prevalence Rate (%)
Sub-Saharan Africa | 25.8 million (70%) | 1.4 million | 4.8
Asia and Pacific | 5.0 million (14%) | 340,000 | 0.2
Western/Central Europe and North America | 2.4 million (7%) | 85,000 | 0.3
Latin America | 1.7 million (5%) | 87,000 | 0.4
Eastern Europe and Central Asia | 1.5 million (4%) | 140,000 | 0.9
Caribbean | 280,000 (<1%) | 13,000 | 1.1
Middle East and North Africa | 240,000 (<1%) | 22,000 | 0.1
TOTAL | 36.9 million | 2.0 million | 0.8

Source: Kaiser Family Foundation (2015).

Data from UNAIDS Global AIDS Report 2014 (2013b).

The current U.S. prevalence of HIV-1 infection is approximately 1.2 million, of which an estimated 13% are unaware of their infection status (CDC 2015a) (which can be confirmed by standardized testing protocols such as those recommended by the CDC (2006)). Approximately 47,350 people were newly infected with HIV-1 in 2013 (CDC 2015a). A total of approximately 660,000 people with an AIDS diagnosis have died since the start of the epidemic in 1981.

## 2.2 Diseases, Prevention, and Treatment

Acquired immune deficiency syndrome (AIDS) typically results from long-term untreated HIV-1 infection. The WHO classification (WHO 2007) is based on four clinical stages from primary HIV-1 infection to AIDS. Criteria for defining a confirmed case have been recently updated given new multi-test algorithms and the need to recognize early HIV infection (CDC 2014c). Cases are currently classified as Stage 0 through 3, with Stage 0 being early infection, recognized by a negative HIV test within 6 months of HIV diagnosis; and Stage 3 being AIDS. This surveillance case definition is intended primarily for monitoring the HIV infection burden, not as a basis for clinical decisions for individual patients. However, studies included in this review have not used this case definition, and therefore, this review will not refer to this staging classification.

The CDC (2015b) has identified a list of the most common opportunistic infections or related conditions for individuals living in the United States that are used to diagnose AIDS. The opportunistic infections occur more frequently and are more severe in individuals with weakened immune systems, including people with HIV-1 infection or a CD4 count of <200/μL. Among non-cancer diseases, the most common are opportunistic infections including candidiasis, Pneumocystis jirovecii, cytomegalovirus disease, tuberculosis, toxoplasmosis, histoplasmosis, mycobacterium avian complex, cryptococcosis and cryptosporidiosis, which are associated with a decrease in CD4 cells and the resulting impairment of immune function. A number of AIDS-related diseases are associated with viruses or other infections, for example, human papillomavirus, herpes simplex or herpes zoster virus, cytomegalovirus, hepatitis B or C virus, Epstein-Barr virus, or Kaposi sarcoma-associated herpesvirus (CDC 2015b; IARC 1996; IARC 2012a). Hepatitis C virus infection, primarily transmitted via injection drug use, and also transmitted via sexual fluids, is estimated to occur among 25% to 30% and hepatitis B virus among 6% to 14% of HIV-1-positive people (Alter 2006). Tuberculosis, caused by Mycobacterium tuberculosis, is a common disease and co-infection, particularly in sub-Saharan Africa and other resource-constrained countries (IARC 1996). Chronic conditions, including HIV-1-associated nephropathy, diabetes, and cardiovascular disease, may also be more common among HIV-1-infected people compared with non-infected populations, although part of this increase in risk may result from long-term treatment with antiretroviral drugs rather than HIV-1 infection per se (Feeney and Mallon 2011).

Since the primary mode of HIV-1 transmission in most populations is unprotected sex, behavioral risk reduction strategies have focused on education about safer sex practices, ranging from abstinence to consistent condom use, and testing for HIV-1 status. In addition, blood-to-blood transmission risk can be decreased by education about the risk of infection from mucous membrane, percutaneous, and intravenous contact with infected fresh blood, and by the use of clean needles, particularly among high-risk populations, including sex workers, injection drug users, and infected pregnant mothers (CDC 2015d).

Effective screening of the blood supply has also reduced infection rates, along with increased penetration of HIV-1 testing programs using rapid tests (CDC 2006). Condom distribution and needle exchange programs have been instituted in some populations. The CDC reports that early HIV-1 treatment has a profound prevention benefit with 96% reduction in the risk of transmitting HIV-1 to an uninfected partner with early initiation of antiretroviral therapy (CDC 2016). Short-term post-exposure prophylaxis in which specific antiretroviral drugs are taken within 72 hours after a high-risk episode, such as sexual assault, or an accidental needlestick injury, can be instituted to prevent the establishment of HIV-1 infection, and prophylactic prevention of mother-to-child transmission including antiretroviral drugs and related precautions have been instituted (CDC 2014d). In addition, pre-exposure prophylaxis, in which uninfected high-risk subgroups take antiretroviral drugs (tenofovir disoproxil fumarate and emtricitabine) on a daily basis and are tested regularly, has undergone clinical trials in the United States and is now recommended for specific at-risk populations (CDC 2014a). Mother-to-child HIV-1 transmission risk has been greatly reduced, in some cases from up to 48% to under 2% (Newell and Thorne 2004) by the use of antiretroviral drug administration to the mother in the pre-labor and breastfeeding period and beyond, and to the infant in the immediate postnatal period and up to 14 weeks among breastfed infants (e.g., with nevirapine in combination with zidovudine), combined with Cesarean delivery in some populations; the latter can reduce infection by up to 70% (European Mode of Delivery Collaboration 1999). Updated recommendations for the prevention of mother-to-child transmission have been made by the Centers for Disease Control (CDC) (CDC 2014d).

Finally, a substantial international effort to develop an effective vaccine for HIV-1 has been made but has proved challenging (Wang et al. 2015) and no prophylactic or therapeutic vaccine is currently available (NIAID 2015).

Treatment to suppress the viral load of HIV-1 consists of five main classes of antiretroviral drugs: fusion or entry inhibitors, integrase inhibitors, protease inhibitors, nucleoside/nucleotide reverse transcriptase inhibitor, and non-nucleotide reverse transcriptase inhibitors, which are designed to block different steps in the HIV-1 replication cycle described above (Avert.org 2015a; 2015b). Two or more of these drugs, with at least two from different classes of compounds, are used in various combinations designed to disrupt viral replication at more than one stage.

Over 20 antiretroviral drugs have been developed since the development of the nucleoside reverse transcriptase inhibitor zidovudine (azidothymidine) in the mid to late 1980s (Avert.org 2015b) followed by the nucleoside reverse transcriptase inhibitors didanosine and stavudine in the early 1990s and lamivudine in 1995. These drugs were shown to be more effective in combination with zidovudine than administered alone. In 1995, the first protease inhibitor (saquinavir) was approved in the United States by the U.S. Food and Drug Administration (FDA), and in combination with one or two of the nucleoside reverse transcriptase inhibitors were considerably more effective in suppressing HIV-1 drug-resistant mutation than nucleoside reverse transcriptase inhibitors alone and thus delaying the onset of AIDS. These combination drugs are called highly active antiretroviral therapies (HAART) or combination antiretroviral therapy (cART) and are now incorporated into standard treatment guidelines (e.g. DHHS 2015b).

Currently, WHO (2013) recommends as a first-line treatment for adults and adolescents one fixed dose daily pill containing two nucleoside reverse transcriptase inhibitors (tenofovir, and lamivudine or emtricitabine) and one non-nucleoside reverse transcriptase inhibitor (efavirenz). However, the availability of antiretroviral therapies, particularly the new generation of drugs, varies widely across the world (UNAIDS 2013a).

## 2.3 Summary

HIV-1 infection has become a global epidemic since its identification in the early 1980s, with approximately 35 million people currently infected worldwide. In the United States, approximately 1.2 million people are currently infected, representing less than 0.5% of the population, and the incidence rate has remained stable over the past decade. Transmission is primarily via blood-to-blood and sexual fluid-to-blood transmission, mostly by anal, oral, and vaginal sex; vertical transmission from mother-to-child also occurs prenatally, during birth, or via breast milk. Occupational or iatrogenic exposure via percutaneous or mucous membrane exposure to blood or transfusion of unscreened blood, organs, or blood products also occurs, although very rarely in countries with effective prevention strategies. Populations at highest risk of infection vary considerably globally, with men who have sex with men and injection drug users forming the highest risk groups in the United States, whereas women may have a higher rate of infection than men in, for example, some southern African countries. Untreated HIV-1 infection usually results in severe immune deficiency and AIDS, typically several years after initial infection. However, effective risk reduction prevention strategies, HIV-1 screening and testing practices, post-exposure prophylaxis, and highly effective antiretroviral therapies have reduced rates of both person-to-person and mother-to-child transmission and morbidity and mortality from HIV-associated diseases in resource-rich countries, although less successfully in other countries. While HIV-1 infection may now be considered a chronic, manageable condition, infection is permanent, and efforts to develop a vaccine have thus far been unsuccessful.