# 1 Properties and Detection

This section reviews the biological properties (Section 1.1) and detection methods (Section 1.2) for human immunodeficiency virus type 1 (HIV-1).

## 1.1 Biological Properties

The following section reviews the types of HIV, its structure, life cycle, and course of infection.

### 1.1.1 Family and Type

HIV-1 was first isolated in 1983 and was associated with acquired immunodeficiency syndrome (AIDS) the following year (IARC 2012a). A second type, HIV-2, is geographically limited to West Africa and is less pathogenic than HIV-1 which is distributed worldwide (De Cock et al. 1991; IARC 2012a). HIV-1 and HIV-2 are enveloped RNA viruses of the family Retroviridae, under the Orthoretrovirinae subfamily, in the genus Lentivirus, characterized by a long period between infection and symptomatic disease. HIV-2 is less transmissible than HIV-1 and is characterized by a slower progression of disease (IARC 2012a).

### 1.1.2 Viral Structure and Genome

The HIV-1 virion (120 nm diameter) is composed of a lipid membrane envelope with two surface proteins (gp120 and gp41), which surrounds a protein matrix, inside which is a protein capsid containing two copies of the viral single-stranded RNA (ssRNA) genome (9.8 kb) and the enzymes reverse transcriptase, integrase, and protease (see Figure 1-1) (IARC 2012a). The lipid membrane envelope is created by budding off the host cell membrane, and viral glycoproteins are situated with gp41 spanning the lipid membrane and gp120 binding to the exterior portion of gp41. The protein gp120 binds to CD4 on T cells, imparting tropism for those cells. RNA is normally very sensitive to degradation by nuclease enzymes, but the HIV-1 genome binds to nucleocapsid proteins (p6 and p7) that inhibit nuclease enzymes. The capsid is made from the p24 protein and the matrix is made from the p17 protein. Aside from these structural proteins there are three enzymes within the capsid (reverse transcriptase, integrase, and protease) and proteins Vif, Vpr, and Nef; the Vif and Vpr proteins help support viral replication and Nef is a regulatory protein that increases virulence.

Figure 1-1

Human Immunodeficiency Virion Structure

Source: NIAID (2009). Courtesy: National Institute of Allergy and Infectious Diseases.

The HIV-1 genome is 9.8 kb long and contains three major genes, which encode multiple proteins, and six genes that encode single proteins, all of which are flanked by two long terminal repeats (LTRs) (see Figure 1-2) (IARC 1996; 2012a). The three main genes are gag, pol, and env. The gag gene produces the matrix protein (p17), viral capsid protein (p24), and two nucleocapsid proteins (p6 and p7). The pol gene produces reverse transcriptase, integrase, and protease; the protease is used to cleave gag and pol proteins into the individual proteins. The third main gene, env, encodes the two envelope proteins gp41 and gp120. The single protein genes include regulatory proteins tat and rev and accessory proteins nef, vif, vpu, and vpr. Viral gene expression is controlled by promoters and enhancers in the two long terminal repeat regions.

Figure 1-2

Human Immunodeficiency Virus Genome Structure

Source: IARC (2012a).

### 1.1.3 Life Cycle and Course of Infection

The life cycle of the virus begins with binding of the viral gp120 protein to CD4 on helper T cells (see Figure 1-3) (IARC 1996; 2012a). A co-receptor CCR5 or CXCR4 on the CD4 T-cell is also needed. Binding allows the viral envelope to fuse with the cell membrane, releasing the contents into the cell’s cytoplasm. Inside the cytoplasm, the matrix and capsid fall apart and release the ssRNA genome and viral enzymes. Reverse transcriptase enzyme reads the RNA and polymerizes a complementary DNA strand. The DNA/RNA genome is then used to replicate a double-stranded DNA (dsDNA) genome. Reverse transcriptase is an error-prone DNA polymerase and introduces random mutations into the viral genome. Integrase then binds the dsDNA genome and travels to the nucleus where it integrates into the host genome, forming a stable infection. The virus can then remain latent and evade immune detection by several mechanisms, including tat- and nef-mediated suppression of major histocompatibility complex I (MHC I) expression so that CD8 T cells cannot “see” the virus or by disruption of nearby immune cells through the secretion of tat and nef proteins. During the lytic phase, viral structural genes and enzymes are expressed and ssRNA genomes are produced and bud off the cell membrane to form immature enveloped virions. Envelope proteins travel to the host cell surface through the endoplasmic reticulum. The virion then matures as the protease cleaves precursor proteins (gag and pol) into their individual proteins so they can form the matrix and capsid. CD4 cells are directly killed in large numbers or indirectly via HIV-1 disruption of cell regulation followed by apoptosis.

Figure 1-3

HIV-1 Replication Cycle

Source: NIAID (2009). Courtesy: National Institute of Allergy and Infectious Diseases.

HIV-1 can also infect other cells of the immune system, including B cells and monocytes and macrophages; these cells are long-lived and are not killed as a result of viral penetration and thus act as one of the body’s reservoirs of HIV-1 infection. Other reservoirs include follicular dendritic cells within lymph nodes, tonsils, adenoids, and mucosa-associated lymphoid tissue (IARC 2012a).

In the symptomatic acute phase of infection, flu-like symptoms are experienced by the majority of people, typically within two to four weeks after initial infection. During the acute phase, which lasts 10 to 12 weeks, viral load and infectiousness are extremely high, with over 20 times the sexual transmission rate compared with that of the established infection period (CDC 2014b). The immune system responds with increased production of CD8 (killer) T cells and B-cell antibodies, which kill infected CD4 cells (along with other cells with HIV-1 on the cell surface), resulting in a fall in HIV-1 titers. After this acute phase, HIV-1 remains at low levels in the blood, but continues to replicate and mutate, mostly in lymphoid tissue. HIV-1 integrated into the host genome can remain undetected and can get carried to the brain by infected monocytes and macrophages that are not killed by the virus. Most untreated individuals are latently infected for an average of 10 to 12 years before symptoms of HIV-1-related diseases appear, although the latency range varies from about 2 to over 25 years (DHHS 2015b). Several prospective studies have shown that the viral load (also referred to as the viral “set point”) occurring within 6 months to a year after infection predicts strongly for the later risk of disease progression (DHHS 2015b).

## 1.2 Detection

HIV-1 has been detected primarily in blood and sexual fluids (semen and vaginal secretions), and in very low concentrations in other body fluids (unless contaminated by blood or sexual fluids) (IARC 1996; IARC 2012a). Detection of HIV-1 infection consists of (1) tests to detect HIV-1 antibodies and/or antigen, (2) HIV-1 RNA tests, and (3) HIV-1 culture.

### 1.2.1 Detection of Antibodies or Antigens in Body Fluids

Detection of anti-HIV-1 antibodies represents current infection since HIV-1 infections are considered lifelong (Cornett and Kirn 2013; IARC 1996). The rate of seroconversion (or “window period”) varies from less than 1 month to 3 months in 97% of people (Hecht et al. 2011). During the window period HIV-1 antibody tests cannot detect the virus. Third generation tests detect IgG and IgM antibodies three weeks after the initial infection (Cornett and Kirn 2013; IARC 1996) and fourth generation immunoassays, available in the United States since 2010, detect a combination of capsid protein p24 antigen, IgG, and IgM, and can be used to detect HIV-1 infection as early as two weeks after infection. p24 antigen levels are short-lived and decline rapidly after the first phase of HIV-1 viremia in the days following infection until much later in the infection period.

Recommended current testing guidelines for U.S. laboratories were adopted in 2014 and consist of a sequence of tests used in combination to improve the accuracy of the laboratory diagnosis of HIV-1 based on testing of serum or plasma specimens. Previously, guidelines from the Centers for Disease Control and Prevention (CDC) for serodiagnosis of HIV-1 infections, testing for antibodies for HIV-2, and confirmation of reactive rapid antibody test results in 2004 employed only tests for HIV antibodies, such as the HIV-1 Western Blot and HIV-1 IFA. The updated recommendations include tests for HIV antigens and HIV nucleic acid based on data from high-risk populations showing that antibody testing alone can miss a high percentage of HIV infections which are detectable by virologic tests (CDC 2014b).

The updated recommendations for testing algorithms are more accurate than previous algorithms for laboratory diagnosis of acute HIV-1 and HIV-2 infections, have fewer indeterminate results and faster turnaround time for most results; and are equally accurate as previous laboratory diagnosis of established HIV-1 infection.

A panel of assays can also be used to distinguish recent from long-standing HIV-1 infections by taking advantage of the sequence of events following infection, thereby assisting in the recognition of HIV-1 incidence in cross-sectional serological studies (Murphy and Parry 2008). The relationship between different measures of HIV-1 infection over time is shown in Figure 1-4.

Figure 1-4

Diagnostic Markers of Human Immunodeficiency Virus (HIV) Infection

Time to reliable positivity of first (1), second (2), third (3), and fourth (4) generation and nucleic acid amplification test (N) HIV-1 diagnostic assays superimposed on a graphical depiction of the kinetics of circulating HIV-1 RNA, p24 antigen, and HIV-1 antibodies.

Ag = antigen; E = eclipse period; HIV = human immunodeficiency virus.

Source: Cornett and Kirn (2013).

### 1.2.2 Detection of HIV-1 RNA in Body Fluids

Nucleic acid-based testing of blood or blood cells for viral genes, predominantly HIV-I gag, HIV-II gag, HIV-env, or HIV-pol, by RT-PCR (converting HIV-1 RNA to complementary DNA by reverse transcriptase [RT] treatment and amplifying by polymerase chain reaction [PCR]) is also used to detect early infection and to measure viral load (Cornett and Kirn 2013; IARC 1996; IARC 2012a). This test can detect HIV-1 within a range of approximately two weeks to one month of infection. PCR-based assays can also measure viral load using dried blood blot samples (Smit et al. 2014). Since RT-PCR can measure viral load, it is often used to predict prognosis and the effectiveness of treatment (IARC 1996; IARC 2012a).

### 1.2.3 Detection of HIV-1 by Viral Culture

In some cases, immunoassays do not give meaningful results (IARC 1996). This can happen either when results are considered indeterminate, as only one of the two antibodies (anti-Gag and anti-Env) needed for a positive result were detected, or when infants less than 15-months-old are tested, as anti-HIV-1 IgG antibodies reflect maternal antibodies and not those of the infant (DHHS 2015a). Detection of HIV-1 can then be performed by culturing the HIV-1 virus and testing the culture for either the p24 antigen or reverse transcriptase activity. HIV-1 culture takes two to four weeks to perform and specialized facilities to conduct. Alternatively, infants can be tested for anti-HIV-1 IgA or IgM antibodies, which do not cross the placenta, or by PCR to detect HIV-1 RNA (Bunders et al. 2010; França et al. 2012; Palmeira et al. 2012; DHHS 2015a).

## 1.3 Summary

HIV-1 is an enveloped single-stranded RNA retrovirus of the subfamily Orthoretrovirinae and genus Lentivirus (IARC 2012a). HIV-1 is composed of an outer lipid membrane envelope with two surface proteins surrounding a protein matrix, inside of which is a protein capsid containing two copies of the 9.8-kb viral genome and the enzymes for viral replication, integration into host cell genetic material, and processing of viral proteins. HIV-1 infection can be detected by anti-HIV-1 antibodies, which typically take one to three months to become detectable serologically, HIV-1 antigens (p24), HIV-1 RNA (gag, env, pol), or by measuring HIV-1 antigen and HIV-1 RNA from in vitro culture of the virus, and which can be used if antibody detection gives indeterminate results.