# Abbreviations

  AIDS: Acquired Immune Deficiency Syndrome
  AZT: azidothymidine
  BMI: body mass index
  BOP: Bureau of Prisons
  cART: combination antiretroviral therapy
  CDC: Centers for Disease Control and Prevention
  CFR: Code of Federal Regulations
  CI: confidence interval
  COPD: chronic obstructive pulmonary disease
  DHHS: Department of Health and Human Services
  DHS: Department of Homeland Security
  DLBCL: diffuse large B-cell lymphoma
  DNA: deoxyribonucleic acid
  DoD: Department of Defense
  DOT: Department of Transportation
  dsDNA: double-stranded DNA
  DVA: Department of Veterans Affairs
  EBV: Epstein-Barr virus
  EIA: enzyme immunoassays
  ELISA: enzyme-linked immunosorbent assays
  FDA: Food and Drug Administration
  HAART: highly active antiretroviral therapies
  HBV: hepatitis B virus
  HCC: hepatocellular carcinoma
  HCV: hepatitis C virus
  HHS: Health and Human Services
  HIV: human immunodeficiency virus
  HIVMA: HIV Medicine Association
  HPV: human papillomavirus
  HR: hazard ratio
  HUD: Department of Housing and Urban Development
  IARC: International Agency for Research on Cancer
  IFA: immunofluorescence assay
  IgG: immunoglobulin G
  IgM: immunoglobulin M
  IRR: incidence rate ratio
  KSHV: Kaposi sarcoma-associated herpesvirus
  L1: type 1 long-interspersed nuclear elements
  LMP1: latent membrane protein 1
  MAC: Multicenter AIDS Cohort Study
  mRR: relative risk from a meta-analysis
  mSIR: standardized incidence ratio from a meta-analysis
  NHL: non-Hodgkin lymphoma
  NIH: National Institutes of Health
  NTP: National Toxicology Program
  OR: odds ratio
  OSHA: Occupational Safety and Health Administration
  PCR: polymerase chain reaction
  PHS: Public Health Service
  RNA: ribonucleic acid
  RR: relative risk
  RT: reverse transcriptase
  SEER: Surveillance, Epidemiology, and End Results Program
  SIR: standardized incidence ratios
  ssRNA: single-stranded RNA
  STI: sexually transmitted infection
  WHO: World Health Organization
  WIHS: Women Interagency HIV Study