# Glossary

AIDS-defining clinical condition: Any HIV-related illness included in the Centers for Disease Control and Prevention’s (CDC) list of diagnostic criteria for AIDS. AIDS-defining conditions include opportunistic infections and cancers that are life threatening in a person with HIV.
Calendar-period analysis: A method of monitoring patient survival in which the most recent survival experience is quantified for patients diagnosed in various years up to the most recent calendar year C, but only survival experience during a particular recent calendar period P (ending at the end of C) is included in the analysis.
Capsid: The protein coat surrounding the nucleic acid of a virus.
Case series: A collection of subjects (usually, patients) with common characteristics used to describe some clinical, pathophysiological, or operational aspect of a disease, treatment, exposure, or diagnostic procedure. A case series does not include a comparison group and is often based on prevalent cases and on a sample of convenience. Common selection biases and confounding severely limit their power to make causal inferences.
Case-comparison study (case-control study, case referent study): The observational epidemiological study of persons with the disease (or another outcome variable) of interest and a suitable control group of persons without the disease (comparison group, reference group). The potential relationship of a suspected risk factor or an attribute to the disease is examined by comparing the diseased and non-diseased subjects with regard to how frequently the factor or attribute is present (or, if quantitative, the levels of the attribute) in each of the groups (diseased and non-diseased).
Co-factor: A factor that activates or enhances the action of another entity such as a disease-causing agent. Cofactors may influence the progression of a disease or the likelihood of becoming ill.
Diagnostic criteria: The specific combination of signs, symptoms, and test results that a clinician uses to identify a person as representing a case of a particular disease or condition.
Enzyme immunoassay: An assay that uses an enzyme-bound antibody to detect an antigen. The enzyme catalyzes a color reaction when exposed to substrate.
Highly active antiretroviral therapy: Treatment regimens that stop or slow the HIV virus from reproducing and keep HIV disease from progressing. The usual HAART regimen combines three or more HIV drugs from at least two different classes. HAART may also be referred to as combination antiretroviral therapy (cART) or antiretroviral therapy (ART).
Horizontal transmission: The spread of an infectious agent from one individual to another, usually through contact with bodily excretions or fluids, such as sputum or blood, which contains the agent.
Latent phase: A phase of the virus life cycle during which the virus is not replicating.
Lytic phase: A phase of the virus life cycle during which the virus replicates within the host cell, releasing a new generation of viruses when the infected cell lyses.
Monoclonal: Pertaining to or designating a group of identical cells or organisms derived from a single cell or organism.
Percutaneous transmission: Exposure through any break in intact skin, whether from sharps injury (e.g., needlesticks) or other types of tissue trauma.
Point-of-care rapid test: A type of HIV antibody test used to screen for HIV infection. A rapid HIV antibody test can detect HIV antibodies in blood or oral fluid in less than 30 minutes. A positive rapid HIV antibody test must be confirmed by a second, different antibody test (a positive Western blot) for a person to be definitively diagnosed with HIV infection.
Polymerase chain reaction: A laboratory technique used to produce large amounts of specific DNA fragments. Polymerase chain reaction is used for genetic testing and to diagnose disease.
Post-exposure prophylaxis: Short-term treatment started as soon as possible after high-risk exposure to an infectious agent, such as HIV, hepatitis B virus (HBV), or hepatitis C virus (HCV). The purpose of post-exposure prophylaxis (PEP) is to reduce the risk of infection. An example of a high-risk exposure is exposure to an infectious agent as the result of unprotected sex.
Pre-exposure prophylaxis: An HIV prevention method for people who are HIV negative and at high risk of HIV infection. Pre-exposure prophylaxis involves taking a specific combination of HIV medicines daily and is even more effective when it is combined with condoms and other prevention tools.
Prospective cancer registry linkage study: A forward-looking analytic epidemiological study that matches identification of cohort members to identification of patients in a population-based cancer registry or registries to determine if cohort members have been diagnosed with cancer. Cancer registries ideally include reports of all incident cancers in a local population identified as soon as possible after first diagnosis. Typically, the principal sources for these reports are the hospitals or cancer centers serving the population.
Provirus: An inactive viral form that has been integrated into the genes of a host cell. For example, when HIV enters a host CD4 cell, HIV RNA is first changed to HIV DNA (provirus). The HIV provirus then gets inserted into the DNA of the CD4 cell. When the CD4 cell replicates, the HIV provirus is passed from one cell generation to the next, ensuring ongoing replication of HIV.
Time-trend descriptive study: An epidemiological study based on group-level data in which comparisons are made between groups to help draw conclusions about the effect of an exposure on different populations. Observations are recorded for each group at equal time intervals (e.g., monthly). Types of measurements may include prevalence of disease, levels of pollution, or mean temperature in a region.
Titer: A laboratory measurement of the concentration of a substance in a solution (e.g., an antibody titer measures the presence and number of antibodies in the blood).
Vertical transmission: The transmission of infection from one generation to the next (e.g., from mother to infant prenatally, during delivery, or in the postnatal period via breast milk).
Viral set point: The viral load (HIV RNA) within a few weeks to months after infection with HIV. Immediately after infection, HIV multiplies rapidly, and a person’s viral load is typically very high. After a few weeks to months, this rapid replication of HIV declines and the person's viral load drops to its set point.
Window period: The time period from infection with HIV until the body produces enough HIV antibodies to be detected by standard HIV antibody tests. The length of the window period varies depending on the antibody test used. During the window period, a person can have a negative result on an HIV antibody test despite being infected with HIV.