# References

Abraham AG, D’Souza G, Jing Y, Gange SJ, Sterling TR, Silverberg MJ, Saag MS, Rourke SB, Rachlis A, Napravnik S, et al. 2013. Invasive cervical cancer risk among HIV-infected women: A North American multicohort collaboration prospective study. J Acquir Immune Defic Syndr. 62(4):405–413. 10.1097/QAI.0b013e31828177d7 23254153
Achhra AC, Petoumenos K, Law MG. 2014. Relationship between CD4 cell count and serious long-term complications among HIV-positive individuals. Curr Opin HIV AIDS. 9(1):63–71. 10.1097/COH.0000000000000017 24275674
Adler DH. 2010. The impact of HAART on HPV-related cervical disease. Curr HIV Res. 8(7):493–497. 10.2174/157016210793499240 20946095
Akarolo-Anthony SN, Maso LD, Igbinoba F, Mbulaiteye SM, Adebamowo CA. 2014. Cancer burden among HIV-positive persons in Nigeria: Preliminary findings from the Nigerian AIDS-cancer match study. Infect Agent Cancer. 9(1):1. 10.1186/1750-9378-9-1 24597902
Albini L, Calabresi A, Gotti D, Ferraresi A, Festa A, Donato F, Magoni M, Castelli F, Quiros-Roldan E. 2013. Burden of non-AIDS-defining and non-virus-related cancers among HIV-infected patients in the combined antiretroviral therapy era. AIDS Res Hum Retroviruses. 29(8):1097–1104. 10.1089/aid.2012.0321 23581483
Allardice GM, Hole DJ, Brewster DH, Boyd J, Goldberg DJ. 2003. Incidence of malignant neoplasms among HIV-infected persons in Scotland. Br J Cancer. 89(3):505–507. 10.1038/sj.bjc.6601139 12888821
Almodovar S. 2014. The complexity of HIV persistence and pathogenesis in the lung under antiretroviral therapy: Challenges beyond AIDS. Viral Immunol. 27(5):186–199. 10.1089/vim.2013.0130 24797368
Altekruse SF, Henley SJ, Cucinelli JE, McGlynn KA. 2014. Changing hepatocellular carcinoma incidence and liver cancer mortality rates in the United States. Am J Gastroenterol. 109(4):542–553. 10.1038/ajg.2014.11 24513805
Alter MJ. 2006. Epidemiology of viral hepatitis and HIV co-infection. J Hepatol. 44(1) Suppl:S6–S9. 10.1016/j.jhep.2005.11.004 16352363
American Cancer Society (ACS). 2015. Cancer facts & figures. Atlanta, GA: American Cancer Society.
Angeletti PC, Zhang L, Wood C. 2008. The viral etiology of AIDS-associated malignancies. Adv Pharmacol. 56:509–557. 10.1016/S1054-3589(07)56016-3 18086422
Araujo A, Sheehy N, Takahashi H, Hall WW. 2002. Chapter 5, Concomitant infections with human immunodeficiency virus type 1 and human T-lymphotropic virus types 1 and 2. In: Brogden KA, Guthmiller JM, editors. Polymicrobial Diseases. Washington, DC: ASM Press. 10.1128/9781555817947.ch5
Ateenyi-Agaba C. 1995. Conjunctival squamous-cell carcinoma associated with HIV infection in Kampala, Uganda. Lancet. 345(8951):695–696. 10.1016/S0140-6736(95)90870-6 7885126
Ateenyi-Agaba C, Weiderpass E, Tommasino M, Smet A, Arslan A, Dai M, Katongole-Mbidde E, Hainaut P, Snijders PJ, Franceschi S. 2006. Papillomavirus infection in the conjunctiva of individuals with and without AIDS: An autopsy series from Uganda. Cancer Lett. 239(1):98–102. 10.1016/j.canlet.2005.07.024 16143449
Avert.org. 2015a. HIV drugs development. https://www.avert.org/hiv-drugs-development.htm. [Accessed: August 26, 2015]
Avert.org. 2015b. Antiretroviral drugs. https://www.avert.org/antiretroviral-drugs.htm. [Accessed: September 8, 2015]
Beachler DC, DʼSouza G. 2013. Oral human papillomavirus infection and head and neck cancers in HIV-infected individuals. Curr Opin Oncol. 25(5):503–510. 10.1097/CCO.0b013e32836242b4 23852381
Beachler DC, Abraham AG, Silverberg MJ, Jing Y, Fakhry C, Gill MJ, Dubrow R, Kitahata MM, Klein MB, Burchell AN, et al. 2014. Incidence and risk factors of HPV-related and HPV-unrelated head and neck squamous cell carcinoma in HIV-infected individuals. Oral Oncol. 50(12):1169–1176. 10.1016/j.oraloncology.2014.09.011 25301563
Beachler DC, Sugar EA, Margolick JB, Weber KM, Strickler HD, Wiley DJ, Cranston RD, Burk RD, Minkoff H, Reddy S, et al. 2015. Risk factors for acquisition and clearance of oral human papillomavirus infection among HIV-infected and HIV-uninfected adults. Am J Epidemiol. 181(1):40–53. 10.1093/aje/kwu247 25480823
Beachler DC, Weber KM, Margolick JB, Strickler HD, Cranston RD, Burk RD, Wiley DJ, Minkoff H, Reddy S, Stammer EE, et al. 2012. Risk factors for oral HPV infection among a high prevalence population of HIV-positive and at-risk HIV-negative adults. Cancer Epidemiol Biomarkers Prev. 21(1):122–133. 10.1158/1055-9965.EPI-11-0734 22045700
Bedimo RJ, McGinnis KA, Dunlap M, Rodriguez-Barradas MC, Justice AC. 2009. Incidence of non-AIDS-defining malignancies in HIV-infected versus noninfected patients in the HAART era: Impact of immunosuppression. J Acquir Immune Defic Syndr. 52(2):203–208. 10.1097/QAI.0b013e3181b033ab 19617846
Beral V, Peterman TA, Berkelman RL, Jaffe HW. 1990. Kaposi’s sarcoma among persons with AIDS: A sexually transmitted infection? Lancet. 335(8682):123–128. 10.1016/0140-6736(90)90001-L 1967430
Bernstein L, Levin D, Menck H, Ross RK. 1989. AIDS-related secular trends in cancer in Los Angeles County men: A comparison by marital status. Cancer Res. 49(2):466–470. 2910464
Bhaskaran K, Brettle R, Porter K, Walker AS. 2004. Systemic non-Hodgkin lymphoma in individuals with known dates of HIV seroconversion: Incidence and predictors. AIDS. 18(4):673–681. 10.1097/00002030-200403050-00012 15090773
Biggar RJ, Burnett W, Mikl J, Nasca P. 1989. Cancer among New York men at risk of acquired immunodeficiency syndrome. Int J Cancer. 43(6):979–985. 10.1002/ijc.2910430605 2732009
Biggar RJ, Chaturvedi AK, Goedert JJ, Engels EA. 2007. AIDS-related cancer and severity of immunosuppression in persons with AIDS. J Natl Cancer Inst. 99(12):962–972. 10.1093/jnci/djm010 17565153
Biggar RJ, Engels EA, Frisch M, Goedert JJ, Group ACMRS. 2001. Risk of T-cell lymphomas in persons with AIDS. J Acquir Immune Defic Syndr. 26(4):371–376. 10.1097/00126334-200104010-00015 11317081
Biggar RJ, Horm J, Goedert JJ, Melbye M. 1987. Cancer in a group at risk of acquired immunodeficiency syndrome (AIDS) through 1984. Am J Epidemiol. 126(4):578–586. 10.1093/oxfordjournals.aje.a114697 3631049
Biggar RJ, Jaffe ES, Goedert JJ, Chaturvedi A, Pfeiffer R, Engels EA. 2006. Hodgkin lymphoma and immunodeficiency in persons with HIV/AIDS. Blood. 108(12):3786–3791. 10.1182/blood-2006-05-024109 16917006
Bohlius J, Schmidlin K, Boué F, Fätkenheuer G, May M, Caro-Murillo AM, Mocroft A, Bonnet F, Clifford G, Paparizos V, et al. 2011. HIV-1-related Hodgkin lymphoma in the era of combination antiretroviral therapy: Incidence and evolution of CD4^+^ T-cell lymphocytes. Blood. 117(23):6100–6108. 10.1182/blood-2010-08-301531 21368291
Bongiovanni M, Tordato F. 2007. Steatohepatitis in HIV-infected subjects: Pathogenesis, clinical impact and implications in clinical management. Curr HIV Res. 5(5):490–498. 10.2174/157016207781662407 17896969
Borges AH, Dubrow R, Silverberg MJ. 2014. Factors contributing to risk for cancer among HIV-infected individuals, and evidence that earlier combination antiretroviral therapy will alter this risk. Curr Opin HIV AIDS. 9(1):34–40. 10.1097/COH.0000000000000025 24225382
Borges ÁH, Silverberg MJ, Wentworth D, Grulich AE, Fätkenheuer G, Mitsuyasu R, Tambussi G, Sabin CA, Neaton JD, Lundgren JD. 2013. Predicting risk of cancer during HIV infection: The role of inflammatory and coagulation biomarkers. AIDS. 27(9):1433–1441. 10.1097/QAD.0b013e32835f6b0c 23945504
Bosch FX, Lorincz A, Muñoz N, Meijer CJ, Shah KV. 2002. The causal relation between human papillomavirus and cervical cancer. J Clin Pathol. 55(4):244–265. https://jcp.bmj.com/content/55/4/244.long. 10.1136/jcp.55.4.244 11919208
Bower M, Powles T, Newsom-Davis T, Thirlwell C, Stebbing J, Mandalia S, Nelson M, Gazzard B. 2004. HIV-associated anal cancer: Has highly active antiretroviral therapy reduced the incidence or improved the outcome? J Acquir Immune Defic Syndr. 37(5):1563–1565. 10.1097/00126334-200412150-00004 15577408
Bruyand M, Ryom L, Shepherd L, Fatkenheuer G, Grulich A, Reiss P, de Wit S, d´Arminio MA, Furrer H, Pradier C et al. 2015. Cancer risk and use of protease inhibitor or nonnucleoside reverse transcriptase inhibitor-based combination antiretroviral therapy: The DAD study. J Acquir Immune Defic Syndr. 68(5):568–577. 10.1097/QAI.0000000000000523 25763785
Bruyand M, Thiébaut R, Lawson-Ayayi S, Joly P, Sasco AJ, Mercié P, Pellegrin JL, Neau D, Dabis F, Morlat P, et al. 2009. Role of uncontrolled HIV RNA level and immunodeficiency in the occurrence of malignancy in HIV-infected patients during the combination antiretroviral therapy era: Agence Nationale de Recherche sur le Sida (ANRS) CO3 Aquitaine Cohort. Clin Infect Dis. 49(7):1109–1116. 10.1086/605594 19705973
Bunders M, Pembrey L, Kuijpers T, Newell ML. 2010. Evidence of impact of maternal HIV infection on immunoglobulin levels in HIV-exposed uninfected children. AIDS Res Hum Retroviruses. 26(9):967–975. 10.1089/aid.2009.0241 20718630
Burbelo PD, Kovacs JA, Wagner J, Bayat A, Rhodes CS, De Souza Y, Greenspan JS, Iadarola MJ. 2012. The cancer-associated virus landscape in HIV patients with oral hairy leukoplakia, Kaposi’s sarcoma, and Non-Hodgkin lymphoma. Aids Res Treat. 2012:634523. 10.1155/2012/634523 22924124
Calabresi A, Ferraresi A, Festa A, Scarcella C, Donato F, Vassallo F, Limina R, Castelli F, Quiros-Roldan E, Brescia HIVCSG. 2013. Incidence of AIDS-defining cancers and virus-related and non-virus-related non-AIDS-defining cancers among HIV-infected patients compared with the general population in a large health district of Northern Italy, 1999-2009. HIV Med. 14(8):481–490. 10.1111/hiv.12034 23560682
Carbone A, Gloghini A, Serraino D, Spina M. 2009. HIV-associated Hodgkin lymphoma. Curr Opin HIV AIDS. 4(1):3–10. 10.1097/COH.0b013e32831a722b 19339934
Cardo DM, Culver DH, Ciesielski CA, Srivastava PU, Marcus R, Abiteboul D, Heptonstall J, Ippolito G, Lot F, McKibben PS, et al. 1997. A case-control study of HIV seroconversion in health care workers after percutaneous exposure. Centers for Disease Control and Prevention Needlestick Surveillance Group. N Engl J Med. 337(21):1485–1490. 10.1056/NEJM199711203372101 9366579
Carreira H, Coutinho F, Carrilho C, Lunet N. 2013. HIV and HPV infections and ocular surface squamous neoplasia: Systematic review and meta-analysis. Br J Cancer. 109(7):1981–1988. 10.1038/bjc.2013.539 24030075
Carrieri MP, Pradier C, Piselli P, Piche M, Rosenthal E, Heudier P, Durant J, Serraino D. 2003. Reduced incidence of Kaposi’s sarcoma and of systemic Non-Hodgkin’s lymphoma in HIV-infected individuals treated with highly active antiretroviral therapy. Int J Cancer. 103(1):142–144. 10.1002/ijc.10790 12455069
Castilho JL, Luz PM, Shepherd BE, Turner M, Ribeiro SR, Bebawy SS, Netto JS, McGowan CC, Veloso VG, Engels EA, et al. 2015. HIV and cancer: A comparative retrospective study of Brazilian and U.S. clinical cohorts. Infect Agent Cancer. 10:4. 10.1186/1750-9378-10-4 25685180
Centers for Disease Control and Prevention (CDC). 1985. Revision of the case definition of acquired immunodeficiency syndrome for national reporting—United States. MMWR. 34(25):373–375. 2989677
Centers for Disease Control and Prevention (CDC). 1987. Recommendations for prevention of HIV transmission in health-care settings. MMWR. 36 SU02.
Centers for Disease Control and Prevention (CDC). 1992. 1993 revised classification system for HIV infection and expanded surveillance case definition for AIDS among adolescents and adults. MMWR Recomm Rep. 41(Rr-17):1-19.
Centers for Disease Control and Prevention (CDC). 2006. Revised recommendations for HIV testing of adults, adolescents, and pregnant women in health-care settings. MMWR. 55 RR-14:1–17. 16988643
Centers for Disease Control and Prevention (CDC). 2012. Estimated HIV incidence in the United States, 2007–2010. HIV Surv Rep. 17(4):1–26.
Centers for Disease Control and Prevention (CDC). 2014 a. Preexposure prophylaxis for the prevention of HIV Infection in the United States - 2014. Atlanta, GA: Centers for Disease Control and Prevention.
Centers for Disease Control and Prevention (CDC). 2014 b. Laboratory testing for the diagnosis of HIV Infection: Updated recommendations. Atlanta, GA: Centers for Disease Control and Prevention.
Centers for Disease Control and Prevention (CDC). 2014c. Revised surveillance case definition for HIV infection--United States, 2014. MMWR Recomm Rep. 63(Rr-03):1-10.
Centers for Disease Control and Prevention (CDC). 2014 d. Recommendations for HIV prevention with adults and adolescents with HIV in the United States, 2014. Atlanta, GA: Centers for Disease Control and Prevention.
Centers for Disease Control and Prevention (CDC). 2015a. HIV in the United States: At a glance. Atlanta, GA: Centers for Disease Control and Prevention. https://www.cdc.gov/hiv/statistics/basics/ataglance.html. [Accessed: August 26, 2015]
Centers for Disease Control and Prevention (CDC). 2015b. Opportunistic infections. Atlanta, GA: Centers for Disease Control and Prevention. https://www.cdc.gov/hiv/basics/livingwithhiv/opportunisticinfections.html. [Accessed: August 26, 2015]
Centers for Disease Control and Prevention (CDC). 2015c. HPV-associated cervical cancer rates by race and ethnicity. Atlanta, GA: Centers for Disease Control and Prevention. https://www.cdc.gov/hpv/parents/cancer.html.
Centers for Disease Control and Prevention (CDC). 2015d. Compendium of evidence-based interventions and best practices for HIV prevention. Atlanta, GA: Centers for Disease Control and Prevention. https://www.cdc.gov/hiv/prevention/research/compendium/rr/complete.html. [Accessed: September 8, 2015]
Centers for Disease Control and Prevention (CDC). 2016. United States cancer statistics: 1999–2012 incidence and mortality web-based report. Atlanta, GA: Centers for Disease Control and Prevention and National Cancer Institute. https://nccd.cdc.gov/uscs/cancersbyraceandethnicity.aspx.
Chao C, Leyden WA, Xu L, Horberg MA, Klein D, Towner WJ, Quesenberry CP Jr, Abrams DI, Silverberg MJ. 2012. Exposure to antiretroviral therapy and risk of cancer in HIV-infected persons. AIDS. 26(17):2223–2231. 10.1097/QAD.0b013e32835935b3 22951631
Chaturvedi AK, Engels EA, Pfeiffer RM, Hernandez BY, Xiao W, Kim E, Jiang B, Goodman MT, Sibug-Saber M, Cozen W, et al. 2011. Human papillomavirus and rising oropharyngeal cancer incidence in the United States. J Clin Oncol. 29(32):4294–4301. 10.1200/JCO.2011.36.4596 21969503
Chaturvedi AK, Madeleine MM, Biggar RJ, Engels EA. 2009. Risk of human papillomavirus-associated cancers among persons with AIDS. J Natl Cancer Inst. 101(16):1120–1130. 10.1093/jnci/djp205 19648510
Chaturvedi AK, Pfeiffer RM, Chang L, Goedert JJ, Biggar RJ, Engels EA. 2007. Elevated risk of lung cancer among people with AIDS. AIDS. 21(2):207–213. 10.1097/QAD.0b013e3280118fca 17197812
Chen M, Jen I, Chen YH, Lin MW, Bhatia K, Sharp GB, Law MG, Arthur Chen YM. 2014. Cancer incidence in a Nationwide HIV/AIDS patient cohort in Taiwan in 1998-2009. J Acquir Immune Defic Syndr. 65(4):463–472. 10.1097/QAI.0000000000000065 24583616
Clarke B, Chetty R. 2002. Postmodern cancer: The role of human immunodeficiency virus in uterine cervical cancer. Mol Pathol. 55(1):19–24. 10.1136/mp.55.1.19 11836442
Clifford GM, Franceschi S. 2009. Cancer risk in HIV-infected persons: Influence of CD4(+) count. Future Oncol. 5(5):669–678. 10.2217/fon.09.28 19519206
Clifford GM, Lise M, Franceschi S, Egger M, Bouchardy C, Korol D, Levi F, Ess S, Jundt G, Wandeler G, et al. 2012. Lung cancer in the Swiss HIV Cohort Study: Role of smoking, immunodeficiency and pulmonary infection. Br J Cancer. 106(3):447–452. 10.1038/bjc.2011.558 22240797
Clifford GM, Polesel J, Rickenbach M, Dal Maso L, Keiser O, Kofler A, Rapiti E, Levi F, Jundt G, Fisch T, et al. 2005. Cancer risk in the Swiss HIV Cohort Study: Associations with immunodeficiency, smoking, and highly active antiretroviral therapy. J Natl Cancer Inst. 97(6):425–432. 10.1093/jnci/dji072 15770006
Clifford GM, Rickenbach M, Polesel J, Dal Maso L, Steffen I, Ledergerber B, Rauch A, Probst-Hensch NM, Bouchardy C, Levi F, et al. 2008. Influence of HIV-related immunodeficiency on the risk of hepatocellular carcinoma. AIDS. 22(16):2135–2141. 10.1097/QAD.0b013e32831103ad 18832877
Coghill AE, Shiels MS, Suneja G, Engels EA. 2015. Elevated cancer-specific mortality among HIV-infected patients in the United States. J Clin Oncol. 33(21):2376–2383. 10.1200/JCO.2014.59.5967 26077242
Cooksley CD, Hwang LY, Waller DK, Ford CE. 1999. HIV-related malignancies: Community-based study using linkage of cancer registry and HIV registry data. Int J STD AIDS. 10(12):795–802. 10.1258/0956462991913574 10639060
Cornett JK, Kirn TJ. 2013. Laboratory diagnosis of HIV in adults: A review of current methods. Clin Infect Dis. 57(5):712–718. 10.1093/cid/cit281 23667267
Coté TR, Howe HL, Anderson SP, Martin RJ, Evans B, Francis BJ. 1991. A systematic consideration of the neoplastic spectrum of AIDS: Registry linkage in Illinois. AIDS. 5(1):49–53. 10.1097/00002030-199101000-00007 2059360
Coté TR, Manns A, Hardy CR, Yellin FJ, Hartge P. 1996. Epidemiology of brain lymphoma among people with or without acquired immunodeficiency syndrome. AIDS/Cancer Study Group. J Natl Cancer Inst. 88(10):675–679. 10.1093/jnci/88.10.675 8627644
Coutlée F, de Pokomandy A, Franco EL. 2012. Epidemiology, natural history and risk factors for anal intraepithelial neoplasia. Sex Health. 9(6):547–555. 10.1071/SH11167 22954036
Craigie R, Bushman FD. 2012. HIV DNA integration. Cold Spring Harb Perspect Med. 2(7):a006890. 10.1101/cshperspect.a006890 22762018
Crane M, Iser D, Lewin SR. 2012. Human immunodeficiency virus infection and the liver. World J Hepatol. 4(3):91–98. 10.4254/wjh.v4.i3.91 22489261
Crosbie EJ, Einstein MH, Franceschi S, Kitchener HC. 2013. Human papillomavirus and cervical cancer. Lancet. 382(9895):889–899. 10.1016/S0140-6736(13)60022-7 23618600
Crothers K, Thompson BW, Burkhardt K, Morris A, Flores SC, Diaz PT, Chaisson RE, Kirk GD, Rom WN, Huang L, et al. 2011. HIV-associated lung infections and complications in the era of combination antiretroviral therapy. Proc Am Thorac Soc. 8(3):275–281. 10.1513/pats.201009-059WR 21653528
Crum-Cianflone NF, Wang X, Ganesan A, Okulicz J, Weintrob A, Lalani T, Agan B. 2015. Short communication: HIV RNA levels predict AIDS-defining and non-ADS-defining cancers after antiretroviral therapy initiation among HIV-infected adults. AIDS Res Hum Retroviruses. 31(5):514–518. 10.1089/aid.2014.0279 25417712
Curry MP. 2013. HIV and hepatitis C virus: Special concerns for patients with cirrhosis. J Infect Dis. 207 Suppl 1:S40–S44. 10.1093/infdis/jis763 23390304
Dal Maso L, Franceschi S, Polesel J, Braga C, Piselli P, Crocetti E, Falcini F, Guzzinati S, Zanetti R, Vercelli M, et al. 2003. Risk of cancer in persons with AIDS in Italy, 1985-1998. Br J Cancer. 89(1):94–100. 10.1038/sj.bjc.6601017 12838307
Dal Maso L, Polesel J, Serraino D, Lise M, Piselli P, Falcini F, Russo A, Intrieri T, Vercelli M, Zambon P, et al. 2009. Pattern of cancer risk in persons with AIDS in Italy in the HAART era. Br J Cancer. 100(5):840–847. 10.1038/sj.bjc.6604923 19223894
De Cock KM, Brun-Vezinet F, Soro B. 1991. HIV-1 and HIV-2 infections and AIDS in West Africa. AIDS. 5 Suppl 1:S21–S28. 10.1097/00002030-199107000-00010 1669921
de Martel C, Shiels MS, Franceschi S, Simard EP, Vignat J, Hall HI, Engels EA, Plummer M. 2015. Cancers attributable to infections among adults with HIV in the United States. AIDS. 29(16):2173–2181. 10.1097/QAD.0000000000000808 26182198
De Vuyst H, Alemany L, Lacey C, Chibwesha CJ, Sahasrabuddhe V, Banura C, Denny L, Parham GP. 2013. The burden of human papillomavirus infections and related diseases in sub-saharan Africa. Vaccine. 31 Suppl 5(0 5):F32-46. 10.1016/j.vaccine.2012.07.092 10.1016/j.vaccine.2012.07.092
Deng LP, Gui XE, Zhang YX, Gao SC, Yang RR. 2009. Impact of human immunodeficiency virus infection on the course of hepatitis C virus infection: A meta-analysis. World J Gastroenterol. 15(8):996–1003. 10.3748/wjg.15.996 19248201
Denny LA, Franceschi S, de Sanjosé S, Heard I, Moscicki AB, Palefsky J. 2012. Human papillomavirus, human immunodeficiency virus and immunosuppression. Vaccine. 30 Suppl 5:F168–F174. 10.1016/j.vaccine.2012.06.045 23199960
Denslow SA, Rositch AF, Firnhaber C, Ting J, Smith JS. 2014. Incidence and progression of cervical lesions in women with HIV: A systematic global review. Int J STD AIDS. 25(3):163–177. 10.1177/0956462413491735 24216030
Desruisseau AJ, Schmidt-Grimminger D, Welty E. 2009. Epidemiology of HPV in HIV-positive and HIV-negative fertile women in Cameroon, West Africa. Infect Dis Obstet Gynecol. 2009:810596. 10.1155/2009/810596 20169094
Dezzutti CS, Lal RB. 1999. Human T-cell lymphotropic virus types I and II. Manual of Clinical Microbiology. Washington, DC: American Society for Microbiology. p. 871.
Dhasmana D, Taylor GP. 2014. Human T-lymphotropic virus/HIV co-infection: A clinical review. Curr Opin Infect Dis. 27(1):16–28. 10.1097/QCO.0000000000000027 24305042
Di Benedetto N, Peralta M, Alvarez E, Schroder MT, Estepo C, Paz S, Fainboim H. 2014. Incidence of hepatocellular carcinoma in hepatitis C cirrhotic patients with and without HIV infection: A cohort study, 1999-2011. Ann Hepatol. 13(1):38–44. 10.1016/S1665-2681(19)30902-0 24378264
Diamond C, Taylor TH, Aboumrad T, Bringman D, Anton-Culver H. 2005. Increased incidence of squamous cell anal cancer among men with AIDS in the era of highly active antiretroviral therapy. Sex Transm Dis. 32(5):314–320. 10.1097/01.olq.0000162366.60245.02 15849533
Diamond C, Taylor TH, Im T, Miradi M, Wallace M, Anton-Culver H. 2006. Highly active antiretroviral therapy is associated with improved survival among patients with AIDS-related primary central nervous system non-Hodgkin’s lymphoma. Curr HIV Res. 4(3):375–378. 10.2174/157016206777709429 16842088
Dore GJ, Li Y, Grulich AE, Hoy JF, Mallal SA, Mijch AM, French MA, Cooper DA, Kaldor JM. 1996. Declining incidence and later occurrence of Kaposi’s sarcoma among persons with AIDS in Australia: The Australian AIDS cohort. AIDS. 10(12):1401–1406. 10.1097/00002030-199610000-00013 8902070
Dugué PA, Rebolj M, Garred P, Lynge E. 2013. Immunosuppression and risk of cervical cancer. Expert Rev Anticancer Ther. 13(1):29–42. 10.1586/era.12.159 23259425
Einstein MH, Phaëton R. 2010. Issues in cervical cancer incidence and treatment in HIV. Curr Opin Oncol. 22(5):449–455. 10.1097/CCO.0b013e32833cff4f 20613518
el-Solh A, Kumar NM, Nair MP, Schwartz SA, Lwebuga-Mukasa JS. 1997. An RGD containing peptide from HIV-1 Tat-(65-80) modulates protooncogene expression in human bronchoalveolar carcinoma cell line, A549. Immunol Invest. 26(3):351–370. 10.3109/08820139709022692 9129988
Eltom MA, Jemal A, Mbulaiteye SM, Devesa SS, Biggar RJ. 2002. Trends in Kaposi’s sarcoma and non-Hodgkin’s lymphoma incidence in the United States from 1973 through 1998. J Natl Cancer Inst. 94(16):1204–1210. 10.1093/jnci/94.16.1204 12189223
Emmanuel B, Ruder E, Lin SW, Abnet C, Hollenbeck A, Mbulaiteye S. 2012. Incidence of squamous-cell carcinoma of the conjunctiva and other eye cancers in the NIH-AARP Diet and Health Study. Ecancermedicalscience. 6:254. 22654961
Engels EA. 2007. Infectious agents as causes of non-Hodgkin lymphoma. Cancer Epidemiol Biomarkers Prev. 16(3):401–404. 10.1158/1055-9965.EPI-06-1056 17337646
Engels EA. 2009. Non-AIDS-defining malignancies in HIV-infected persons: Etiologic puzzles, epidemiologic perils, prevention opportunities. AIDS. 23(8):875–885. 10.1097/QAD.0b013e328329216a 19349851
Engels EA, Biggar RJ, Hall HI, Cross H, Crutchfield A, Finch JL, Grigg R, Hylton T, Pawlish KS, McNeel TS, et al. 2008. Cancer risk in people infected with Human Immunodeficiency Virus in the United States. Int J Cancer. 123(1):187–194. 10.1002/ijc.23487 18435450
Engels EA, Brock MV, Chen J, Hooker CM, Gillison M, Moore RD. 2006 a. Elevated incidence of lung cancer among HIV-infected individuals. J Clin Oncol. 24(9):1383–1388. 10.1200/JCO.2005.03.4413 16549832
Engels EA, Frisch M, Goedert JJ, Biggar RJ, Miller RW. 2002 a. Merkel cell carcinoma and HIV infection. Lancet. 359(9305):497–498. 10.1016/S0140-6736(02)07668-7 11853800
Engels EA, Frisch M, Lubin JH, Gail MH, Biggar RJ, Goedert JJ. 2002 b. Prevalence of hepatitis C virus infection and risk for hepatocellular carcinoma and non-Hodgkin lymphoma in AIDS. J Acquir Immune Defic Syndr. 31(5):536–541. 10.1097/00126334-200212150-00012 12473843
Engels EA, Goedert JJ. 2005. Human immunodeficiency virus/acquired immunodeficiency syndrome and cancer: Past, present, and future. J Natl Cancer Inst. 97(6):407–409. 10.1093/jnci/dji085 15769998
Engels EA, Pfeiffer RM, Fraumeni JF Jr, Kasiske BL, Israni AK, Snyder JJ, Wolfe RA, Goodrich NP, Bayakly AR, Clarke CA, et al. 2011. Spectrum of cancer risk among US solid organ transplant recipients. JAMA. 306(17):1891–1901. 10.1001/jama.2011.1592 22045767
Engels EA, Pfeiffer RM, Goedert JJ, Virgo P, McNeel TS, Scoppa SM, Biggar RJ. 2006 b. Trends in cancer risk among people with AIDS in the United States 1980-2002. AIDS. 20(12):1645–1654. 10.1097/01.aids.0000238411.75324.59 16868446
Engels EA, Pfeiffer RM, Landgren O, Moore RD. 2010. Immunologic and virologic predictors of AIDS-related non-hodgkin lymphoma in the highly active antiretroviral therapy era. J Acquir Immune Defic Syndr. 54(1):78–84. 10.1097/01.qai.0000371677.48743.8d 20418723
Epeldegui M, Breen EC, Hung YP, Boscardin WJ, Detels R, Martínez-Maza O. 2007. Elevated expression of activation induced cytidine deaminase in peripheral blood mononuclear cells precedes AIDS-NHL diagnosis. AIDS. 21(17):2265–2270. 10.1097/QAD.0b013e3282ef9f59 18090274
Epeldegui M, Thapa DR, De la Cruz J, Kitchen S, Zack JA, Martínez-Maza O. 2010. CD40 ligand (CD154) incorporated into HIV virions induces activation-induced cytidine deaminase (AID) expression in human B lymphocytes. PLoS One. 5(7):e11448. 10.1371/journal.pone.0011448 20625427
European Mode of Delivery Collaboration. 1999. Elective caesarean-section versus vaginal delivery in prevention of vertical HIV-1 transmission: A randomised clinical trial. Lancet. 353(9158):1035–1039. 10.1016/S0140-6736(98)08084-2 10199349
Fan H, Kim SC, Chima CO, Israel BF, Lawless KM, Eagan PA, Elmore S, Moore DT, Schichman SA, Swinnen LJ, et al. 2005. Epstein-Barr viral load as a marker of lymphoma in AIDS patients. J Med Virol. 75(1):59–69. 10.1002/jmv.20238 15543571
Feeney ER, Mallon PW. 2011. Insulin resistance in treated HIV infection. Best Pract Res Clin Endocrinol Metab. 25(3):443–458. 10.1016/j.beem.2010.11.002 21663838
Fernandes JV, de Medeiros Fernandes TA, de Azevedo JC, Cobucci RN, de Carvalho MG, Andrade VS, de Araújo JM. 2015. Link between chronic inflammation and human papillomavirus-induced carcinogenesis [Review]. Oncol Lett. 9(3):1015–1026. 10.3892/ol.2015.2884 25663851
Fontas E, Kousignian I, Pradier C, Duvivier C, Poizot-Martin I, Durier C, Jarrousse B, Weiss L, Levy Y, Costagliola D. 2009. Interleukine-2 therapy does not increase the risk of Hodgkin or non-Hodgkin lymphoma in HIV-infected patients: Results from FHDH ANRS CO4. J Acquir Immune Defic Syndr. 50(2):206–214. 10.1097/QAI.0b013e318190018c 19131886
França EL, Calderon Ide M, Vieira EL, Morceli G, Honorio-França AC. 2012. Transfer of maternal immunity to newborns of diabetic mothers. Clin Dev Immunol. 2012:928187. 10.1155/2012/928187 22991568
Franceschi S, Lise M, Clifford G, Rickenbach M, Levi F, Maspoli M, Bouchardy C, Dehler S, Jundt G, Ess S, et al. 2010. Changing patterns of cancer incidence in the early- and late-HAART periods: The Swiss HIV Cohort Study. Br J Cancer. 103:416–422. 10.1038/sj.bjc.6605756 20588274
Franceschi S, Maso LD, Rickenbach M, Polesel J, Hirschel B, Cavassini M, Bordoni A, Elzi L, Ess S, Jundt G, et al. 2008. Kaposi sarcoma incidence in the Swiss HIV Cohort Study before and after highly active antiretroviral therapy. Br J Cancer. 99(5):800–804. 10.1038/sj.bjc.6604520 18665172
Franzetti M, Adorni F, Parravicini C, Vergani B, Antinori S, Milazzo L, Galli M, Ridolfo AL. 2013. Trends and predictors of non-AIDS-defining cancers in men and women with HIV infection: A single-institution retrospective study before and after the introduction of HAART. J Acquir Immune Defic Syndr. 62(4):414–420. 10.1097/QAI.0b013e318282a189 23274934
Frisch M, Biggar RJ, Engels EA, Goedert JJ, Group AI-CMRS. 2001. Association of cancer with AIDS-related immunosuppression in adults. JAMA. 285(13):1736–1745. 10.1001/jama.285.13.1736 11277828
Frisch M, Biggar RJ, Goedert JJ. 2000. Human papillomavirus-associated cancers in patients with human immunodeficiency virus infection and acquired immunodeficiency syndrome. J Natl Cancer Inst. 92(18):1500–1510. 10.1093/jnci/92.18.1500 10995805
Fukumoto H, Sato Y, Hasegawa H, Katano H. 2013. Frequent detection of Merkel cell polyomavirus DNA in sera of HIV-1-positive patients. Virol J. 10:84. 10.1186/1743-422X-10-84 23496956
Gadducci A, Barsotti C, Cosio S, Domenici L, Riccardo Genazzani A. 2011. Smoking habit, immune suppression, oral contraceptive use, and hormone replacement therapy use and cervical carcinogenesis: A review of the literature. Gynecol Endocrinol. 27(8):597–604. 10.3109/09513590.2011.558953 21438669
Galceran J, Marcos-Gragera R, Soler M, Romaguera A, Ameijide A, Izquierdo A, Borràs J, de Sanjosé S, Casabona J. 2007. Cancer incidence in AIDS patients in Catalonia, Spain. Eur J Cancer. 43(6):1085–1091. 10.1016/j.ejca.2007.01.028 17349785
Gantt S, Casper C. 2011. Human herpesvirus 8-associated neoplasms: The roles of viral replication and antiviral treatment. Curr Opin Infect Dis. 24(4):295–301. 10.1097/QCO.0b013e3283486d04 21666458
Gantt S, Cattamanchi A, Krantz E, Magaret A, Selke S, Kuntz SR, Huang ML, Corey L, Wald A, Casper C. 2014. Reduced human herpesvirus-8 oropharyngeal shedding associated with protease inhibitor-based antiretroviral therapy. J Clin Virol. 60(2):127–132. 10.1016/j.jcv.2014.03.002 24698158
Gelu-Simeon M, Sobesky R, Haïm-Boukobza S, Ostos M, Teicher E, Fontaine H, Salmon-Ceron D, Meyer L, Trinchet JC, Paule B, et al. 2014. Do the epidemiology, physiological mechanisms and characteristics of hepatocellular carcinoma in HIV-infected patients justify specific screening policies? AIDS. 28(10):1379–1391. 10.1097/QAD.0000000000000300 24785953
Giagkou E, Christodoulou DK, Katsanos KH. 2016. Mouth cancer in inflammatory bowel diseases. Oral Dis. 22(4):260–264. 10.1111/odi.12420 26671147
Gichuhi S, Ohnuma S, Sagoo MS, Burton MJ. 2014. Pathophysiology of ocular surface squamous neoplasia. Exp Eye Res. 129:172–182. 10.1016/j.exer.2014.10.015 25447808
Gichuhi S, Sagoo MS, Weiss HA, Burton MJ. 2013. Epidemiology of ocular surface squamous neoplasia in Africa. Trop Med Int Health. 18(12):1424–1443. 10.1111/tmi.12203 24237784
Gillison ML. 2009. Oropharyngeal cancer: A potential consequence of concomitant HPV and HIV infection. Curr Opin Oncol. 21(5):439–444. 10.1097/CCO.0b013e32832f3e1b 19587593
Gillison ML, Chaturvedi AK, Anderson WF, Fakhry C. 2015. Epidemiology of Human Papillomavirus-Positive Head and Neck Squamous Cell Carcinoma. J Clin Oncol. 33(29):3235–3242. 10.1200/JCO.2015.61.6995 26351338
Gillison ML, D’Souza G, Westra W, Sugar E, Xiao W, Begum S, Viscidi R. 2008. Distinct risk factor profiles for human papillomavirus type 16-positive and human papillomavirus type 16-negative head and neck cancers. J Natl Cancer Inst. 100(6):407–420. 10.1093/jnci/djn025 18334711
Glaser SL, Clarke CA, Gulley ML, Craig FE, DiGiuseppe JA, Dorfman RF, Mann RB, Ambinder RF. 2003. Population-based patterns of human immunodeficiency virus-related Hodgkin lymphoma in the Greater San Francisco Bay Area, 1988-1998. Cancer. 98(2):300–309. 10.1002/cncr.11459 12872349
Gloghini A, Dolcetti R, Carbone A. 2013. Lymphomas occurring specifically in HIV-infected patients: From pathogenesis to pathology. Semin Cancer Biol. 23(6):457–467. 10.1016/j.semcancer.2013.08.004 23999127
Goedert JJ, Bower M. 2012. Impact of highly effective antiretroviral therapy on the risk for Hodgkin lymphoma among people with human immunodeficiency virus infection. Curr Opin Oncol. 24(5):531–536. 10.1097/CCO.0b013e3283560697 22729154
Goedert JJ, Coté TR. 1995. Conjunctival malignant disease with AIDS in USA. Lancet. 346(8969):257–258. 10.1016/S0140-6736(95)91309-2 7616836
Goedert JJ, Coté TR, Virgo P, Scoppa SM, Kingma DW, Gail MH, Jaffe ES, Biggar RJ. 1998. Spectrum of AIDS-associated malignant disorders. Lancet. 351(9119):1833–1839. 10.1016/S0140-6736(97)09028-4 9652666
Gopal S, Achenbach CJ, Yanik EL, Dittmer DP, Eron JJ, Engels EA. 2014. Moving forward in HIV-associated cancer. J Clin Oncol. 32(9):876–880. 10.1200/JCO.2013.53.1376 24550416
Graham CS, Baden LR, Yu E, Mrus JM, Carnie J, Heeren T, Koziel MJ. 2001. Influence of human immunodeficiency virus infection on the course of hepatitis C virus infection: A meta-analysis. Clin Infect Dis. 33(4):562–569. 10.1086/321909 11462196
Gravitt PE, Kirk GD. 2010. Progress and pitfalls in defining the influence of highly active antiretroviral therapy on human papillomavirus-associated cervical disease. J Infect Dis. 201(5):650–652. 10.1086/650468 20105079
Grivennikov SI, Karin M. 2011. Inflammatory cytokines in cancer: Tumour necrosis factor and interleukin 6 take the stage. Ann Rheum Dis. 70 Suppl 1:i104–i108. 10.1136/ard.2010.140145 21339211
Grulich AE. 1999. AIDS-associated non-Hodgkin’s lymphoma in the era of highly active antiretroviral therapy. J Acquir Immune Defic Syndr. 21 Suppl 1:S27–S30. 10430215
Grulich AE, Li Y, McDonald A, Correll PK, Law MG, Kaldor JM. 2002. Rates of non-AIDS-defining cancers in people with HIV infection before and after AIDS diagnosis. AIDS. 16(8):1155–1161. 10.1097/00002030-200205240-00009 12004274
Grulich AE, Li Y, McDonald AM, Correll PK, Law MG, Kaldor JM. 2001. Decreasing rates of Kaposi’s sarcoma and non-Hodgkin’s lymphoma in the era of potent combination anti-retroviral therapy. AIDS. 15(5):629–633. 10.1097/00002030-200103300-00013 11317001
Grulich AE, van Leeuwen MT, Falster MO, Vajdic CM. 2007. Incidence of cancers in people with HIV/AIDS compared with immunosuppressed transplant recipients: A meta-analysis. Lancet. 370(9581):59–67. 10.1016/S0140-6736(07)61050-2 17617273
Guech-Ongey M, Engels EA, Goedert JJ, Biggar RJ, Mbulaiteye SM. 2008. Elevated risk for squamous cell carcinoma of the conjunctiva among adults with AIDS in the United States. Int J Cancer. 122(11):2590–2593. 10.1002/ijc.23384 18224690
Guiguet M, Boué F, Cadranel J, Lang JM, Rosenthal E, Costagliola D. 2009. Effect of immunodeficiency, HIV viral load, and antiretroviral therapy on the risk of individual malignancies (FHDH-ANRS CO4): A prospective cohort study. Lancet Oncol. 10(12):1152–1159. 10.1016/S1470-2045(09)70282-7 19818686
Harnly ME, Swan SH, Holly EA, Kelter A, Padian N. 1988. Temporal trends in the incidence of non-Hodgkin’s lymphoma and selected malignancies in a population with a high incidence of acquired immunodeficiency syndrome (AIDS). Am J Epidemiol. 128(2):261–267. 10.1093/oxfordjournals.aje.a114966 3394695
He B, Qiao X, Klasse PJ, Chiu A, Chadburn A, Knowles DM, Moore JP, Cerutti A. 2006. HIV-1 envelope triggers polyclonal Ig class switch recombination through a CD40-independent mechanism involving BAFF and C-type lectin receptors. J Immunol. 176(7):3931–3941. 10.4049/jimmunol.176.7.3931 16547227
Hecht FM, Wellman R, Busch MP, Pilcher CD, Norris PJ, Margolick JB, Collier AC, Little SJ, Markowitz M, Routy JP, et al. 2011. Identifying the early post-HIV antibody seroconversion period. J Infect Dis. 204(4):526–533. 10.1093/infdis/jir304 21791654
Helleberg M, May MT, Ingle SM, Dabis F, Reiss P, Fätkenheuer G, Costagliola D, d’Arminio A, Cavassini M, Smith C, et al. 2015. Smoking and life expectancy among HIV-infected individuals on antiretroviral therapy in Europe and North America. AIDS. 29(2):221–229. 10.1097/QAD.0000000000000540 25426809
Henderson WA, Shankar R, Gill JM, Kim KH, Ghany MG, Skanderson M, Butt AA. 2010. Hepatitis C progressing to hepatocellular carcinoma: The HCV dialysis patient in dilemma. J Viral Hepat. 17(1):59–64. 10.1111/j.1365-2893.2009.01151.x 19566787
Herndier BG, Shiramizu BT, Jewett NE, Aldape KD, Reyes GR, McGrath MS. 1992. Acquired immunodeficiency syndrome-associated T-cell lymphoma: Evidence for human immunodeficiency virus type 1-associated T-cell transformation. Blood. 79(7):1768–1774. 10.1182/blood.V79.7.1768.1768 1373087
Hessol NA, Holly EA, Efird JT, Minkoff H, Schowalter K, Darragh TM, Burk RD, Strickler HD, Greenblatt RM, Palefsky JM. 2009. Anal intraepithelial neoplasia in a multisite study of HIV-infected and high-risk HIV-uninfected women. AIDS. 23(1):59–70. 10.1097/QAD.0b013e32831cc101 19050387
Hessol NA, Katz MH, Liu JY, Buchbinder SP, Rubino CJ, Holmberg SD. 1992. Increased incidence of Hodgkin disease in homosexual men with HIV infection. Ann Intern Med. 117(4):309–311. 10.7326/0003-4819-117-4-309 1637026
Hessol NA, Martínez-Maza O, Levine AM, Morris A, Margolick JB, Cohen MH, Jacobson LP, Seaberg EC. 2015. Lung cancer incidence and survival among HIV-infected and uninfected women and men. AIDS. 29(10):1183–1193. 10.1097/QAD.0000000000000690 25888645
Hessol NA, Pipkin S, Schwarcz S, Cress RD, Bacchetti P, Scheer S. 2007. The impact of highly active antiretroviral therapy on non-AIDS-defining cancers among adults with AIDS. Am J Epidemiol. 165(10):1143–1153. 10.1093/aje/kwm017 17344204
Hill AB. 1965. The environment and disease: Association or causation? Proc R Soc Med. 58:295–300. 10.1177/003591576505800503 14283879
Hleyhel M, Belot A, Bouvier AM, Tattevin P, Pacanowski J, Genet P, De Castro N, Berger JL, Dupont C, Lavole A, et al. 2013. Risk of AIDS-defining cancers among HIV-1-infected patients in France between 1992 and 2009: Results from the FHDH-ANRS CO4 cohort. Clin Infect Dis. 57(11):1638–1647. 10.1093/cid/cit497 23899679
Hleyhel M, Hleyhel M, Bouvier AM, Belot A, Tattevin P, Pacanowski J, Genet P, De Castro N, Berger JL, Dupont C, et al. 2014. Risk of non-AIDS-defining cancers among HIV-1-infected individuals in France between 1997 and 2009: Results from a French cohort. AIDS. 28(14):2109–2118. 10.1097/QAD.0000000000000382 25265077
Holkar S, Mudhar HS, Jain A, Gupta M, Rogstad KE, Parsons MA, Singh AD, Rennie IG. 2005. Regression of invasive conjunctival squamous carcinoma in an HIV-positive patient on antiretroviral therapy. Int J STD AIDS. 16(12):782–783. 10.1258/095646205774988028 16336757
Hussain SK, Zhu W, Chang SC, Breen EC, Vendrame E, Magpantay L, Widney D, Conn D, Sehl M, Jacobson LP, et al. 2013. Serum levels of the chemokine CXCL13, genetic variation in CXCL13 and its receptor CXCR5, and HIV-associated non-hodgkin B-cell lymphoma risk. Cancer Epidemiol Biomarkers Prev. 22(2):295–307. 10.1158/1055-9965.EPI-12-1122 23250934
International Agency for Research on Cancer (IARC). 1996. IARC Working Group on the Evaluation of Carcinogenic Risks to Humans. Lyon, France: International Agency for Research on Cancer; Human Immunodeficiency Viruses and Human T-Cell Lymphotropic Viruses; p. 447.
International Agency for Research on Cancer (IARC). 1997. IARC Working Group on the Evaluation of Carcinogenic Risks to Humans. Lyon, France: International Agency for Research on Cancer; Epstein-Barr virus and Kaposi’s sarcoma herpesvirus/human herpesvirus 8; p. 549.
International Agency for Research on Cancer (IARC). 2000. IARC Working Group on the Evaluation of Carcinogenic Risks to Humans. Lyon, France: International Agency for Research on Cancer; Some antiviral and antineoplastic drugs, and other pharmaceutical agents; p. 689.
International Agency for Research on Cancer (IARC). 2007. IARC Working Group on the Evaluation of Carcinogenic Risks to Humans. Lyon, France: International Agency for Research on Cancer; Human Papillomaviruses; p. 689.
International Agency for Research on Cancer (IARC). 2012 a. Human immunodeficiency virus-1. Biological Agents. Lyon, France: International Agency for Research on Cancer; p. 215–253.
International Agency for Research on Cancer (IARC). 2012 b. Biological Agents. Lyon, France: International Agency for Research on Cancer; Epstein-Barr virus; p. 49–92.
International Collaboration on HIV and Cancer (ICHIVC). 2000. Highly active antiretroviral therapy and incidence of cancer in human immunodeficiency virus-infected adults. J Natl Cancer Inst. 92(22):1823–1830. 10.1093/jnci/92.22.1823 11078759
Ipp H, Zemlin A. 2013. The paradox of the immune response in HIV infection: When inflammation becomes harmful. Clin Chim Acta. 416:96–99. 10.1016/j.cca.2012.11.025 23228847
Ipp H, Zemlin AE, Erasmus RT, Glashoff RH. 2014. Role of inflammation in HIV-1 disease progression and prognosis. Crit Rev Clin Lab Sci. 51(2):98–111. 10.3109/10408363.2013.865702 24479745
Ippolito G, Puro V, Heptonstall J, Jagger J, De Carli G, Petrosillo N. 1999. Occupational human immunodeficiency virus infection in health care workers: Worldwide cases through September 1997. Clin Infect Dis. 28(2):365–383. 10.1086/515101 10064256
Iscovich J, Boffetta P, Franceschi S, Azizi E, Sarid R. 2000. Classic kaposi sarcoma: Epidemiology and risk factors. Cancer. 88(3):500–517. 10.1002/(SICI)1097-0142(20000201)88:3<500::AID-CNCR3>3.0.CO;2-9 10649240
Ives NJ, Gazzard BG, Easterbrook PJ. 2001. The changing pattern of AIDS-defining illnesses with the introduction of highly active antiretroviral therapy (HAART) in a London clinic. J Infect. 42(2):134–139. 10.1053/jinf.2001.0810 11531320
Izikson L, Nornhold E, Iyer JG, Nghiem P, Zeitouni NC. 2011. Merkel cell carcinoma associated with HIV: Review of 14 patients. AIDS. 25(1):119–121. 10.1097/QAD.0b013e328340a19c 21119325
Joint United Nations Programme on HIV/AIDS (UNAIDS). 2013a. Global report update on HIV treatment 2013: Results, impact and opportunities. Joint United Nations Programme on HIV/AIDS. https://www.unaids.org/sites/default/files/sub_landing/files/20130630_treatment_report_en_3.pdf. [Accessed: September 8, 2015]
Joint United Nations Programme on HIV/AIDS (UNAIDS). 2013 b. Global report: UNAIDS report on the global AIDS epidemic 2013. Joint United Nations Programme on HIV/AIDS.
Joint United Nations Programme on HIV/AIDS (UNAIDS). 2013c. Global report 2013: Fact sheet. United Nations. https://www.unaids.org/en/resources/campaigns/globalreport2013/factsheet. [Accessed: September 8, 2015]
Joshi D, O’Grady J, Dieterich D, Gazzard B, Agarwal K. 2011. Increasing burden of liver disease in patients with HIV infection. Lancet. 377(9772):1198–1209. 10.1016/S0140-6736(10)62001-6 21459211
Kaiser Family Foundation. 2015. The global HIV/AIDS epidemic. Menlo Park, CA: Henry J. Kaiser Family Foundation. https://kff.org/global-health-policy/fact-sheet/the-global-hivaids-epidemic/. [Accessed: September 9, 2015]
Kaplan LD. 2012. HIV-associated lymphoma. Best Pract Res Clin Haematol. 25(1):101–117. 10.1016/j.beha.2012.01.001 22409827
Kesselring A, Gras L, Smit C, van Twillert G, Verbon A, de Wolf F, Reiss P, Wit F. 2011. Immunodeficiency as a risk factor for non-AIDS-defining malignancies in HIV-1-infected patients receiving combination antiretroviral therapy. Clin Infect Dis. 52(12):1458–1465. 10.1093/cid/cir207 21628488
Kestelyn P, Stevens AM, Ndayambaje A, Hanssens M, van de Perre P. 1990. HIV and conjunctival malignancies. Lancet. 336(8706):51–52. 10.1016/0140-6736(90)91562-O 1973230
Kirk GD, Merlo C, O' Driscoll P, Mehta SH, Galai N, Vlahov D, Samet J, Engels EA. 2007. HIV infection is associated with an increased risk for lung cancer, independent of smoking. Clin Infect Dis. 45(1):103–110. 10.1086/518606 17554710
Kramer JR, Giordano TP, Souchek J, Richardson P, Hwang LY, El-Serag HB. 2005. The effect of HIV coinfection on the risk of cirrhosis and hepatocellular carcinoma in U.S. veterans with hepatitis C. Am J Gastroenterol. 100(1):56–63. 10.1111/j.1572-0241.2005.40670.x 15654781
Kramer JR, Kowalkowski MA, Duan Z, Chiao EY. 2015. The effect of HIV viral control on the incidence of hepatocellular carcinoma in veterans with hepatitis C and HIV coinfection. J Acquir Immune Defic Syndr. 68(4):456–462. 10.1097/QAI.0000000000000494 25559606
Kreimer AR, Alberg AJ, Daniel R, Gravitt PE, Viscidi R, Garrett ES, Shah KV, Gillison ML. 2004. Oral human papillomavirus infection in adults is associated with sexual behavior and HIV serostatus. J Infect Dis. 189(4):686–698. 10.1086/381504 14767823
Kreimer AR, Pierce Campbell CM, Lin HY, Fulp W, Papenfuss MR, Abrahamsen M, Hildesheim A, Villa LL, Salmerón JJ, Lazcano-Ponce E, et al. 2013. Incidence and clearance of oral human papillomavirus infection in men: The HIM cohort study. Lancet. 382(9895):877–887. 10.1016/S0140-6736(13)60809-0 23827089
Kristal AR, Nasca PC, Burnett WS, Mikl J. 1988. Changes in the epidemiology of non-Hodgkin’s lymphoma associated with epidemic human immunodeficiency virus (HIV) infection. Am J Epidemiol. 128(4):711–718. 10.1093/oxfordjournals.aje.a115024 3421237
Kundu RK, Sangiorgi F, Wu LY, Pattengale PK, Hinton DR, Gill PS, Maxson R. 1999. Expression of the human immunodeficiency virus-Tat gene in lymphoid tissues of transgenic mice is associated with B-cell lymphoma. Blood. 94(1):275–282. 10.1182/blood.V94.1.275.413a30_275_282 10381523
Lambert AA, Merlo CA, Kirk GD. 2013. Human immunodeficiency virus-associated lung malignancies. Clin Chest Med. 34(2):255–272. 10.1016/j.ccm.2013.01.008 23702175
Lanoy E, Costagliola D, Engels EA. 2010. Skin cancers associated with HIV infection and solid-organ transplantation among elderly adults. Int J Cancer. 126(7):1724–1731. 10.1002/ijc.24931 19810102
Lanoy E, Dores GM, Madeleine MM, Toro JR, Fraumeni JF Jr, Engels EA. 2009. Epidemiology of nonkeratinocytic skin cancers among persons with AIDS in the United States. AIDS. 23(3):385–393. 10.1097/QAD.0b013e3283213046 19114864
Leiss JK, Ratcliffe JM, Lyden JT, Sousa S, Orelien JG, Boal WL, Jagger J. 2006. Blood exposure among paramedics: Incidence rates from the national study to prevent blood exposure in paramedics. Ann Epidemiol. 16(9):720–725. 10.1016/j.annepidem.2005.12.007 16581265
Leitao MM Jr, White P, Cracchiolo B. 2008. Cervical cancer in patients infected with the human immunodeficiency virus. Cancer. 112(12):2683–2689. 10.1002/cncr.23504 18438877
Levine AM, Seaberg EC, Hessol NA, Preston-Martin S, Silver S, Cohen MH, Anastos K, Minkoff H, Orenstein J, Dominguez G, et al. 2010. HIV as a risk factor for lung cancer in women: Data from the Women’s Interagency HIV Study. J Clin Oncol. 28(9):1514–1519. 10.1200/JCO.2009.25.6149 20177022
Li M, Saghafi N, Freymiller E, Basile JR, Lin YL. 2013. Metastatic Merkel cell carcinoma of the oral cavity in a human immunodeficiency virus-positive patient and the detection of Merkel cell polyomavirus. Oral Surg Oral Med Oral Pathol Oral Radiol. 115(5):e66–e71. 10.1016/j.oooo.2012.09.002 23246177
Limketkai BN, Mehta SH, Sutcliffe CG, Higgins YM, Torbenson MS, Brinkley SC, Moore RD, Thomas DL, Sulkowski MS. 2012. Relationship of liver disease stage and antiviral therapy with liver-related events and death in adults coinfected with HIV/HCV. JAMA. 308(4):370–378. 10.1001/jama.2012.7844 22820790
Long JL, Engels EA, Moore RD, Gebo KA. 2008. Incidence and outcomes of malignancy in the HAART era in an urban cohort of HIV-infected individuals. AIDS. 22(4):489–496. 10.1097/QAD.0b013e3282f47082 18301061
Louie KS, de Sanjose S, Mayaud P. 2009. Epidemiology and prevention of human papillomavirus and cervical cancer in sub-Saharan Africa: A comprehensive review. Trop Med Int Health. 14(10):1287–1302. 10.1111/j.1365-3156.2009.02372.x 19772550
Lubin JH, Blot WJ. 1984. Assessment of lung cancer risk factors by histologic category. J Natl Cancer Inst. 73(2):383–389. 10.1093/jnci/73.2.383 6087006
Lundgren JD, Melbye M, Pedersen C, Rosenberg PS, Gerstoft J. 1995. Changing patterns of Kaposi’s sarcoma in Danish acquired immunodeficiency syndrome patients with complete follow-up. The Danish Study Group for HIV Infection (DASHI). Am J Epidemiol. 141(7):652–658. 10.1093/oxfordjournals.aje.a117481 7702040
Lyter DW, Bryant J, Thackeray R, Rinaldo CR, Kingsley LA. 1995. Incidence of human immunodeficiency virus-related and nonrelated malignancies in a large cohort of homosexual men. J Clin Oncol. 13(10):2540–2546. 10.1200/JCO.1995.13.10.2540 7595705
Machalek DA, Poynten M, Jin F, Fairley CK, Farnsworth A, Garland SM, Hillman RJ, Petoumenos K, Roberts J, Tabrizi SN, et al. 2012. Anal human papillomavirus infection and associated neoplastic lesions in men who have sex with men: A systematic review and meta-analysis. Lancet Oncol. 13(5):487–500. 10.1016/S1470-2045(12)70080-3 22445259
Maldarelli F, Wu X, Su L, Simonetti FR, Shao W, Hill S, Spindler J, Ferris AL, Mellors JW, Kearney MF, et al. 2014. HIV latency. Specific HIV integration sites are linked to clonal expansion and persistence of infected cells. Science. 345(6193):179–183. 10.1126/science.1254194 24968937
Mallet V, Vallet-Pichard A, Pol S. 2011. The impact of human immunodeficiency virus on viral hepatitis. Liver Int. 31 Suppl 1:135–139. 10.1111/j.1478-3231.2010.02394.x 21205151
Martínez-Maza O, Breen EC. 2002. B-cell activation and lymphoma in patients with HIV. Curr Opin Oncol. 14(5):528–532. 10.1097/00001622-200209000-00009 12192272
Mbulaiteye SM, Biggar RJ, Goedert JJ, Engels EA. 2003. Immune deficiency and risk for malignancy among persons with AIDS. J Acquir Immune Defic Syndr. 32(5):527–533. 10.1097/00126334-200304150-00010 12679705
Mbulaiteye SM, Katabira ET, Wabinga H, Parkin DM, Virgo P, Ochai R, Workneh M, Coutinho A, Engels EA. 2006. Spectrum of cancers among HIV-infected persons in Africa: The Uganda AIDS-Cancer Registry Match Study. Int J Cancer. 118(4):985–990. 10.1002/ijc.21443 16106415
McDonald SA, Hutchinson SJ, Bird SM, Mills PR, Dillon J, Bloor M, Robertson C, Donaghy M, Hayes P, Graham L, et al. 2009. A population-based record linkage study of mortality in hepatitis C-diagnosed persons with or without HIV coinfection in Scotland. Stat Methods Med Res. 18(3):271–283. 10.1177/0962280208094690 19036907
McGinnis KA, Fultz SL, Skanderson M, Conigliaro J, Bryant K, Justice AC. 2006. Hepatocellular carcinoma and non-Hodgkin’s lymphoma: The roles of HIV, hepatitis C infection, and alcohol abuse. J Clin Oncol. 24(31):5005–5009. 10.1200/JCO.2006.05.7984 17075119
Medscape. 2016. HIV Disease. WebMD. https://www.webmd.com/hiv-aids/default.htm. [Last updated on April 7, 2016]
Melbye M, Coté TR, Kessler L, Gail M, Biggar RJ. 1994. High incidence of anal cancer among AIDS patients. The AIDS/Cancer Working Group. Lancet. 343(8898):636–639. 10.1016/S0140-6736(94)92636-0 7906812
Merchante N, Merino E, López-Aldeguer J, Jover F, Delgado-Fernández M, Galindo MJ, Ortega E, Rivero A, Mínguez C, Romero-Palacios A, et al. 2013. Increasing incidence of hepatocellular carcinoma in HIV-infected patients in Spain. Clin Infect Dis. 56(1):143–150. 10.1093/cid/cis777 22955438
Mesri EA, Feitelson MA, Munger K. 2014. Human viral oncogenesis: A cancer hallmarks analysis. Cell Host Microbe. 15(3):266–282. 10.1016/j.chom.2014.02.011 24629334
Meys R, Gotch FM, Bunker CB. 2010. Human papillomavirus in the era of highly active antiretroviral therapy for human immunodeficiency virus: An immune reconstitution-associated disease? Br J Dermatol. 162(1):6–11. 10.1111/j.1365-2133.2009.09365.x 19709102
Mincione GP, Taddei GL, Wolovsky M, Calzolari A, Mincione F. 1992. Detection of human papillomavirus (HPV) DNA type 6/11 in a conjunctival papilloma by in situ hybridization with biotinylated probes. Pathologica. 84(1092):483–488. 1337200
Moore PS, Chang Y. 2014. The conundrum of causality in tumor virology: The cases of KSHV and MCV. Semin Cancer Biol. 26:4–12. 10.1016/j.semcancer.2013.11.001 24304907
Moore PS, Chang YA. 2010. Why do viruses cause cancer? Highlights of the first century of human tumour virology. Nat Rev Cancer. 10(12):878–889. 10.1038/nrc2961 21102637
Moore RD, Kessler H, Richman DD, Flexner C, Chaisson RE. 1991. Non-Hodgkin’s lymphoma in patients with advanced HIV infection treated with zidovudine. JAMA. 265(17):2208–2211. 10.1001/jama.1991.03460170062034 2013953
Mounier N, Spina M, Spano JP. 2010. Hodgkin lymphoma in HIV positive patients. Curr HIV Res. 8(2):141–146. 10.2174/157016210790442704 20163350
Muñoz A, Schrager LK, Bacellar H, Speizer I, Vermund SH, Detels R, Saah AJ, Kingsley LA, Seminara D, Phair JP. 1993. Trends in the incidence of outcomes defining acquired immunodeficiency syndrome (AIDS) in the Multicenter AIDS Cohort Study: 1985-1991. Am J Epidemiol. 137(4):423–438. 10.1093/oxfordjournals.aje.a116691 8096356
Murphy G, Parry JV. 2008. Assays for the detection of recent infections with human immunodeficiency virus type 1. Euro Surveill. 13(36). 10.2807/ese.13.36.18966-en 18775293
Mutalima N, Molyneux E, Jaffe H, Kamiza S, Borgstein E, Mkandawire N, Liomba G, Batumba M, Lagos D, Gratrix F, et al. 2008. Associations between Burkitt lymphoma among children in Malawi and infection with HIV, EBV and malaria: Results from a case-control study. PLoS One. 3(6):e2505. 10.1371/journal.pone.0002505 18560562
National Cancer Institute (NCI). 2015a. SEER Stat Fact Sheets: Liver and intrahepatic bile duct cancer. Bethesda, MD: National Cancer Institute. https://seer.cancer.gov/statfacts/html/livibd.html. [Accessed: September 9, 2015]
National Cancer Institute (NCI). 2015b. SEER stat fact sheets: Cervix uteri cancer. Bethesda, MD: National Cancer Institute. https://seer.cancer.gov/statfacts/html/cervix.html. [Accessed: September 9, 2015]
National Cancer Institute (NCI). 2015c. SEER Stat Fact Sheets: Lung and bronchus cancer. Bethesda, MD: National Cancer Institute. https://seer.cancer.gov/statfacts/html/lungb.html. [Accessed: September 9, 2015]
National Cancer Institute (NCI). 2015d. SEER Stat Fact Sheets: Vulvar cancer. Bethesda, MD: National Cancer Institute. https://seer.cancer.gov/statfacts/html/vulva.html. [Accessed: September 9, 2015]
National Cancer Institute (NCI). 2015e. SEER stat fact sheets: Anal cancer. Bethesda, MD: National Cancer Institute. https://seer.cancer.gov/statfacts/html/anus.html. [Accessed: September 9, 2015]
National Cancer Institute (NCI). 2015f. SEER stat fact sheets: Hodgkin lymphoma. Bethesda, MD: National Cancer Institute. https://seer.cancer.gov/statfacts/html/hodg.html. [Accessed: September 9, 2015]
National Cancer Institute (NCI). 2015g. SEER Stat Fact Sheets: Oral cavity and pharynx cancer. Bethesda, MD: National Cancer Institute. https://seer.cancer.gov/statfacts/html/oralcav.html. [Accessed: September 9, 2015]
National Cancer Institute (NCI). 2015h. SEER stat fact sheets: Non-Hodgkin lymphoma. Bethesda, MD: National Cancer Institute. https://seer.cancer.gov/statfacts/html/nhl.html. [Accessed: September 9, 2015]
National Institute of Allergy and Infectious Diseases (NIAID). 2009. More on how HIV causes AIDS. National Institutes of Allergy and Infectious Disease. http://www.niaid.nih.gov/topics/HIVAIDS/Understanding/howHIVCausesAIDS/Pages/howhiv.aspx. [Accessed: September 25, 2015]
National Institute of Allergy and Infectious Diseases (NIAID). 2015. HIV vaccine research. National Institute of Allergy and Infectious Diseases. http://www.niaid.nih.gov/topics/hivaids/research/vaccines/Pages/default.aspx. [Accessed: October 27, 2015]
National Toxicology Program (NTP). 2003. Report on Carcinogens background document for human papillomaviruses: Genital-mucosal types. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health. http://ntp.niehs.nih.gov/ntp/newhomeroc/roc11/hpv_rg2_public_508.pdf#HPV.
National Toxicology Program (NTP). 2013 a. Toxicology and carcinogenesis studies of mixtures of 3′-azido-3′-deoxythymidine (AZT), lamivudine (3TC), nevirapine (NVP) and nelfinavir mesylate (NFV) (CAS Nos. 30516-87-1, 134678-17-4, 129618-40-2, 159989-65-8) in B6C3F1 mice (transplacental exposure studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health.
National Toxicology Program (NTP). 2013 b. Toxicology and carcinogenicity study of mixtures of 3′-azido-3′ deoxythymidine (AZT), lamivudine (3TC), and nevirapine (NVP) (CAS nos. 30516-87-1, 134678-17-4, 129618-40-2) in genetically modified C3B6.129F1-Trp53tm1brd N12 haploinsufficient mice (in utero and postnatal gavage study). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health.
National Toxicology Program (NTP). 2013 c. Toxicology and carcinogenicity studies of 3′-azido-3′-deoxythymidine (CAS No. 30516-87-1) in genetically modified C3B6.129F1-Trp53tm1brd N12 haploinsufficient mice (in utero and postnatal gavage study). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health.
National Toxicology Program (NTP). 2014 a. Report on Carcinogens. 13th ed. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; Human papillomaviruses: Some genital-mucosal types.
National Toxicology Program (NTP). 2014b. Hepatitis C Virus. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health. https://ntp.niehs.nih.gov/pubhealth/roc/roc13/index.html.
National Toxicology Program (NTP). 2014c. Hepatitis B Virus. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health. https://ntp.niehs.nih.gov/pubhealth/roc/roc13/index.html.
National Toxicology Program (NTP). 2015. Handbook for preparing the Report on Carcinogens monographs. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health. https://ntp.niehs.nih.gov/ntp/roc/handbook/roc_handbook_508.pdf.
Neuhaus J, Jacobs DR Jr, Baker JV, Calmy A, Duprez D, La Rosa A, Kuller LH, Pett SL, Ristola M, Ross MJ, et al. 2010. Markers of inflammation, coagulation, and renal function are elevated in adults with HIV infection. J Infect Dis. 201(12):1788–1795. 10.1086/652749 20446848
Newell ML, Thorne C. 2004. Antiretroviral therapy and mother-to-child transmission of HIV-1. Expert Rev Anti Infect Ther. 2(5):717–732. 10.1586/14789072.2.5.717 15482235
Newnham A, Harris J, Evans HS, Evans BG, Moller H. 2005. The risk of cancer in HIV-infected people in southeast England: A cohort study. Br J Cancer. 92(1):194–200. 10.1038/sj.bjc.6602273 15583689
Newton R, Grulich A, Beral V, Sindikubwabo B, Ngilimana PJ, Nganyira A, Parkin DM. 1995. Cancer and HIV infection in Rwanda. Lancet. 345(8961):1378–1379. 10.1016/S0140-6736(95)92583-X 7752795
Newton R, Ziegler J, Beral V, Mbidde E, Carpenter L, Wabinga H, Mbulaiteye S, Appleby P, Reeves G, Jaffe H. 2001. A case-control study of human immunodeficiency virus infection and cancer in adults and children residing in Kampala, Uganda. Int J Cancer. 92(5):622–627. 10.1002/1097-0215(20010601)92:5<622::AID-IJC1256>3.0.CO;2-K 11340563
Ng BE, Butler LM, Horvath T, Rutherford GW. 2011. Population-based biomedical sexually transmitted infection control interventions for reducing HIV infection. Cochrane Database Syst Rev.(3):CD001220. 10.1002/14651858.CD001220.pub3 21412869
Nunnari G, Berretta M, Pinzone MR, Di Rosa M, Berretta S, Cunsolo G, Malaguarnera M, Cosentino S, De Paoli S, Schnell JM, et al. 2012. Hepatocellular carcinoma in HIV positive patients. Eur Rev Med Pharmacol Sci. 16(9):1257–1270. 23047511
Olsen CM, Knight LL, Green AC. 2014. Risk of melanoma in people with HIV/AIDS in the pre- and post-HAART eras: A systematic review and meta-analysis of cohort studies. PLoS One. 9(4):e95096. 10.1371/journal.pone.0095096 24740329
Palefsky J. 2009. Human papillomavirus-related disease in people with HIV. Curr Opin HIV AIDS. 4(1):52–56. 10.1097/COH.0b013e32831a7246 19339939
Palmeira P, Quinello C, Silveira-Lessa AL, Zago CA, Carneiro-Sampaio M. 2012. IgG placental transfer in healthy and pathological pregnancies. Clin Dev Immunol. 2012(985646). 10.1155/2012/985646 22235228
Park LS, Tate JP, Rodriguez-Barradas MC, Rimland D, Goetz MB, Gibert C, Brown ST, Kelley MJ, Justice AC, Dubrow R. 2014. Cancer incidence in HIV-infected versus uninfected veterans: Comparison of cancer registry and ICD-9 code diagnoses. J AIDS Clin Res. 5(7):1000318. 25580366
Park LS, Tate JP, Rodriguez-Barradas MC, Rimland D, Goetz MB, Gibert C, Brown ST, Kelley MJ, Justice AC, Dubrow R. 2016. Prevalence of non-HIV cancer risk factors in persons living with HIV/AIDS: A meta-analysis. AIDS. 30(2):273–291. 10.1097/QAD.0000000000000922 26691548
Patel P, Armon C, Chmiel JS, Brooks JT, Buchacz K, Wood K, Novak RM. 2014. Factors associated with cancer incidence and with all-cause mortality after cancer diagnosis among human immunodeficiency virus-infected persons during the combination antiretroviral therapy era. Open Forum Infect Dis. 1(1):ofu012. 10.1093/ofid/ofu012 25734086
Patel P, Hanson DL, Sullivan PS, Novak RM, Moorman AC, Tong TC, Holmberg SD, Brooks JT. 2008. Incidence of types of cancer among HIV-infected persons compared with the general population in the United States. Ann Intern Med. 148(10):728–736. 10.7326/0003-4819-148-10-200805200-00005 18490686
Paulson KG, Iyer JG, Blom A, Warton EM, Sokil M, Yelistratova L, Schuman L, Nagase K, Bhatia S, Asgari MM, et al. 2013. Systemic immune suppression predicts diminished Merkel cell carcinoma-specific survival independent of stage. J Invest Dermatol. 133(3):642–646. 10.1038/jid.2012.388 23190897
Penn I. 1986. Cancer is a complication of severe immunosuppression. Surg Gynecol Obstet. 162(6):603–610. 3520906
Penn I. 1988. Tumors of the immunocompromised patient. Annu Rev Med. 39:63–73. 10.1146/annurev.me.39.020188.000431 3285791
Penn I, Starzl TE. 1973. Immunosuppression and cancer. Transplant Proc. 5(1):943–947. 4735211
Pernot S, Terme M, Zaanan A, Tartour E, Weiss L, Taieb J. 2014. Immunity and squamous cell carcinoma of the anus: Epidemiological, clinical and therapeutic aspects. Clin Res Hepatol Gastroenterol. 38(1):18–23. 10.1016/j.clinre.2013.07.002 23932704
Petrara MR, Freguja R, Gianesin K, Zanchetta M, De Rossi A. 2013. Epstein-Barr virus-driven lymphomagenesis in the context of human immunodeficiency virus type 1 infection. Front Microbiol. 4:311. 10.3389/fmicb.2013.00311 24151490
Phelps RM, Smith DK, Heilig CM, Gardner LI, Carpenter CC, Klein RS, Jamieson DJ, Vlahov D, Schuman P, Holmberg SD. 2001. Cancer incidence in women with or at risk for HIV. Int J Cancer. 94(5):753–757. 10.1002/ijc.1528 11745473
Pickard RK, Xiao W, Broutian TR, He X, Gillison ML. 2012. The prevalence and incidence of oral human papillomavirus infection among young men and women, aged 18-30 years. Sex Transm Dis. 39(7):559–566. 10.1097/OLQ.0b013e31824f1c65 22706220
Piketty C, Selinger-Leneman H, Grabar S, Duvivier C, Bonmarchand M, Abramowitz L, Costagliola D, Mary-Krause M, Fhdh-Anrs CO. 2008. Marked increase in the incidence of invasive anal cancer among HIV-infected patients despite treatment with combination antiretroviral therapy. AIDS. 22(10):1203–1211. 10.1097/QAD.0b013e3283023f78 18525266
Pine SR, Mechanic LE, Enewold L, Chaturvedi AK, Katki HA, Zheng YL, Bowman ED, Engels EA, Caporaso NE, Harris CC. 2011. Increased levels of circulating interleukin 6, interleukin 8, C-reactive protein, and risk of lung cancer. J Natl Cancer Inst. 103(14):1112–1122. 10.1093/jnci/djr216 21685357
Pinzone MR, Berretta M, Cacopardo B, Nunnari G. 2015. Epstein-Barr virus- and Kaposi sarcoma-associated herpesvirus-related malignancies in the setting of human immunodeficiency virus infection. Semin Oncol. 42(2):258–271. 10.1053/j.seminoncol.2014.12.026 25843730
Piriou ER, van Dort K, Nanlohy NM, Miedema F, van Oers MH, van Baarle D. 2004. Altered EBV viral load setpoint after HIV seroconversion is in accordance with lack of predictive value of EBV load for the occurrence of AIDS-related non-Hodgkin lymphoma. J Immunol. 172(11):6931–6937. 10.4049/jimmunol.172.11.6931 15153512
Pluda JM, Venzon DJ, Tosato G, Lietzau J, Wyvill K, Nelson DL, Jaffe ES, Karp JE, Broder S, Yarchoan R. 1993. Parameters affecting the development of non-Hodgkin’s lymphoma in patients with severe human immunodeficiency virus infection receiving antiretroviral therapy. J Clin Oncol. 11(6):1099–1107. 10.1200/JCO.1993.11.6.1099 8099121
Pluda JM, Yarchoan R, Jaffe ES, Feuerstein IM, Solomon D, Steinberg SM, Wyvill KM, Raubitschek A, Katz D, Broder S. 1990. Development of non-Hodgkin lymphoma in a cohort of patients with severe human immunodeficiency virus (HIV) infection on long-term antiretroviral therapy. Ann Intern Med. 113(4):276–282. 10.7326/0003-4819-113-4-276 1973886
Polesel J, Clifford GM, Rickenbach M, Dal Maso L, Battegay M, Bouchardy C, Furrer H, Hasse B, Levi F, Probst-Hensch NM, et al. 2008. Non-Hodgkin lymphoma incidence in the Swiss HIV Cohort Study before and after highly active antiretroviral therapy. AIDS. 22(2):301–306. 10.1097/QAD.0b013e3282f2705d 18097233
Powles T, Robinson D, Stebbing J, Shamash J, Nelson M, Gazzard B, Mandelia S, Moller H, Bower M. 2009. Highly active antiretroviral therapy and the incidence of non-AIDS-defining cancers in people with HIV infection. J Clin Oncol. 27(6):884–890. 10.1200/JCO.2008.19.6626 19114688
Rabkin CS, Biggar RJ, Horm JW. 1991. Increasing incidence of cancers associated with the human immunodeficiency virus epidemic. Int J Cancer. 47(5):692–696. 10.1002/ijc.2910470511 2004849
Rabkin CS, Hilgartner MW, Hedberg KW, Aledort LM, Hatzakis A, Eichinger S, Eyster ME, White GC 2nd, Kessler CM, Lederman MM, et al. 1992. Incidence of lymphomas and other cancers in HIV-infected and HIV-uninfected patients with hemophilia. JAMA. 267(8):1090–1094. 10.1001/jama.1992.03480080060027 1735926
Rabkin CS, Yellin F. 1994. Cancer incidence in a population with a high prevalence of infection with human immunodeficiency virus type 1. J Natl Cancer Inst. 86(22):1711–1716. 10.1093/jnci/86.22.1711 7966400
Raffetti E, Albini L, Gotti D, Segala D, Maggiolo F, di Filippo E, Saracino A, Ladisa N, Lapadula G, Fornabaio C, et al. 2015. Cancer incidence and mortality for all causes in HIV-infected patients over a quarter century: A multicentre cohort study. BMC Public Health. 15:235. 10.1186/s12889-015-1565-0 25884678
Ragni MV, Belle SH, Jaffe RA, Duerstein SL, Bass DC, McMillan CW, Lovrien EW, Aledort LM, Kisker CT, Stabler SP, et al. 1993. Acquired immunodeficiency syndrome-associated non-Hodgkin’s lymphomas and other malignancies in patients with hemophilia. Blood. 81(7):1889–1897. 10.1182/blood.V81.7.1889.1889 8461474
Rapezzi D, Ugolini D, Ferraris AM, Racchi O, Gaetani GF. 2001. Histological subtypes of Hodgkin’s disease in the setting of HIV infection. Ann Hematol. 80(6):340–344. 10.1007/s002770100294 11475147
Reekie J, Kosa C, Engsig F, Monforte A, Wiercinska-Drapalo A, Domingo P, Antunes F, Clumeck N, Kirk O, Lundgren JD, et al. 2010. Relationship between current level of immunodeficiency and non-acquired immunodeficiency syndrome-defining malignancies. Cancer. 116(22):5306–5315. 10.1002/cncr.25311 20661911
Reniers G, Watkins S. 2010. Polygyny and the spread of HIV in sub-Saharan Africa: A case of benign concurrency. AIDS. 24(2):299–307. 10.1097/QAD.0b013e328333af03 19890204
Reszec J, Sulkowski S. 2005. The expression of P53 protein and infection of human papilloma virus in conjunctival and eyelid neoplasms. Int J Mol Med. 16(4):559–564. 16142387
Reynolds P, Saunders LD, Layefsky ME, Lemp GF. 1993. The spectrum of acquired immunodeficiency syndrome (AIDS)-associated malignancies in San Francisco, 1980-1987. Am J Epidemiol. 137(1):19–30. 10.1093/oxfordjournals.aje.a116598 8434570
Robbins HA, Pfeiffer RM, Shiels MS, Li J, Hall HI, Engels EA. 2015. Excess cancers among HIV-infected people in the United States. J Natl Cancer Inst. 107(4). 10.1093/jnci/dju503 25663691
Ross R, Dworsky R, Paganini-Hill A, Levine A, Mack T. 1985. Non-Hodgkin’s lymphomas in never married men in Los Angeles. Br J Cancer. 52(5):785–787. 10.1038/bjc.1985.258 4063152
Rothman KJ, Greenland S. 2005. Causation and causal inference in epidemiology. Am J Public Health. 95 Suppl 1:S144–S150. 10.2105/AJPH.2004.059204 16030331
Ruiz M. 2010. Early lung cancer detection in HIV: The role of CT screening in high risk cases. HIV Clin. 22(1):1–5. 20333820
Sahasrabuddhe VV, Shiels MS, McGlynn KA, Engels EA. 2012. The risk of hepatocellular carcinoma among individuals with acquired immunodeficiency syndrome in the United States. Cancer. 118(24):6226–6233. 10.1002/cncr.27694 22736272
Schneider E, Whitmore S, Glynn KM, Dominguez K, Mitsch A, McKenna MT. 2008. Revised surveillance case definitions for HIV infection among adults, adolescents, and children aged <18 months and for HIV infection and AIDS among children aged 18 months to <13 years--United States, 2008. MMWR Recomm Rep. 57(Rr-10):1-12.
Seaberg EC, Wiley D, Martinez-Maza O, Chmiel JS, Kingsley L, Tang Y, Margolick JB, Jacobson LP, Multicenter Aids Cohort S. 2010. Cancer incidence in the multicenter AIDS Cohort Study before and during the HAART era: 1984 to 2007. Cancer. 116(23):5507–5516. 10.1002/cncr.25530 20672354
Sekar D, Hairul Islam VI, Thirugnanasambantham K, Saravanan S. 2014. Relevance of miR-21 in HIV and non-HIV-related lymphomas. Tumour Biol. 35(9):8387–8393. 10.1007/s13277-014-2068-9 24961346
Serraino D, Angeletti C, Carrieri MP, Longo B, Piche M, Piselli P, Arbustini E, Burra P, Citterio F, Colombo V, et al. 2005. Kaposi’s sarcoma in transplant and HIV-infected patients: An epidemiologic study in Italy and France. Transplantation. 80(12):1699–1704. 10.1097/01.tp.0000187864.65522.10 16378064
Serraino D, Boschini A, Carrieri P, Pradier C, Dorrucci M, Dal Maso L, Ballarini P, Pezzotti P, Smacchia C, Pesce A, et al. 2000. Cancer risk among men with, or at risk of, HIV infection in southern Europe. AIDS. 14(5):553–559. 10.1097/00002030-200003310-00011 10780718
Serraino D, Carbone A, Franceschi S, Tirelli U. 1993. Increased frequency of lymphocyte depletion and mixed cellularity subtypes of Hodgkin’s disease in HIV-infected patients. Italian Cooperative Group on AIDS and Tumours. Eur J Cancer. 29a(14):1948–1950. 10.1016/0959-8049(93)90450-T 8280487
Serraino D, Piselli P, Busnach G, Burra P, Citterio F, Arbustini E, Baccarani U, De Juli E, Pozzetto U, Bellelli S, et al. 2007. Risk of cancer following immunosuppression in organ transplant recipients and in HIV-positive individuals in southern Europe. Eur J Cancer. 43(14):2117–2123. 10.1016/j.ejca.2007.07.015 17764927
Sgadari C, Monini P, Barillari G, Ensoli B. 2003. Use of HIV protease inhibitors to block Kaposi’s sarcoma and tumour growth. Lancet Oncol. 4(9):537–547. 10.1016/S1470-2045(03)01192-6 12965274
Shackelford J, Pagano JS. 2007. Role of the ubiquitin system and tumor viruses in AIDS-related cancer. BMC Biochem. 8 Suppl 1(Suppl 1):S8.
Shiels MS, Cole SR, Kirk GD, Poole C. 2009. A meta-analysis of the incidence of non-AIDS cancers in HIV-infected individuals. J Acquir Immune Defic Syndr. 52(5):611–622. 10.1097/QAI.0b013e3181b327ca 19770804
Shiels MS, Cole SR, Mehta SH, Kirk GD. 2010. Lung cancer incidence and mortality among HIV-infected and HIV-uninfected injection drug users. J Acquir Immune Defic Syndr. 55(4):510–515. 10.1097/QAI.0b013e3181f53783 20838223
Shiels MS, Pfeiffer RM, Gail MH, Hall HI, Li J, Chaturvedi AK, Bhatia K, Uldrick TS, Yarchoan R, Goedert JJ, et al. 2011 a. Cancer burden in the HIV-infected population in the United States. J Natl Cancer Inst. 103(9):753–762. 10.1093/jnci/djr076 21483021
Shiels MS, Pfeiffer RM, Hall HI, Li J, Goedert JJ, Morton LM, Hartge P, Engels EA. 2011 b. Proportions of Kaposi sarcoma, selected non-Hodgkin lymphomas, and cervical cancer in the United States occurring in persons with AIDS, 1980-2007. JAMA. 305(14):1450–1459. 10.1001/jama.2011.396 21486978
Shiramizu B, Herndier BG, McGrath MS. 1994. Identification of a common clonal human immunodeficiency virus integration site in human immunodeficiency virus-associated lymphomas. Cancer Res. 54(8):2069–2072. 8174106
Sigel K, Wisnivesky J, Gordon K, Dubrow R, Justice A, Brown ST, Goulet J, Butt AA, Crystal S, Rimland D, et al. 2012. HIV as an independent risk factor for incident lung cancer. AIDS. 26(8):1017–1025. 10.1097/QAD.0b013e328352d1ad 22382152
Silverberg MJ, Abrams DI. 2007. AIDS-defining and non-AIDS-defining malignancies: Cancer occurrence in the antiretroviral therapy era. Curr Opin Oncol. 19(5):446–451. 10.1097/CCO.0b013e3282c8c90d 17762569
Silverberg MJ, Chao C, Leyden WA, Xu L, Horberg MA, Klein D, Towner WJ, Dubrow R, Quesenberry CP Jr, Neugebauer RS, et al. 2011. HIV infection, immunodeficiency, viral replication, and the risk of cancer. Cancer Epidemiol Biomarkers Prev. 20(12):2551–2559. 10.1158/1055-9965.EPI-11-0777 22109347
Silverberg MJ, Chao C, Leyden WA, Xu L, Tang B, Horberg MA, Klein D, Quesenberry CP Jr, Towner WJ, Abrams DI. 2009. HIV infection and the risk of cancers with and without a known infectious cause. AIDS. 23(17):2337–2345. 10.1097/QAD.0b013e3283319184 19741479
Silverberg MJ, Leyden W, Warton EM, Quesenberry CP Jr, Engels EA, Asgari MM. 2013. HIV infection status, immunodeficiency, and the incidence of non-melanoma skin cancer. J Natl Cancer Inst. 105(5):350–360. 10.1093/jnci/djs529 23291375
Silverberg MJ, Neuhaus J, Bower M, Gey D, Hatzakis A, Henry K, Hidalgo J, Lourtau L, Neaton JD, Tambussi G, et al. 2007. Risk of cancers during interrupted antiretroviral therapy in the SMART study. AIDS. 21(14):1957–1963. 10.1097/QAD.0b013e3282ed6338 17721103
Simard EP, Pfeiffer RM, Engels EA. 2010. Spectrum of cancer risk late after AIDS onset in the United States. Arch Intern Med. 170(15):1337–1345. 10.1001/archinternmed.2010.253 20696958
Simard EP, Shiels MS, Bhatia K, Engels EA. 2012. Long-term cancer risk among people diagnosed with AIDS during childhood. Cancer Epidemiol Biomarkers Prev. 21(1):148–154. 10.1158/1055-9965.EPI-11-0823 22068287
Singh DK, Anastos K, Hoover DR, Burk RD, Shi Q, Ngendahayo L, Mutimura E, Cajigas A, Bigirimani V, Cai X, et al. 2009. Human papillomavirus infection and cervical cytology in HIV-infected and HIV-uninfected Rwandan women. J Infect Dis. 199(12):1851–1861. 10.1086/599123 19435429
Sissolak G, Sissolak D, Jacobs P. 2010. Human immunodeficiency and Hodgkin lymphoma. Transfus Apher Sci. 42(2):131–139. 10.1016/j.transci.2010.01.008 20138008
Smit PW, Sollis KA, Fiscus S, Ford N, Vitoria M, Essajee S, Barnett D, Cheng B, Crowe SM, Denny T, et al. 2014. Systematic review of the use of dried blood spots for monitoring HIV viral load and for early infant diagnosis. PLoS One. 9(3):e86461. 10.1371/journal.pone.0086461 24603442
Stanley MA, Winder DM, Sterling JC, Goon PK. 2012. HPV infection, anal intra-epithelial neoplasia (AIN) and anal cancer: Current issues. BMC Cancer. 12:398. 10.1186/1471-2407-12-398 22958276
Stefan DC, Wessels G, Poole J, Wainwright L, Stones D, Johnston WT, Newton R. 2011. Infection with human immunodeficiency virus-1 (HIV) among children with cancer in South Africa. Pediatr Blood Cancer. 56(1):77–79. 10.1002/pbc.22672 21110416
Stein AP, Saha S, Kraninger JL, Swick AD, Yu M, Lambert PF, Kimple RJ. 2015. Prevalence of human papillomavirus in oropharyngeal cancer: A systematic review. Cancer J. 21(3):138–146. 10.1097/PPO.0000000000000115 26049691
Stein L, Urban MI, O’Connell D, Yu XQ, Beral V, Newton R, Ruff P, Donde B, Hale M, Patel M, et al. 2008. The spectrum of human immunodeficiency virus-associated cancers in a South African black population: Results from a case-control study, 1995-2004. Int J Cancer. 122(10):2260–2265. 10.1002/ijc.23391 18241034
Sulkowski MS, Thomas DL, Chaisson RE, Moore RD. 2000. Hepatotoxicity associated with antiretroviral therapy in adults infected with human immunodeficiency virus and the role of hepatitis C or B virus infection. JAMA. 283(1):74–80. 10.1001/jama.283.1.74 10632283
Sun EC, Fears TR, Goedert JJ. 1997. Epidemiology of squamous cell conjunctival cancer. Cancer Epidemiol Biomarkers Prev. 6(2):73–77. 9037556
Tabrizi SN, McCurrach FE, Drewe RH, Borg AJ, Garland SM, Taylor HR. 1997. Human papillomavirus in corneal and conjunctival carcinoma. Aust N Z J Ophthalmol. 25(3):211–215. 10.1111/j.1442-9071.1997.tb01394.x 9296295
Tolstov YL, Knauer A, Chen JG, Kensler TW, Kingsley LA, Moore PS, Chang Y. 2011. Asymptomatic primary Merkel cell polyomavirus infection among adults. Emerg Infect Dis. 17(8):1371–1380. 10.3201/eid1708.110079 21801612
Tong WW, Hillman RJ, Kelleher AD, Grulich AE, Carr A. 2014. Anal intraepithelial neoplasia and squamous cell carcinoma in HIV-infected adults. HIV Med. 15(2):65–76. 10.1111/hiv.12080 24007498
Tradati F, Colombo M, Mannucci PM, Rumi MG, De Fazio C, Gamba G, Ciavarella N, Rocino A, Morfini M, Scaraggi A, et al. 1998. A prospective multicenter study of hepatocellular carcinoma in italian hemophiliacs with chronic hepatitis C. The Study Group of the Association of Italian Hemophilia Centers. Blood. 91(4):1173–1177. 9454746
United Nations Special Session on HIV/AIDS. 2001. Fact sheet: Mother-to-child transmission of HIV. 25-27 June 2001, New York: United Nations Special Session on HIV/AIDS. https://www.un.org/ga/aids/ungassfactsheets/html/fsmotherchild_en.htm. [Accessed: September 8, 2015]
U.S. Department of Health and Human Services (DHHS). 2015a. Guidelines for the use of antiretroviral agents in pediatric HIV infection. Washington, DC: U.S. Department of Health and Human Services. https://aidsinfo.nih.gov/contentfiles/lvguidelines/pediatricguidelines.pdf.
U.S. Department of Health and Human Services (DHHS). 2015b. Guidelines for the use of antiretroviral agents in HIV-1-infected adults and adolescents. Washington, DC: U.S. Department of Health and Human Services. https://aidsinfo.nih.gov/contentfiles/lvguidelines/adultandadolescentgl.pdf.
Vaccher E, Serraino D, Carbone A, De Paoli P. 2014. The evolving scenario of non-AIDS-defining cancers: Challenges and opportunities of care. Oncologist. 19(8):860–867. 10.1634/theoncologist.2014-0024 24969164
Vajdic CM, van Leeuwen MT, McDonald SP, McCredie MR, Law M, Chapman JR, Webster AC, Kaldor JM, Grulich AE. 2007. Increased incidence of squamous cell carcinoma of eye after kidney transplantation. J Natl Cancer Inst. 99(17):1340–1342. 10.1093/jnci/djm085 17698951
van Leeuwen MT, Vajdic CM, Middleton MG, McDonald AM, Law M, Kaldor JM, Grulich AE. 2009. Continuing declines in some but not all HIV-associated cancers in Australia after widespread use of antiretroviral therapy. AIDS. 23(16):2183–2190. 10.1097/QAD.0b013e328331d384 19734774
Veugelers PJ, Strathdee SA, Moss AR, Page KA, Tindall B, Schechter MT, Coutinho RA, van Griensven GJ. 1995. Is the human immunodeficiency virus-related Kaposi’s sarcoma epidemic coming to an end? Insights from the Tricontinental Seroconverter Study. Epidemiology. 6(4):382–386. 10.1097/00001648-199507000-00009 7548345
Vogel M, Friedrich O, Luchters G, Holleczek B, Wasmuth JC, Anadol E, Schwarze-Zander C, Nattermann J, Oldenburg J, Sauerbruch T, et al. 2011. Cancer risk in HIV-infected individuals on HAART is largely attributed to oncogenic infections and state of immunocompetence. Eur J Med Res. 16(3):101–107. 10.1186/2047-783X-16-3-101 21486722
Waddell K, Magyezi J, Bousarghin L, Coursaget P, Lucas S, Downing R, Casabonne D, Newton R. 2003. Antibodies against human papillomavirus type 16 (HPV-16) and conjunctival squamous cell neoplasia in Uganda. Br J Cancer. 88(12):2002–2003. 10.1038/sj.bjc.6600950 12799649
Waddell KM, Lewallen S, Lucas SB, Atenyi-Agaba C, Herrington CS, Liomba G. 1996. Carcinoma of the conjunctiva and HIV infection in Uganda and Malawi. Br J Ophthalmol. 80(6):503–508. 10.1136/bjo.80.6.503 8759259
Wang HB, Mo QH, Yang Z. 2015. HIV vaccine research: The challenge and the way forward. J Immunol Res. 2015:503978. 10.1155/2015/503978 25861656
Wieland U, Kreuter A. 2011. Merkel cell polyomavirus infection and Merkel cell carcinoma in HIV-positive individuals. Curr Opin Oncol. 23(5):488–493. 10.1097/CCO.0b013e3283495a5b 21734578
Wieland U, Silling S, Scola N, Potthoff A, Gambichler T, Brockmeyer NH, Pfister H, Kreuter A. 2011. Merkel cell polyomavirus infection in HIV-positive men. Arch Dermatol. 147(4):401–406. 10.1001/archdermatol.2011.42 21482890
Winstone TA, Man SFP, Hull M, Montaner JS, Sin DD. 2013. Epidemic of lung cancer in patients with HIV infection. Chest. 143(2):305–314. 10.1378/chest.12-1699 23381313
Wistuba II, Behrens C, Milchgrub S, Virmani AK, Jagirdar J, Thomas B, Ioachim HL, Litzky LA, Brambilla EM, Minna JD, et al. 1998. Comparison of molecular changes in lung cancers in HIV-positive and HIV-indeterminate subjects. JAMA. 279(19):1554–1559. 10.1001/jama.279.19.1554 9605900
Witt KL, Cunningham CK, Patterson KB, Kissling GE, Dertinger SD, Livingston E, Bishop JB. 2007. Elevated frequencies of micronucleated erythrocytes in infants exposed to zidovudine in utero and postpartum to prevent mother-to-child transmission of HIV. Environ Mol Mutagen. 48(3-4):322–329. 10.1002/em.20266 17358032
World Health Organization (WHO). 2007. WHO case definitions of HIV for surveillance and revised clinical staging and immunological classification of HIV-related disease in adults and children. Geneva, Switzerland: World Health Organization.
World Health Organization (WHO). 2013. Consolidated guidelines on the use of antiretroviral drugs for treating and preventing HIV infection. Geneva, Switzerland: World Health Organization.
Yang J, Foster CS. 1997. Squamous cell carcinoma of the conjunctiva. Int Ophthalmol Clin. 37(4):73–85. 10.1097/00004397-199703740-00007 9429933
Zaleski L, Turiansky GW. 2010. Squamous cell carcinoma of the anal canal. Cutis. 85(3):143–145. 20408513
Zetola NM, Bernstein KT, Wong E, Louie B, Klausner JD. 2009. Exploring the relationship between sexually transmitted diseases and HIV acquisition by using different study designs. J Acquir Immune Defic Syndr. 50(5):546–551. 10.1097/QAI.0b013e318195bd2b 19367993
Zhang YX, Gui XE, Zhong YH, Rong YP, Yan YJ. 2011. Cancer in cohort of HIV-infected population: Prevalence and clinical characteristics. J Cancer Res Clin Oncol. 137(4):609–614. 10.1007/s00432-010-0911-y 20532560
Zhao H, Shu G, Wang S. 2015. The risk of non-melanoma skin cancer in HIV-infected patients: New data and meta-analysis. Int J STD AIDS. 25999166
Zoufaly A, Stellbrink HJ, Heiden MA, Kollan C, Hoffmann C, van Lunzen J, Hamouda O. 2009. Cumulative HIV viremia during highly active antiretroviral therapy is a strong predictor of AIDS-related lymphoma. J Infect Dis. 200(1):79–87. 10.1086/599313 19476437
zur Hausen H. 1994. Molecular pathogenesis of cancer of the cervix and its causation by specific human papillomavirus types. Curr Top Microbiol Immunol. 186:131–156. 10.1007/978-3-642-78487-3_8 8205839
zur Hausen H. 2001. Oncogenic DNA viruses. Oncogene. 20(54):7820–7823. 10.1038/sj.onc.1204958 11753664
zur Hausen H, de Villiers EM. 2014. Cancer “causation” by infections—individual contributions and synergistic networks. Semin Oncol. 41(6):860–875. 10.1053/j.seminoncol.2014.10.003 25499643