# Appendix A Literature Search Strategy

The objective of the literature search approach is to identify published literature that is relevant for evaluating the potential carcinogenicity of the HIV-1virus. As discussed in the Viruses Concept Document (https://ntp.niehs.nih.gov/ntp/roc/concept_docs/2014/virusesconcept_508.pdf), the monograph relies on the IARC monograph and studies published since the monograph (new studies). The literature search strategy was used to identify new human cancer studies and recent reviews of mechanistic data.

## A.1 General Approach

Database searching encompasses selecting databases and search terms and conducting the searches. Searches of several citation databases are generally conducted using search terms for the individual viruses of interest, combined with search terms for cancer and/or specific topics, including epidemiological and mechanistic studies. A critical step in the process involves consultation with an information specialist to develop relevant search terms. These terms are used to search bibliographic databases. IARC used literature found by searching PubMed for HIV-1 through 12/2008, so new information for these viruses were searched in PubMed from >2008 to August 2015.

The large and complex body of literature for HIV-1 was searched using narrowing terms for the relevant major topics within the bibliographic database. The results were then processed in EndNote to remove duplicates before being transferred to DistillerSR for screening. Table A-1 highlights the general concepts searched with selected example terms. To review all the terms used, please refer to the full search strings below.

Table A-1 Major Topics Searched

Topics | Example Terms
Human immunodeficiency virus | “HIV,” “human immunodeficiency virus,” “acquired immunodeficiency virus,” “HIV Infections”(MESH), “HIV-1”(MESH)
General cancer Relevant cancers | Neoplasms(MESH), tumor(s), leukemia Oral cancers, genital cancers, Hodgkin lymphoma, non-Hodgkin lymphoma, multiple myeloma
Study types Epidemiology terms | Case control, ecological studies, follow-up study Cohort, epidemiologic studies (MESH), epidemiology (Subheading)
Mechanistic terms Genetox terms | Mechanism of action, Key event, etiology (subheading) Aneuploidy, DNA-Adduct, DNA-synthes*, gene expression

Figure A-1

Literature Processing Flow

The wealth of literature in the subject of HIV lead to a focus on review literature. For mechanistic studies, a focus on the most recent reviews (2013 to 2015) allowed for an understanding of the most current advances in understanding the carcinogenic mechanism of HIV. To ensure full coverage of the non-AIDS-defining cancers, a specific search for cohort studies in primary literature was also conducted.

The bibliographic database search results (2,294) were processed in EndNote then imported into DistillerSR for first and second tier screening. Relevant studies found through the citations of review articles and other secondary search processes were also included. Tagging in DistillerSR categorized the useful articles into Human Epidemiologic literature (674) or Mechanistic literature (499).

## A.2 Search Strings for HIV Searches

### A.2.1 Cohort Studies (Primary Literature)

[underlined: PubMed]: 2009–2015

“HIV”[Ti] OR “HIV”[Other Term] OR “human immunodeficiency virus”[Ti] OR “human immunodeficiency virus”[Other Term] OR “HIV Infections”[mh] OR “HIV-1”[mh] OR “HIV”[Mesh:noexp] OR “acquired immunodeficiency virus”[tiab]

AND

cohort[tiab] OR Cohorts[tiab] OR cancer-registry[tiab] OR registries[tiab]

AND

Journal Article[ptyp] OR Meta-Analysis[ptyp] OR systematic[sb]

AND

List of general cancer terms (see Section A.2.2).

### A.2.2 Relevant Cancers and Epidemiology

[underlined: PubMed]: 2009–2015, Reviews only

“HIV Infections”[Mesh] OR “HIV”[Mesh:NoExp] OR “HIV-1”[Mesh] OR “HIV”[Title/Abstract] OR “HIV”[Other Term] OR “AIDS”[Title/Abstract] OR “AIDS”[Other Term] OR “human immunodeficiency virus”[Title/Abstract] OR “human immunodeficiency virus”[Other Term])

AND

(“Mouth Neoplasms/epidemiology”[Mesh] OR “Mouth Neoplasms/etiology”[Mesh] OR “Mouth Neoplasms/pathology”[Mesh] OR “Mouth Neoplasms/diagnosis”[Mesh] OR “Pharyngeal Neoplasms/epidemiology”[Mesh] OR “Pharyngeal Neoplasms/etiology”[Mesh] OR “Pharyngeal Neoplasms/pathology”[Mesh] OR “Pharyngeal Neoplasms/diagnosis”[Mesh] OR “Carcinoma, Hepatocellular/epidemiology”[Mesh] OR “Carcinoma, Hepatocellular/etiology”[Mesh] OR “Carcinoma, Hepatocellular/pathology”[Mesh] OR “Carcinoma, Hepatocellular/diagnosis”[Mesh] OR “Lung Neoplasms/epidemiology”[Mesh] OR “Lung Neoplasms/etiology”[Mesh] OR “Lung Neoplasms/pathology”[Mesh] OR “Lung Neoplasms/diagnosis”[Mesh] OR “Genital Neoplasms, Female/epidemiology”[Mesh] OR “Genital Neoplasms, Female/etiology”[Mesh] OR “Genital Neoplasms, Female/pathology”[Mesh] OR “Genital Neoplasms, Female/diagnosis”[Mesh] OR “Genital Neoplasms, Male/epidemiology”[Mesh] OR “Genital Neoplasms, Male/etiology”[Mesh] OR “Genital Neoplasms, Male/pathology”[Mesh] OR “Genital Neoplasms, Male/diagnosis”[Mesh] OR “Anus Neoplasms/epidemiology”[Mesh] OR “Anus Neoplasms/etiology”[Mesh] OR “Anus Neoplasms/pathology”[Mesh] OR “Anus Neoplasms/diagnosis”[Mesh] OR “Uterine Cervical Neoplasms/epidemiology”[Mesh] OR “Uterine Cervical Neoplasms/etiology”[Mesh] OR “Uterine Cervical Neoplasms/pathology”[Mesh] OR “Uterine Cervical Neoplasms/diagnosis”[Mesh] OR “Hodgkin Disease/epidemiology”[Mesh] OR “Hodgkin Disease/etiology”[Mesh] OR “Hodgkin Disease/pathology”[Mesh] OR “Hodgkin Disease/diagnosis”[Mesh] OR “Lymphoma, Non-Hodgkin/epidemiology”[Mesh] OR “Lymphoma, Non-Hodgkin/etiology”[Mesh] OR “Lymphoma, Non-Hodgkin/pathology”[Mesh] OR “Lymphoma, Non-Hodgkin/diagnosis”[Mesh] OR “Sarcoma, Kaposi/epidemiology”[Mesh] OR “Sarcoma, Kaposi/etiology”[Mesh] OR “Sarcoma, Kaposi/pathology”[Mesh] OR “Sarcoma, Kaposi/diagnosis”[Mesh] OR “Neoplasms/epidemiology”[Mesh] OR “Neoplasms/etiology”[Mesh] OR “Neoplasms/pathology”[Mesh] OR “Neoplasms/diagnosis”[Mesh]OR carcinogen*[Title/Abstract] OR carcinogen*[Other Term] OR tumor*[Title/Abstract] OR tumor*[Other Term] OR cancer[Title/Abstract] OR cancer[Other Term] OR cancers[Title/Abstract] OR cancers[Other Term]OR cancerous[Title/Abstract] OR cancerous[Other Term] OR “Kaposi sarcoma”[Title/Abstract] OR “Kaposi sarcoma”[Other Term] OR “Non-Hodgkin lymphoma”[Title/Abstract] OR “Non-Hodgkin lymphoma”[Other Term] OR “Hodgkin Lymphoma”[Title/Abstract] OR “Hodgkin Lymphoma”[Other Term] OR “Cervix cancer?”[Title/Abstract] OR “Cervix cancer?”[Other Term] OR “cervical cancer?”[Title/Abstract] OR “cervical cancer?”[Other Term] OR “Anal Cancer?”[Title/Abstract] OR “Anal Cancer?”[Other Term] OR “penis cancer?”[Title/Abstract] OR “penis cancer?”[Other Term] OR “penile cancer?”[Title/Abstract] OR “penile cancer?”[Other Term] OR “lung cancer?”[Title/Abstract] OR “lung cancer?”[Other Term] OR “liver cancer?”[Title/Abstract] OR “liver cancer?”[Other Term] OR “hepatocellular carcinoma?”[Title/Abstract] OR “hepatocellular carcinoma?”[Other Term] OR “lip cancer?”[Title/Abstract] OR “lip cancer?”[Other Term] OR “oral cancer?”[Title/Abstract] OR “oral cancer?”[Other Term] OR “pharyngeal cancer?”[Title/Abstract] OR “pharyngeal cancer?”[Other Term] OR “Pharynx Cancer?”[Title/Abstract] OR “Pharynx Cancer?”[Other Term] OR lymphoma[Title/Abstract] OR lymphoma[Other Term] OR “leukemia”[Title/Abstract] OR “leukemia”[Other Term] OR “multiple myeloma”[Title/Abstract] OR “multiple myeloma”[Other Term] OR “lymphohematopoietic cancer?”[Title/Abstract] OR “lymphohematopoietic cancer?”[Other Term] OR lymphomas[Title/Abstract] OR lymphomas[Other Term] OR leukemias[Title/Abstract] OR leukemias[Other Term] OR “multiple myelomas”[Title/Abstract] OR “multiple myelomas”[Other Term] OR “lymphohematopoietic cancers”[Title/Abstract] OR “lymphohematopoietic cancers”[Other Term]) AND (“Epidemiologic Studies”[Mesh] OR “epidemiology”[Subheading] OR “cohort?”[Title/Abstract] OR “cohort?”[Other Term] OR “case control”[Title/Abstract] OR “case control”[Other Term] OR “cohorts”[Title/Abstract] OR “cohorts”[Other Term] OR “ecological study”[Title/Abstract] OR “ecological study”[Other Term] OR “follow-up study”[Title/Abstract] OR “follow-up study”[Other Term] OR “ecological studies”[Title/Abstract] OR “ecological studies”[Other Term] OR “follow-up studies”[Title/Abstract] OR “follow-up studies”[Other Term] OR “occupational exposure?”[Title/Abstract] OR “occupational exposure?”[Other Term] OR “Worker?”[Title/Abstract] OR “Worker?”[Other Term] OR “Epidemiologic Methods”[Mesh] OR “occupational exposures”[Title/Abstract] OR “occupational exposures”[Other Term] OR “Workers”[Title/Abstract] OR “Workers”[Other Term])

### A.2.3 Mechanism

[underlined: PubMed]: 2013–2015, Reviews only

(“HIV”[Ti] OR “HIV”[Other Term] OR “human immunodeficiency virus”[Ti] OR “human immunodeficiency virus”[Other Term] OR “HIV Infections”[mh] OR “HIV-1”[mh] OR “HIV”[Mesh:NoExp] OR “acquired immunodeficiency virus”[tiab]) OR ((immunocompromised[tiab] OR “immunocompromise”[tiab] OR immune-suppressed[tiab] OR immune-suppression[tiab]))

AND

((cytotoxicities[tiab] OR Cytotoxicity[tiab] OR adverse-outcome-pathway*[tiab] OR Ames test[tiab] OR Aneuploid[tiab] OR Aneuploidy[tiab] OR angiogenesis[tiab] OR biomarkers[tiab] OR Cell-proliferation[tiab] OR Chromosom*[tiab] OR chronic-inflammation[tiab] OR chronically inflamed[tiab] OR Clastogen*[tiab] OR Comet-assay[tiab] OR Crosslink[tiab] OR Cytogenesis[tiab] OR Cytogenetic[tiab] OR Cytogenic[tiab] OR Cytotoxic[tiab] OR Cytotoxin[tiab] OR DNA-protein-crosslink*[tiab] OR DNA protein crosslinks[tiab] OR DNA-Adduct*[tiab] OR DNA-damag*[tiab] OR DNA-inhibit*[tiab] OR DNA-promot*[tiab] OR DNA-Repair[tiab] OR DNA-Repair inhibition [tiab] OR DNA-synthes*[tiab] OR down-regulate[tiab] OR down-regulated[tiab] OR down-regulating[tiab] OR down-regulation[tiab] OR down-regulator[tiab] OR epigenetic*[tiab] OR etiology[tiab] OR gene-Activation [tiab] OR gene-expression[tiab] OR Genetic-toxicology[tiab] OR Germ-line-mutation[tiab] OR Immunologic-Cytotoxicity [tiab] OR Key Event*[tiab] OR Key-Event[tiab] OR Mechanism-of-action[tiab] OR Mechanisms-of-action[tiab] OR Micronuclei[tiab] OR Micronucleus[tiab] OR Mode-of-action[tiab] OR modes-of-action[tiab] OR Molecular-Initiating-Event*[tiab] OR Mutagenic[tiab] OR Mutagenicity[tiab] OR Mutagens[tiab] OR neoplastic-cell-transform*[tiab] OR Oncogenes[tiab] OR Oncogenesis[tiab] OR Oncogenic[tiab] OR Oxidative-damage*[tiab] OR Oxidative-damage[tiab] OR Oxidative-stress[tiab] OR Oxidative-stress*[tiab] OR pathogenesis[tiab] OR Polyploid[tiab] OR Polyploidy[tiab] OR Strand-break*[tiab] OR toxic-pathway*[tiab] OR Toxicity-Pathway*[tiab] OR transcriptional-activat*[tiab] OR tumor-inhibition[tiab] OR tumor-promot*[tiab] OR tumor-promotion[tiab] OR Unscheduled-DNA-synthes*[tiab] OR up-regulate[tiab] OR up-regulated[tiab] OR up-regulating[tiab] OR up-regulation[tiab] OR up-regulator[tiab] OR miRNA[tiab] OR microRNA[tiab] OR SiRNA[tiab] OR small-inhibitory-RNA[tiab] OR Small-interfering-RNA[tiab] OR non-coding-RNA[tiab]))

AND

List of general cancer terms (see Section A.2.4).

### A.2.4 Cancer Terms

Neoplasms[mh] OR “American Cancer Society”[mh] OR “angiogenesis inducing agents”[mh] OR “antibodies, neoplasm”[mh] OR “antigens, neoplasm”[mh] OR “carcinogenicity tests”[mh] OR “carcinogens”[mh] OR clonal evolution[mh] OR “clonal evolution” OR “dna, neoplasm”[mh] OR “genes, neoplasm”[mh] OR leukostasis[mh] OR myelodysplastic-myeloproliferative diseases[mh] OR neoplasm proteins[mh] OR “neoplastic processes”[mh] OR “neoplastic stem cells”[mh] OR “oncogene fusion”[mh] OR “oncogenic viruses”[mh] OR “oncolytic viruses”[mh] OR “polyomavirus”[mh] OR “rna, neoplasm”[mh] OR “SEER program”[mh] OR “tumor lysis syndrome”[mh] OR “tumor markers, biological”[mh] OR AACR OR AJCC [tw] OR (ASCO NOT fungi) OR IARC OR “National Cancer Institute” OR AGCUS [tw] OR ASCUS [tw] OR ATLL [tw] OR CIN [tw] OR CLL [tw] OR CMML [tw] OR CMPD [tw] OR ECCL [tw] OR EGIST [tw] OR FMTC [tw] OR GLNH [tw] OR HNPCC [tw] OR HNSCC [tw] OR HPV [tw] OR HSIL [tw] OR ICD O [tw] OR JCML [tw] OR JMML [tw] OR LGLL [tw] OR MGUS [tw] OR MLH1[tw] OR MPD [tw] OR MSH2[tw] OR NSCLC [tw] OR RAEB [tw] OR RCMD [tw] OR SCLC [tw] OR VOD [tw] OR Neoplasm-Antibod*[tiab] OR Tumor Antibod*[tiab] OR Neoplasm-Antigen*[tiab] OR Tumor-Antigen*[tiab] OR SEER-program[tiab] OR carcinogenicity-test*[tiab] OR leukostasis[tiab] OR 5q syndrome [tw] OR BCR ABL [tw] OR c erbB 2 [tw] OR c erbB2 [tw] OR carney complex [tw] OR cone biopsy [tw] OR denys drash [tw] OR essential thrombocythemia [tw] OR estrogen receptor negative [tw] OR estrogen receptor positive [tw] OR li fraumeni [tw] OR meigs syndrome [tw] OR mycosis fungoides [tiab] OR peutz jeghers [tiab] OR sentinel lymph node[tiab] NOT biopsy[tiab] OR sezary syndrome [tiab] OR struma ovarii [tiab] OR zollinger ellison [tiab] OR aberrant-crypt-foci [tiab] OR Aberrant-crypt-focus[tiab] OR ((anti-n-methyl-d-aspartate [tiab] OR anti-nmda[tiab]) AND encephalitis[tiab]) OR (barrett [tiab] AND esophagus [tiab]) OR (gestational [tiab] AND trophoblastic [tiab]) OR (microsatellite [tiab] AND instability [tiab]) OR (paget [tiab] AND (breast [tiab] OR nipple [tiab])) OR (WAGR [tiab] AND syndrome [tiab]) OR acanthoma [tw] OR acanthomas [tw] OR acrochordon [tw] OR acrochordons [tw] OR acrospiroma [tw] OR acrospiromas [tw] OR adamantinoma [tw] OR adamantinomas [tw] OR adenoacanthoma [tw] OR adenoacanthomas [tw] OR adenoameloblastoma [tw] OR adenoameloblastomas [tw] OR adenocanthoma [tw] OR adenocanthomas [tw] OR adenocarcinoma [tw] OR adenocarcinomas [tw] OR adenofibroma [tw] OR adenofibromas [tw] OR adenolipoma [tw] OR adenolipomas [tw] OR adenolymphoma [tw] OR adenolymphomas [tw] OR adenoma [tw] OR adenomas [tw] OR adenomatosis [tw] OR adenomatous [tw] OR adenomyoepithelioma [tw] OR adenomyoepitheliomas [tw] OR adenomyoma [tw] OR adenomyomas [tw] OR adenosarcoma [tw] OR adenosarcomas [tw] OR adenosis [tw] OR aesthesioneuroblastoma [tw] OR aesthesioneuroblastomas [tw] OR ameloblastoma [tw] OR ameloblastomas [tw] OR amyloidoses [tw] OR amyloidosis [tw] OR anaplasia [tw] OR androblastoma [tw] OR androblastomas [tw] OR angioblastoma [tw] OR angioblastomas [tw] OR angioendothelioma [tw] OR angioendotheliomas [tw] OR angioendotheliomatosis [tw] OR angiofibroma [tw] OR angiofibromas [tw] OR angiofibrosarcoma [tw] OR angiogenesis factor [tw] OR angiokeratoma [tw] OR angiokeratomas [tw] OR angioleiomyoma [tw] OR angioleiomyomas [tw] OR angiolipoma [tw] OR angiolipomas [tw] OR angioma [tw] OR angiomas [tw] OR angiomatosis [tw] OR angiomyolipoma [tw] OR angiomyolipomas [tw] OR angiomyoma [tw] OR angiomyomas [tw] OR angiomyxoma [tw] OR angiomyxomas [tw] OR angioreticuloma [tw] OR angioreticulomas [tw] OR angiosarcoma [tw] OR angiosarcomas [tw] OR apudoma [tw] OR apudomas [tw] OR argentaffinoma [tw] OR argentaffinomas [tw] OR arrhenoblastoma [tw] OR arrhenoblastomas [tw] OR astroblastoma [tw] OR astroblastomas [tw] OR astrocytoma [tw] OR astrocytomas [tw] OR astroglioma [tw] OR astrogliomas [tw] OR atypia [tw] OR baltoma [tw] OR basiloma [tw] OR basilomas [tw] OR biochemotherapies [tw] OR Birt-Hogg-Dube [tw] OR blastoma [tw] OR blastomas [tw] OR Buschke-Lowenstein [tw] OR cachexia [tw] OR cancer [tw] OR cancerous [tw] OR cancers [tw] OR carcinogen [tw] OR carcinogenesis [tw] OR carcinogenic [tw] OR carcinogens [tw] OR carcinoid [tw] OR carcinoma [tw] OR carcinomas [tw] OR carcinomatosis [tw] OR carcinosarcoma [tw] OR carcinosarcomas [tw] OR cavernoma [tw] OR cavernomas [tw] OR cementoma [tw] OR cementomas [tw] OR cerbB2 [tw] OR ceruminoma [tw] OR ceruminomas [tw] OR chemodectoma [tw] OR chemodectomas [tw] OR cherubism [tw] OR chloroma [tw] OR chloromas [tw] OR cholangiocarcinoma [tw] OR cholangiocarcinomas [tw] OR cholangiohepatoma [tw] OR cholangioma [tw] OR cholangiomas [tw] OR cholangiosarcoma [tw] OR cholesteatoma [tw] OR cholesteatomas [tw] OR chondroblastoma [tw] OR chondroblastomas [tw] OR chondroma [tw] OR chondromas [tw] OR chondrosarcoma [tw] OR chondrosarcomas [tw] OR chordoma [tw] OR chordomas [tw] OR chorioadenoma [tw] OR chorioadenomas [tw] OR chorioangioma [tw] OR chorioangiomas [tw] OR choriocarcinoma [tw] OR choriocarcinomas [tw] OR chorioepithelioma [tw] OR chorioepitheliomas [tw] OR chorionepithelioma [tw] OR chorionepitheliomas [tw] OR choristoma [tw] OR choristomas [tw] OR chromaffinoma [tw] OR chromaffinomas [tw] OR cocarcinogenesis [tw] OR collagenoma [tw] OR collagenomas [tw] OR comedocarcinoma [tw] OR comedocarcinomas [tw] OR condyloma [tw] OR condylomas [tw] OR corticotropinoma [tw] OR corticotropinomas [tw] OR craniopharyngioma [tw] OR craniopharyngiomas [tw] OR cylindroma [tw] OR cylindromas [tw] OR cyst [tw] OR cysts [tw] OR cystadenocarcinoma [tw] OR cystadenocarcinomas [tw] OR cystadenofibroma [tw] OR cystadenofibromas [tw] OR cystadenoma [tw] OR cystadenomas [tw] OR cystoma [tw] OR cystomas [tw] OR cystosarcoma [tw] OR cystosarcomas [tw] OR dentinoma [tw] OR dentinomas [tw] OR dermatofibroma [tw] OR dermatofibromas [tw] OR dermatofibrosarcoma [tw] OR dermatofibrosarcomas [tw] OR dermoid [tw] OR desmoid [tw] OR desmoplastic [tw] OR dictyoma [tw] OR dysgerminoma [tw] OR dysgerminomas [tw] OR dyskeratoma [tw] OR dyskeratomas [tw] OR dysmyelopoiesis [tw] OR dysplasia [tw] OR dysplastic [tw] OR ectomesenchymoma [tw] OR ectomesenchymomas [tw] OR elastofibroma [tw] OR elastofibromas [tw] OR enchondroma [tw] OR enchondromas [tw] OR enchondromatosis [tw] OR endothelioma [tw] OR endotheliomas [tw] OR ependymoblastoma [tw] OR ependymoblastomas [tw] OR ependymoma [tw] OR ependymomas [tw] OR epidermoid [tw] OR epithelioma [tw] OR epitheliomas [tw] OR erythroleukaemia [tw] OR erythroleukaemias [tw] OR erythroleukemia [tw] OR erythroleukemias [tw] OR erythroplakia [tw] OR erythroplakias [tw] OR erythroplasia [tw] OR esthesioneuroblastoma [tw] OR esthesioneuroblastomas [tw] OR esthesioneuroepithelioma [tw] OR esthesioneuroepitheliomas [tw] OR exostosis [tw] OR fibroadenoma [tw] OR fibroadenomas [tw] OR fibroadenosarcoma [tw] OR fibroadenosis [tw] OR fibrochondrosarcoma [tw] OR fibroelastoma [tw] OR fibroelastomas [tw] OR fibroepithelioma [tw] OR fibroepitheliomas [tw] OR fibrofolliculoma [tw] OR fibrofolliculomas [tw] OR fibroid [tw] OR fibroids [tw] OR fibrolipoma [tw] OR fibrolipomas [tw] OR fibroliposarcoma [tw] OR fibroma [tw] OR fibromas [tw] OR fibromatosis [tw] OR fibromyoma [tw] OR fibromyomas [tw] OR fibromyxolipoma [tw] OR fibromyxoma [tw] OR fibromyxomas [tw] OR fibroodontoma [tw] OR fibroodontomas [tw] OR fibrosarcoma [tw] OR fibrosarcomas [tw] OR fibrothecoma [tw] OR fibrothecomas [tw] OR fibroxanthoma [tw] OR fibroxanthomas [tw] OR fibroxanthosarcoma [tw] OR fibroxanthosarcomas [tw] OR ganglioblastoma [tw] OR ganglioblastomas [tw] OR gangliocytoma [tw] OR gangliocytomas [tw] OR ganglioglioma [tw] OR gangliogliomas [tw] OR ganglioneuroblastoma [tw] OR ganglioneuroblastomas [tw] OR ganglioneurofibroma [tw] OR ganglioneurofibromas [tw] OR ganglioneuroma [tw] OR ganglioneuromas [tw] OR gastrinoma [tw] OR gastrinomas [tw] OR germinoma [tw] OR germinomas [tw] OR glioblastoma [tw] OR glioblastomas [tw] OR gliofibroma [tw] OR gliofibromas [tw] OR glioma [tw] OR gliomas [tw] OR gliomatosis [tw] OR glioneuroma [tw] OR glioneuromas [tw] OR gliosarcoma [tw] OR gliosarcomas [tw] OR glomangioma [tw] OR glomangiomas [tw] OR glomangiomatosis [tw] OR glomangiomyoma [tw] OR glomangiomyomas [tw] OR glomangiosarcoma [tw] OR glomangiosarcomas [tw] OR glucagonoma [tw] OR glucagonomas [tw] OR gonadoblastoma [tw] OR gonadoblastomas [tw] OR gonocytoma [tw] OR gonocytomas [tw] OR granuloma [tw] OR granulomas [tw] OR granulomatosis [tw] OR gynaecomastia [tw] OR gynandroblastoma [tw] OR gynecomastia [tw] OR haemangioblastoma [tw] OR haemangioblastomas [tw] OR haemangioma [tw] OR haemangiomas [tw] OR haemangiopericytoma [tw] OR haemangiopericytomas [tw] OR haemangiosarcoma [tw] OR haemangiosarcomas [tw] OR hamartoma [tw] OR hamartomas [tw] OR hemangioblastoma [tw] OR hemangioblastomas [tw] OR hemangioendothelioma [tw] OR hemangioendotheliomas [tw] OR hemangioendotheliosarcoma [tw] OR hemangioendotheliosarcomas [tw] OR hemangioma [tw] OR hemangiomas [tw] OR hemangiomatosis [tw] OR hemangiopericytoma [tw] OR hemangiopericytomas [tw] OR hemangioperithelioma [tw] OR hemangiosarcoma [tw] OR hemangiosarcomas [tw] OR hepatoblastoma [tw] OR hepatoblastomas [tw] OR hepatocarcinoma [tw] OR hepatocarcinomas [tw] OR hepatocholangiocarcinoma [tw] OR hepatocholangiocarcinomas [tw] OR hepatoma [tw] OR hepatomas [tw] OR hibernoma [tw] OR hibernomas [tw] OR hidradenoma [tw] OR hidradenomas [tw] OR hidrocystoma [tw] OR hidrocystomas [tw] OR histiocytoma [tw] OR histiocytomas [tw] OR hodgkin [tw] OR hodgkins [tw] OR hydatidiform [tw] OR hydradenoma [tw] OR hydradenomas [tw] OR hypernephroma [tw] OR hypernephromas [tw] OR immunocytoma [tw] OR immunocytoma [tw] OR insulinomas [tw] OR kasabach-merritt [tw] OR keratoacanthoma [tw] OR keratoacanthomas [tw] OR keratosis [tw] OR leiomyoblastoma [tw] OR leiomyoblastomas [tw] OR leiomyofibroma [tw] OR leiomyofibromas [tw] OR leiomyoma [tw] OR leiomyomas [tw] OR leiomyomatosis [tw] OR leiomyosarcoma [tw] OR leiomyosarcomas [tw] OR leukaemia [tw] OR leukaemias [tw] OR leukemia [tw] OR leukemias [tw] OR leukoplakia [tw] OR leukoplakias [tw] OR lipoadenoma [tw] OR lipoadenomas [tw] OR lipoblastoma [tw] OR lipoblastomas [tw] OR lipoblastomatosis [tw] OR lipoma [tw] OR lipomas [tw] OR lipomatosis [tw] OR liposarcoma [tw] OR liposarcomas [tw] OR luteinoma [tw] OR luteoma [tw] OR luteomas [tw] OR lymphangioendothelioma [tw] OR lymphangioendotheliomas [tw] OR lymphangioleiomyomatosis [tw] OR lymphangioma [tw] OR lymphangiomas [tw] OR lymphangiomatosis [tw] OR lymphangiomyoma [tw] OR lymphangiomyomas [tw] OR lymphangiomyomatosis [tw] OR lymphangiosarcoma [tw] OR lymphangiosarcomas [tw] OR lymphoepithelioma [tw] OR lymphoepitheliomas [tw] OR lymphoma [tw] OR lymphomas [tw] OR lymphoproliferation [tw] OR lymphoproliferations [tw] OR lymphoproliferative [tw] OR lymphoscintigraphic [tw] OR lymphoscintigraphy [tw] OR macroglobulinemia [tw] OR macroglobulinemias [tw] OR macroprolactinoma [tw] OR malignancies [tw] OR malignancy [tw] OR malignant [tw] OR maltoma [tw] OR maltomas [tw] OR masculinovoblastoma [tw] OR mastocytoma [tw] OR mastocytomas [tw] OR mastocytosis [tw] OR mcf-7 [tw] OR medulloblastoma [tw] OR medulloblastomas [tw] OR medullocytoma [tw] OR medullocytomas [tw] OR medulloepithelioma [tw] OR medulloepitheliomas [tw] OR medullomyoblastoma [tw] OR medullomyoblastomas [tw] OR melanoacanthoma [tw] OR melanoacanthomas [tw] OR melanoameloblastoma [tw] OR melanocytoma [tw] OR melanocytomas [tw] OR melanoma [tw] OR melanomas [tw] OR melanomatosis [tw] OR meningioblastoma [tw] OR meningioma [tw] OR meningiomas [tw] OR meningiomatosis [tw] OR mesenchymoma [tw] OR mesenchymomas [tw] OR mesonephroma [tw] OR mesonephromas [tw] OR mesothelioma [tw] OR mesotheliomas [tw] OR metaplasia [tw] OR metastases [tw] OR metastasis [tw] OR metastatic [tw] OR microglioma [tw] OR microgliomas [tw] OR micrometastases [tw] OR micrometastasis [tw] OR mucositis [tw] OR myelodysplasia [tw] OR myelodysplasias [tw] OR myelodysplastic [tw] OR myelofibrosis [tw] OR myelolipoma [tw] OR myelolipomas [tw] OR myeloma [tw] OR myelomas [tw] OR myelomatosis [tw] OR myeloproliferation [tw] OR myeloproliferations [tw] OR myeloproliferative [tw] OR myelosuppression [tw] OR myoblastoma [tw] OR myoblastomas [tw] OR myoepithelioma [tw] OR myoepitheliomas [tw] OR myofibroblastoma [tw] OR myofibroblastomas [tw] OR myofibroma [tw] OR myofibromas [tw] OR myofibromatosis [tw] OR myofibrosarcoma [tw] OR myofibrosarcomas [tw] OR myolipoma [tw] OR myolipomas [tw] OR myoma [tw] OR myomas [tw] OR myosarcoma [tw] OR myosarcomas [tw] OR myxofibroma [tw] OR myxofibromas [tw] OR myxolipoma [tw] OR myxolipomas [tw] OR myxoliposarcoma [tw] OR myxoma [tw] OR myxomas [tw] OR naevus [tw] OR neoplasia [tw] OR neoplasia [tw] OR neoplasm [tw] OR neoplasms [tw] OR neoplastic [tw] OR nephroblastoma [tw] OR nephroblastomas [tw] OR neurilemmoma [tw] OR neurilemmomas [tw] OR neurilemmomatosis [tw] OR neurilemoma [tw] OR neurilemomas [tw] OR neurinoma [tw] OR neurinomas [tw] OR neuroblastoma [tw] OR neuroblastomas [tw] OR neurocytoma [tw] OR neurocytomas [tw] OR neuroepithelioma [tw] OR neuroepitheliomas [tw] OR neurofibroma [tw] OR neurofibromas [tw] OR neurofibromatosis [tw] OR neurofibrosarcoma [tw] OR neurofibrosarcomas [tw] OR neurolipocytoma [tw] OR neuroma [tw] OR neuromas [tw] OR neuronevus [tw] OR neurothekeoma [tw] OR neurothekeomas [tw] OR nevus [tw] OR nonhodgkin [tw] OR nonhodgkins [tw] OR nonseminoma [tw] OR nonseminomas [tw] OR nonseminomatous [tw] OR odontoameloblastoma [tw] OR odontoma [tw] OR oligoastrocytoma [tw] OR oligoastrocytomas [tw] OR oligodendroglioma [tw] OR oligodendrogliomas [tw] OR oncocytoma [tw] OR oncocytomas [tw] OR oncogen [tw] OR oncogene [tw] OR oncogenes [tw] OR oncogenesis [tw] OR oncogenic [tw] OR oncogens [tw] OR oncologic [tw] OR oncologist [tw] OR oncoprotein [tw] OR oncoproteins [tw] OR opsoclonus-myoclonus [tw] OR orchioblastoma [tw] OR orchioblastomas [tw] OR osteoblastoma [tw] OR osteoblastomas [tw] OR osteochondroma [tw] OR osteochondromas [tw] OR osteochondrosarcoma [tw] OR osteochondrosarcomas [tw] OR osteoclastoma [tw] OR osteoclastomas [tw] OR osteofibrosarcoma [tw] OR osteoma [tw] OR osteomas [tw] OR osteosarcoma [tw] OR osteosarcomas [tw] OR pancreatoblastoma [tw] OR pancreatoblastomas [tw] OR papilloma [tw] OR papillomas [tw] OR papillomata [tw] OR papillomatosis [tw] OR papillomavirus [tw] OR papillomaviruses [tw] OR parachordoma [tw] OR parachordomas [tw] OR paraganglioma [tw] OR paragangliomas [tw] OR paraneoplastic [tw] OR perineurioma [tw] OR perineuriomas [tw] OR phaeochromocytoma [tw] OR phaeochromocytomas [tw] OR pheochromoblastoma [tw] OR pheochromoblastomas [tw] OR pheochromocytoma [tw] OR pheochromocytomas [tw] OR pilomatricoma [tw] OR pilomatricomas [tw] OR pilomatrixoma [tw] OR pilomatrixomas [tw] OR pinealblastoma [tw] OR pinealoblastoma [tw] OR pinealoblastomas [tw] OR pinealoma [tw] OR pinealomas [tw] OR pineoblastoma [tw] OR pineoblastomas [tw] OR pineocytoma [tw] OR pineocytomas [tw] OR plasmacytoma [tw] OR plasmacytomas [tw] OR pneumoblastoma [tw] OR pneumoblastomas [tw] OR pneumocytoma [tw] OR polyembryoma [tw] OR polyembryomas [tw] OR polyhistioma [tw] OR polyhistiomas [tw] OR polyp [tw] OR polyposis [tw] OR polyps [tw] OR porocarcinoma [tw] OR porocarcinomas [tw] OR poroma [tw] OR poromas [tw] OR precancer [tw] OR precancerous [tw] OR preleukaemia [tw] OR preleukaemias [tw] OR preleukemia [tw] OR preleukemias [tw] OR premalignant [tw] OR preneoplastic [tw] OR prolactinoma [tw] OR prolactinomas [tw] OR protooncogene [tw] OR protooncogenes [tw] OR pseudotumor [tw] OR pseudotumors [tw] OR reninoma [tw] OR reninomas [tw] OR reticuloendothelioma [tw] OR reticuloendotheliomas [tw] OR reticulohistiocytoma [tw] OR reticulohistiocytomas [tw] OR reticulosis [tw] OR retinoblastoma [tw] OR retinoblastomas [tw] OR rhabdomyoma [tw] OR rhabdomyomas [tw] OR rhabdomyosarcoma [tw] OR rhabdomyosarcomas [tw] OR rhabdosarcoma [tw] OR rhabdosarcomas [tw] OR sarcoma [tw] OR sarcomas [tw] OR sarcomatosis [tw] OR schwannoma [tw] OR schwannomas [tw] OR schwannomatosis [tw] OR seminoma [tw] OR seminomas [tw] OR seminomatous [tw] OR somatostatinoma [tw] OR somatostatinomas [tw] OR somatotropinoma [tw] OR somatotropinomas [tw] OR spermatocytoma [tw] OR spiradenoma [tw] OR spiradenomas [tw] OR spongioblastoma [tw] OR spongioblastomas [tw] OR steatocystoma [tw] OR steatocystomas [tw] OR subependymoma [tw] OR subependymomas [tw] OR syringadenoma [tw] OR syringadenomas [tw] OR syringocystadenoma [tw] OR syringocystadenomas [tw] OR syringoma [tw] OR syringomas [tw] OR teratocarcinoma [tw] OR teratocarcinomas [tw] OR teratoma [tw] OR teratomas [tw] OR thecoma [tw] OR thecomas [tw] OR thymolipoma [tw] OR thymolipomas [tw] OR thymoma [tw] OR thymomas [tw] OR trichilemmoma [tw] OR trichilemmomas [tw] OR trichoadenoma [tw] OR trichoblastoma [tw] OR trichoblastomas [tw] OR trichodiscoma [tw] OR trichodiscomas [tw] OR trichoepithelioma [tw] OR trichoepitheliomas [tw] OR trichofolliculoma [tw] OR trichofolliculomas [tw] OR tricholemmoma [tw] OR tricholemmomas [tw] OR tumor [tw] OR tumorgenesis [tw] OR tumorgenic [tw] OR tumorigenesis [tw] OR tumorigenic [tw] OR tumorogenesis [tw] OR tumorogenic [tw] OR tumors [tw] OR tumour [tw] OR tumours [tw] OR vipoma [tw] OR vipomas [tw] OR waldenstrom [tw] OR waldenstroms [tw] OR xanthoastrocytoma [tw] OR xanthoastrocytomas [tw] OR xanthofibroma [tw] OR xanthofibromas [tw] OR xanthogranuloma [tw] OR xanthogranulomas [tw] OR xanthoma [tw] OR xanthomas [tw] OR xanthosarcoma [tw] OR xanthosarcomas [tw]