# 5 Overall Cancer Hazard Evaluation and Listing Recommendation

Epstein-Barr virus (EBV) is known to be a human carcinogen based on sufficient evidence from studies in humans. This conclusion is based on epidemiological studies showing that it causes endemic Burkitt lymphoma (Table 5-1), Hodgkin lymphoma (Table 5-2), immunosuppression-related non-Hodgkin lymphoma (Table 5-3), nasal type NK/T-cell leukemia/lymphoma, (Table 5-4), nasopharyngeal carcinoma (Table 5-5), and gastric cancer (Table 5-6) in humans, together with supporting evidence from mechanistic studies demonstrating the biological plausibility of its carcinogenicity in humans. There is also limited evidence for an association with Burkitt lymphoma (sporadic) (Table 5-1) and lymphoepithelial cancer of the salivary gland (Table 5-7) from studies in humans.

Table 5-1 Summary of the Evidence for EBV and Burkitt Lymphoma (Endemic or Sporadic) from Human Studies

Types of Studies | Burkitt Lymphoma (Endemic) | Burkitt Lymphoma (Sporadic)
Epidemiological Number of studies reporting a positive association^a^ | EBV antibodies or DNA: 8/8 case-control studies (993 cases) & 1 cohort study (16 cases) All statistically significant; high RRs/ORs Dose response with viral titer in cohort study and several case-control studies | EBV antibodies: 4/5 case-control studies (113 cases) Mostly statistically non-significant; moderate ORs
Molecular (human tissue) Clonality for EBV % EBV-infected tumors EBV protein expression | Monoclonal 95% EBNA-1 | NA 20% NA
Level of evidence | Sufficient | Limited

EBNA = Epstein-Barr nuclear antigen; EBV = Epstein-Barr virus; NA = not available; OR = odds ratio; RR = risk ratio.

^a^ The number of studies is based on those reporting risk estimates.

Table 5-2 Summary of the Evidence for EBV and Hodgkin Lymphoma from Human Studies

Types of Studies | Hodgkin Lymphoma
Epidemiological Number of studies reporting a positive association (OR > 1.2)^a^ | EBV DNA: 3/3 case-control studies; very high ORs EBV antibodies: 17/20 case-control studies & 1 nested case-control study; mostly statistically significant OR between 4 & 19 Infectious mononucleosis: 10/11 case-control studies and 7/7 cohort studies with modest ORs/RRs
Molecular (human tissue) Clonality for EBV % EBV-infected tumors EBV protein expression | Monoclonal 20%–50% North America and Europe; 65% Asia; 90%–100% Africa and South America LMP-1, -2A in 50% of cases
Level of evidence | Sufficient

EBV = Epstein-Barr virus; LMP-1 = latent membrane protein 1; LMP-2A = latent membrane protein 2A; OR = odds ratio.

^a^ The number of studies is based on those reporting risk estimates.

Table 5-3 Summary of the Evidence for EBV and Immunosuppression-related Non-Hodgkin Lymphoma (NHL) from Human Studies

Types of Studies | Immunosuppression-related NHL
Epidemiological | Consistent evidence in case-series studies Elevated statistically non-significant increase with EBV antibodies in one nested case-control study
Molecular (human tissue) Clonality for EBV % EBV-infected tumors EBV protein expression Other | Monoclonal 100% (CNS + HIV-1) >50% post-transplant lymphoproliferative disease LMP-1, -2A, -2B, EBNAs; EBV-specific cytotoxic T-cells protect against or reduce viral load and tumor size
Level of evidence | Sufficient

CNS = central nervous system; EBNA = Epstein-Barr nuclear antigen; EBV = Epstein-Barr virus; HIV-1 = human immunodeficiency virus type 1; LMP-1 = latent membrane protein 1; LMP-2A = latent membrane protein 2A; LMP-2B = latent membrane protein 2B.

Table 5-4 Summary of the Evidence for EBV and NK/T-Cell Leukemia/Lymphoma, Nasal Type from Studies in Humans

Types of Studies | NK/T-Cell Leukemia/Lymphoma, Nasal Type
Epidemiological | Consistent evidence in case-series studies; at least 16 case series with more than 400 cases Two case-comparison studies: EBV DNA found in plasma or CD3+ cells from cases but not from controls
Molecular (human tissue) Clonality for EBV % EBV-infected tumors EBV protein expression Other | Monoclonal 100% EBNA-1, LMP-1, -2A EBV found in majority of CD56+ tumors
Level of evidence | Sufficient

EBNA = Epstein-Barr nuclear antigen; EBV = Epstein-Barr virus; LMP-1 = latent membrane protein 1; LMP-2A = latent membrane protein 2A.

Table 5-5 Summary of the Evidence for EBV and Nasopharyngeal Carcinoma from Human Studies

Types of Studies | Nasopharyngeal Carcinoma
Epidemiological Number of studies reporting a positive association^a^ | EBV antibody: 11/11 case-control and two cohort studies; high to very high statistically significant RRs; no association in two small-nested case-control studies EBV DNA: 6/6 case-control studies; very high RR
Molecular (human tissue) Clonality for EBV % EBV-infected tumors EBV protein expression | Monoclonal in precancer/cancer 98% in non-keratinizing tumors EBNA-1, LMP-1, -2A
Level of evidence | Sufficient

EBNA = Epstein-Barr nuclear antigen; EBV = Epstein-Barr virus; LMP-1 = latent membrane protein 1; LMP-2A = latent membrane protein 2A; RR = risk ratio.

^a^ The number of studies is based on those reporting risk estimates.

Table 5-6 Summary of the Evidence for EBV and Gastric Cancer from Human Studies

Types of Studies | Gastric Cancer
Epidemiological Number of studies reporting a positive association | 3/3 case-control studies (77 EBV cases/184 gastric); statistically significant high ORs 2/3 nested case-control studies; statistically non-significant modest ORs; statistically significant elevated mean EBV antibodies for EBV-positive cases in one study compared to controls
Molecular (human tissue) Clonality for EBV % EBV-infected tumors EBV protein expression Other | Monoclonal 8%–11% EBNA-1, LMP-2A (variable expression) Unique molecular profile
Level of evidence | Sufficient

EBNA = Epstein-Barr nuclear antigen; EBV = Epstein-Barr virus; LMP-1 = latent membrane protein 1; LMP-2A = latent membrane protein 2A; OR = odds ratio.

Table 5-7 Summary of the Evidence for EBV and Lymphoepithelial Carcinoma of the Salivary Gland from Human Studies

Types of Studies | Lymphoepithelial Carcinoma/Salivary Gland
Epidemiological | No case-control or cohort studies available to evaluate these cancers although one case-case study found EBV DNA in salivary gland lymphoepithelial carcinoma tumors but not other types of salivary gland tumors
Molecular (human tissue) Clonality for EBV % EBV-infected tumors EBV protein expression Other | Monoclonal (four samples from two studies) Close to 100% (208/209 cases) in Asian, Greenland, and Eskimo populations; variable in few cases in Western populations EBNA-1, LMP-1 Mechanism(s) in epithelial cells unknown
Level of evidence | Inadequate

EBNA = Epstein-Barr nuclear antigen; EBV = Epstein-Barr virus; LMP-1 = latent membrane protein 1

The following tables provide the level of evidence recommendations for the carcinogenicity of EBV for each tumor endpoint from studies in humans, including the key data from both epidemiological and molecular studies.