# 4 Mechanisms and Other Relevant Data

Epstein-Barr virus (EBV) was the first oncogenic virus identified in humans and was found to be associated with endemic Burkitt lymphoma over 50 years ago (Epstein et al. 1964). Evidence of the oncogenic potential of EBV was demonstrated by its ability to transform human B lymphocytes in cell culture and by studies in nonhuman primates (Pope et al. 1968; Shope et al. 1973). Over 90% of the world’s adult population is infected with EBV by age 20. For the most part, the result is an asymptomatic life-long infection—similar to other herpesviruses—and is held in check by immune surveillance. Several patterns of gene expression during virus latency have been shown to be associated with EBV pathogenesis of some cancers (see Table 1-1). From studies of human cancer populations and refinement of molecular techniques, several types of cancer have a clear causal association with this virus such as Burkitt lymphoma, Hodgkin lymphoma, and nasopharyngeal carcinoma. However, the presence of EBV and its possible role in other cancers, such as carcinoma of the lung, skin, or various glandular tissues (e.g., breast cancer), are not as well understood and clinical studies showing a clear causative link are not available. Other tumor types, such as EBV-positive diffuse large B-cell lymphoma (DLBCL), lacked an adequate database. Investigation of the properties of the virus, as well as the cofactors and mechanisms that enable cancer formation in various tissues or are protective, is an ongoing process.

This section provides a brief review of the characteristics of EBV-associated neoplasms (Section 4.1), the roles of viral gene transcripts and proteins in malignant transformation (Section 4.2), the mode of action and evidence for cancer causation (Section 4.3), and a synthesis of this information (Section 4.4).

## 4.1 General Characteristics

As discussed in the previous sections, seven neoplasms—four in lymphoid tissue and three in epithelial tissue—have been primarily associated with EBV in humans, although the level of evidence for each tumor varies (IARC 2012). These neoplasms include: (1) Burkitt lymphoma (2) Hodgkin lymphoma, (3) immunosuppression-related non-Hodgkin lymphoma, (4) nasal type extranodal NK/T-cell lymphoma, (5) nasopharyngeal cancer, (6) gastric cancer, and (7) lymphoepithelial-like carcinoma of the salivary gland. General characteristics of these EBV-associated neoplasms and degree of association of the neoplasm with EBV, i.e., percentage of tumor cells containing the EBV genome are listed in Table 4-1.

Table 4-1 Characteristics of EBV-associated Neoplasms

Neoplasm | Clinical Presentation | Lineage and Primary Tumor Cell; Evidence of EBV Clonality^a^ | Percent of Tumors or Tumor Cells EBV Positive; Clonality
Burkitt lymphoma | Endemic form - Extra nodal lymphoid tissue (jaw, kidney, bowel, adrenal gland); positive malaria titer; children Sporadic form - Abdomen, lymph nodes; adults and children Immunodeficiency-associated form - anti-rejection therapy; early latency with HIV infection; also, congenital cause | Neoplastic B cells with c-myc translocation to immunoglobulin locus - all forms of Burkitt lymphoma; monoclonal | Endemic form - 95% of tumor cells contain EBV genome Sporadic form - at most 20% of tumors contain EBV genome Immunodeficiency-associated form - 40% of lymphomas in HIV-1-positive patients (Gloghini et al. 2013; Stefan et al. 2011)
Hodgkin lymphoma | Nodal tissue of neck, mediastinal, axillary and paraaortic regions; lymphadenopathy with rich inflammatory background | Multinucleated, clonal Hodgkin Reed-Sternberg cells (B-cell origin; CD15, CD30 markers) | EBV primarily associated with 75% of mixed cellularity and 20% of nodular sclerosis subtypes of classical Hodgkin lymphoma; Hodgkin lymphomas in HIV-1-positive patients are 100% EBV associated
Immunosuppression-related NHL | Lymph nodes, gastrointestinal tract, lungs, liver; associated with CNS lymphomas in HIV-1-positive patients; Lymphomas may occur with anti-rejection therapy | Primarily (85%) B-cell origin, monoclonal and polyclonal forms | 100% of CNS lymphomas in HIV-1-positive patients; Systemic - 90% diffuse large cell lymphomas, 40% small non-cleaved cell lymphadenopathies (Burkitt lymphomas) EBV-associated; 60% EBV associated in post-transplant lymphoproliferative disease
Extra nodal NK/T-cell lymphoma | Lymphoid tissue; extra nodal; diffuse lymphocytic infiltrate and vascular damage | NK and T cells; most cases are NK cell neoplasms, some have a cytotoxic T-cell phenotype; monoclonal | 100% in nasal variant
NPC | Epithelial tissue; strong ethnic and geographic association: Inuit, Southern Asia, China; keratinizing and non-keratinizing forms | Nasal epithelial cells; monoclonal | 98% in non-keratinizing carcinoma; clonal detection in precancers (Pathmanathan et al. 1995; Tsang et al. 2014; Tsao et al. 2015)
Gastric cancer | Epithelial tissue; 89% with lymphocytic infiltration; proximal stomach or associated with stomach remnant | Gastric epithelial cells; monoclonal | 9% of gastric cancers
LEC of the salivary gland | Epithelial tissue and non-cancerous lymphoid cells | Salivary gland epithelial cells; monoclonal (few samples) | Primarily parotid salivary gland

Sources: Information from IARC (1997a; 2012) unless cited in the table.

LEC = lymphoepithelial cancer; NPC = nasopharyngeal carcinoma.

^a^ Evidence of clonality of virus in tumor tissue.

## 4.2 EBV Latent Genes and Malignant Transformation

EBV in its latent phase can express different transcription programs (0, I, II, III). In an immunocompetent host, EBV persists in memory B cells as a latent infection (latency 0). Since no proteins are produced during latency 0, the presence of the virus is not recognized by the immune system, resulting in lifetime infection. EBV-encoded small RNAs (EBERs) and microRNAs are expressed in all latency phases and approximately 22 microRNAs have been identified (IARC 2012). MicroRNAs have been shown to have a role in transformed growth properties of EBV-infected cells (Marquitz et al. 2012). NF-kB and Wnt pathways, and apoptosis and immune activation processes, are known to be regulated by EBV microRNAs (Skalsky and Cullen 2015). EBERs and microRNAs as well as the full complement of latent gene proteins are expressed in latency III. Latent gene proteins consist of six nuclear antigens (EBNAs), and three latent membrane proteins (LMPs) (IARC 2012; Yau et al. 2014). EBV transcripts include coding and non-coding RNAs and proteins produced during latency phases (see Table 1-1). Primarily latency II, but also latency I and III phases, promote acquisition of various cancer hallmarks, e.g., insensitivity to antigrowth signals, avoiding cell-cycle arrest, immune evasion, genetic instability, cell proliferation, resisting apoptosis, promotion of angiogenesis, and induction of genomic instability (Mesri et al. 2014). Table 1-1 relate their expression pattern to that found in various neoplasias. The general functions of key viral proteins and transcripts important in the pathogenesis of EBV-associated cancers are described in Table 4-2.

Table 4-2 Activation of Oncogenic Pathways by Viral Genes

EBV Transcription Program and Gene Products | Some Host Pathways Affected | Potential Cancer Property | Associated Malignancies^a^
Latency 0: EBERs | – | Promote growth, anti-apoptotic | None
Latency I: EBNA-1, EBERs | Regulation of RAG-1 and RAG-2 by EBNA-1 | Resisting cell death, avoiding immune destruction, genome instability, increase in reactive oxygen species | Burkitt lymphoma and gastric carcinoma^b^
Latency II: EBNA-1, LMP-1, LMP-2A, EBERs | NFkB, JNK by LMP-1 | Resisting cell death, enabling replicative immortality, angiogenesis, inflammation | NPC, Hodgkin lymphoma, NK and T-cell lymphoma, nasal type^c^, LEC of the salivary gland
Latency III: EBNA-1, -2, -3A, -3B, -3C, -LP, LMP-1, LMP-2A, LMP-2B, EBERs | PI3K-Akt-mTOR, ERK by LMP-2A | Inducing angiogenesis, sustaining proliferative signaling, deregulation of cellular pathways, activation of invasion and metastasis, enables replicative immortality, activation of host methyltransferase | Immunosuppression-related NHL (AIDS-associated, post-transplant disorder, iatrogenic)
MicroRNAs^d^ | Repression of translation | Immune evasion | –

Sources: Grywalska and Rolinski (2015); IARC (2012); Mesri et al. (2014).

EBER = EBV-encoded small RNA; EBNA = EBV nuclear antigen; LMP = latent membrane protein; EBNA-LP = EBV nuclear antigen leader protein; NHL = non-Hodgkin lymphoma; LEC = lymphoepithelial cancer; NPC = nasopharyngeal carcinoma.

^a^ General classification of disease and heterogeneous patterns may be present in different cell populations in same individual.

^b^ Expression of lytic genes and LMP-2A variable.

^c^ Previously called sinonasal angiocentric T-cell lymphoma.

^d^ In latency I, II, III microRNAs (at least 22) are expressed in various amounts.

## 4.3 Mode of Action and Evidence for Cancer Causation

Direct evidence for causality of EBV in lymphomagenesis comes from in vitro studies and studies in mice. EBV has been shown to transform lymphoblastoid cells in culture and can transform epithelial cells when co-cultured with transformed lymphoblastoid cells (Imai et al. 1998). In addition, lymphoblastoid cells transfected with activated c-myc genes were tumorigenic in nude mice, and infected B cells have been shown to cause B-cell lymphomas in SCID mice (Lombardi et al. 1987; Mosier et al. 1989; Rowe et al. 1991). In order to understand the contribution of viral and host factors in development of lymphomas, humanized mouse models using transplanted human fetal hematopoietic stem cells and lymphoid tissue are under development (Cocco et al. 2008; Ma et al. 2011).

EBV proteins, EBNA-1, -2, -3A, -3C, and LMP-1 are all necessary for immortalization of B-lymphocytes (Grywalska and Rolinski 2015). Clearly, EBV has oncogenic potential to transform lymphoid and epithelial cells in culture and has been found associated with cancers of epithelial and lymphoid origin. EBV is a ubiquitous virus, and criteria have been outlined by IARC as well as discussed by others for judging cancer causality by viruses (IARC 1997a; zur Hausen 2001) (see the Introduction and Methods section). The key causality criteria included the following: (1) the presence of the virus in the tumor, (2) monoclonality of EBV in the tumor (suggesting the presence of latent infection prior to expansion of the malignant clone), and (3) expression of viral proteins in pre-neoplastic lesions and in malignant tissue (IARC 1997a). The epidemiological and experimental data show that EBV meets these criteria. The mode(s) of action and evidence linking EBV with cancer are briefly reviewed by tumor type in the following sections.

### 4.3.1 Burkitt Lymphoma

Burkitt lymphoma is a B-cell non-Hodgkin lymphoma that presents mostly as an extranodal mass, although nodal involvement is seen in sporadic cases. In normal lymphoid tissue, B-cell response to antigenic stimulation produces B cytoblasts that differentiate into plasma cells that produce antibodies. In Burkitt lymphoma, B-cell differentiation in response to antigen stimulus undergoes faulty DNA recombination in the lymphoid tissue germinal center resulting in immunoglobulin gene/c-myc translocation. This results in constitutive expression of the c-myc oncogene driven by immunoglobulin promoters and is the primary lesion in Burkitt lymphoma. From human cancer studies, it is known that endemic Burkitt lymphoma is associated with chronic antigenic stimulation found with malarial infection, and B cells infected with EBV have latency I EBV gene expression pattern. Malarial infections can promote B-cell hyperplasia and increase the chances that B-cell translocations will occur. Moreover, malarial infection has been shown to directly increase the number of germinal center translocations occurring via deregulation of activation-induced cytidine deaminase, an enzyme responsible for class switch recombination and somatic hypermutation, in the germinal center (Torgbor et al. 2014). Normally, defective cells exiting the germinal center undergo apoptosis; however, it has been shown that EBV expression of EBNA-1 rescues defective B cells from removal by apoptosis by directly upregulating survivin production by complexing with SP1 on the survivin gene promoter (Kennedy et al. 2003; Lu et al. 2011). This would potentially result in more Burkitt lymphoma cells forming in the germinal center with malarial infection, and EBV cells expressing EBNA-1 would be the ones that survive.

Other lines of evidence linking EBV and Burkitt lymphoma include the following:

- EBV is associated with all three clinical forms of Burkitt lymphoma (endemic, sporadic, immune suppression related) (IARC 1997a; 2012).
- EBV DNA is present in Burkitt lymphoma cells in monoclonal form (IARC 1997a).
- Both malaria and EBV cause B-cell hyperplasia, and increase in B cells could increase the probability of a faulty gene translocation (Robbiani et al. 2015; Torgbor et al. 2014).
- EBNA-1 prevents apoptosis of Burkitt lymphoma cells and enables cell survival (Kennedy et al. 2003; Lu et al. 2011).

### 4.3.2 Hodgkin Lymphoma

Hodgkin lymphoma is a group of lymphoid neoplasms arising from a single lymph node, spreading to contiguous lymph nodes, and containing Hodgkin Reed-Sternberg cells, which are giant multinucleated neoplastic cells of clonal B-cell origin (Stein et al. 2008). Over 90% of the tumor is characterized by non-malignant inflammatory cells (i.e., reactive lymphocytes, macrophages, granulocytes, and fibrocytes) and fibrosis. Based on histopathology, Hodgkin lymphoma is divided into classical (with four subtypes: mixed cellularity, nodular sclerosis, lymphocyte depleted, and lymphocyte rich) and nodular lymphocyte-predominant Hodgkin lymphoma, an uncommon form that is almost always EBV negative (Stein et al. 2008). Hodgkin lymphomas account for approximately 30% of all lymphomas worldwide; however, as noted in Table 4-1, the degree of EBV infection varies among different subtypes of classical Hodgkin lymphoma (IARC 1997a; 2012).

Unlike germinal center maturation of B lymphocytes to plasma cells or memory B lymphocytes, Hodgkin Reed-Sternberg cells have not undergone somatic hypermutation and do not express immunoglobulins or most B-cell specific genes. These cells do reveal deregulation of multiple signaling pathways such as NF-κB, JAK/STAT, MAP kinase, PI3-kinase/AKT and produce an abnormal pattern of release of cytokines and chemokines resulting in a local inflammatory response. LMP-1 has been shown to be a transforming oncogene in cell culture and promotes growth and survival of Hodgkin Reed-Sternberg cells through upregulation of these pathways (Mohamed et al. 2014). EBV expresses type II latency genes (Table 4-2) in Hodgkin Reed-Sternberg cells (IARC 1997a; 2012).

Further evidence that supports EBV infection as a causal agent in some forms of Hodgkin lymphoma is as follows (IARC 2012)

- Monoclonal EBV episomes are detected in Hodgkin Reed-Sternberg cells indicating that EBV infection has occurred before clonal expansion.
- Antibody titers to EBV viral capsid antigens are increased with Hodgkin lymphoma.
- The risk of Hodgkin lymphoma increases 4-fold with a previous history of infectious mononucleosis.

### 4.3.3 Immunosuppression-related Non-Hodgkin Lymphoma (HIV-1-positive and Post-transplant Lymphoproliferative Disease)

EBV infection in a severely immunocompromised host can lead to immunosuppression-related non-Hodgkin lymphoma. EBV-related non-Hodgkin lymphomas have been linked to immunosuppression therapies related to transplant of organs or cells (stem cells or bone marrow), and to severe immune suppression as a result of HIV-1 infection (Pietersma et al. 2008). The link between immune suppression and non-Hodgkin lymphoma caused by EBV has been characterized from studies measuring viral load and EBV-specific cytotoxic T lymphocytes in the blood of patients with severe immune suppression (acquired immune deficiency syndrome, AIDS) or with post-transplant lymphoproliferative disorders (Gulley and Tang 2010; IARC 1997a; 2012). Post-transplant lymphoproliferative disorder occurs in approximately 0.5% to 1% overall of kidney or bone marrow transplants and varies with the patient age and type of transplant (Vegso et al. 2011). Early lesions are often polyclonal and, if untreated, continued B-cell proliferation driven by active EBV will generate a neoplastic clone (Gulley and Tang 2010).

With HIV-1 infection, perturbations in the immune system and loss of lymphocytes decrease immune surveillance. Central nervous system non-Hodgkin lymphoma may result from HIV-1-related profound immunosuppression; 100% of these lymphomas are associated with EBV (IARC 1997a). In addition, there is evidence of clonality of EBV and production of LMP-1, an oncoprotein, by EBV in HIV-associated central nervous system non-Hodgkin lymphoma tissues (IARC 1997a). EBV is also associated with a large percentage of systemic AIDS-related non-Hodgkin lymphomas with up to 90% of diffuse large cell lymphomas and in approximately 40% of small non-cleaved cell lymphadenopathies associated with EBV (IARC 1997a).

Patients receiving transplants but not previously infected with EBV, such as children, are at a greater risk of developing non-Hodgkin lymphoma from infected transplant tissue or from transmission of EBV in saliva from an infected person. Polymorphic post-transplant lymphoproliferative disease appears early after transplant procedure (<1 year) in children and is associated with a primary EBV infection (Vegso et al. 2011). Most of the post-transplant lymphoproliferative disease lesions are of B-cell origin (85%) and >90% are associated with EBV infection (IARC 2012; Taylor et al. 2005; Vegso et al. 2011). The most common EBV gene expression pattern with post-transplant patients is latency III growth pattern (Carbone et al. 2008, Table 1.1) (see also Table 1-1).

Evidence that EBV is causal in some cases of immunosuppression-related non-Hodgkin lymphoma includes the following (Lim et al. 2006):

- Treatment with EBV-specific cytotoxic lymphocytes results in decreases in EBV viral load and in tumor size.
- Further administration of EBV-specific cytotoxic lymphocytes to an immune-suppressed individual can protect against lymphoma development.
- In organ or cell transplant cases, decreasing therapy for immunosuppression can decrease viral load and tumor size. Not all cases of post-transplant lymphoproliferative disease or lymphoproliferative disease with HIV-1 are related to EBV infection, but reactivation of a latent infection or initiation of a primary EBV infection can lead to lymphoproliferative disease.

### 4.3.4 Extranodal NK/T-cell Lymphoma, Nasal Type

Extranodal NK/T-cell lymphoma, previously known as angiocentric T-cell lymphoma, is a rare EBV-associated lymphoma that has a higher prevalence in South America, Mexico, and Asia than in the United States. NK/T-cell lymphomas are classified by location of the tumor to nasal, intestinal, and subcutaneous panniculitis-like lymphomas. The amount of association of these lymphomas with EBV varies with tumor site, geographic location, and genotype of the patient (Ambinder and Cesarman 2007).

EBV expresses type II latency genes (Table 4-2) in this cancer. LMP-1, an EBV-specific oncoprotein, has been shown to be a transforming protein in cell culture and promotes cell growth and survival through upregulation of NF-κB, JAK/STAT, MAP kinase, PI3-kinase/AKT pathways (IARC 2012). Kanemitsu et al. (2012) examined 30 cases of nasal type NK/T-cell lymphoma, for expression profile of EBV-encoded protein; results show that all tissues were positive by immunohistochemistry for EBER, none were positive for EBNA-2, and LMP-1 was positive in 22 cases and correlated with a localized disease (p = 0.06). Furthermore, nuclear localization of phosphorylated RelA (NF-κB) and phosphorylated Akt (PI3K) were observed in conjunction with positive cases (p < 0.002 and p < 0.001, respectively). RNA silencing experiments of LMP-1 correlated with decreased phosphorylation of RelA and Akt in vitro providing evidence that EBV LMP-1 expression was in part enhancing NFκB and PI3K expression.

Additional evidence that supports EBV infection as a causal agent in some forms of NK/T-cell lymphoma is as follows:

- Nasal type NK/T-cell lymphoma presents as a localized disease with near 100% positivity for EBV (IARC 1997a).
- EBV is clonal in these nasal tumors (IARC 1997a).
- Viral proteins (LMP-1) associated with EBV latency II gene expression pattern are present in these tumors (IARC 2012).

### 4.3.5 Nasopharyngeal Carcinoma

Research efforts have focused on addressing biological properties of EBV that may result in differences in nasopharyngeal cancer incidence among different populations. Initial characterization relied on the use of restriction enzymes to identify DNA polymorphisms describing EBV strain variation in different populations. Genome sequence analysis identified specific genetic variants (such as in LMP-1) that could potentially enhance transforming potential and virulence of EBV and enable variants of LMP-1 to evade immune recognition (Raab-Traub 2002). In addition, multiple EBV microRNAs have immune evasion functions (Tsao et al. 2015). Whole-EBV genome sequencing studies have revealed that the nasopharyngeal carcinoma-derived EBV strains from endemic regions vary and show significant differences from the reported EBV genomes from non-endemic populations (Liu et al. 2011). A review by Lung et al. (2014) lists oncogenes and tumor suppressor genes important in nasopharyngeal carcinoma development and the effects of EBV infection on regulation of gene expression. The findings suggest the existence of disease-specific viral variations that may possess higher oncogenic properties, propensity for infection of epithelial cells, and persistence of the latency II program, or less efficiency in inducing host immune response, especially in the nasopharyngeal carcinoma endemic population (Liu et al. 2011). Linkage analysis of susceptible Chinese populations has demonstrated an association between nasopharyngeal carcinoma risk and allelic variations in human leukocyte antigen (HLA), a part of the MHC I complex of immunosurveillance. A consistent association between nasopharyngeal carcinoma and a Chinese HLA subtype, as compared to a Caucasian subtype, was detected by a genotyping study (Hildesheim et al. 2002). Multiple areas of hypermethylation are present in the nasopharyngeal carcinoma genome resulting in inactivation of tumor suppressor genes (e.g., p16 and RASSF1A) and disruption of cell functions (i.e., cell-cycle controls, signal transduction, apoptosis, and DNA repair) (Kwong et al. 2002). As the efficiency of sample collection and genetic assays improve and are replicated, more details of host-virus interactions will likely be found.

Evidence that EBV is a primary causal factor in nasopharyngeal carcinoma is as follows:

- Clonal EBV episomes are detected in undifferentiated tumors (Liu et al. 2011).
- Studies showing early preneoplastic nasopharyngeal lesions (dysplastic lesions, carcinoma in situ) but not normal tissues are also infected with EBV and express latency II program gene products (IARC 2012; Pathmanathan et al. 1995; Raab-Traub 2002; Tsang et al. 2014; Tsao et al. 2015).

### 4.3.6 Gastric Carcinoma

Gastric cancer is a common cancer, and it is estimated that EBV is a causal factor in 5% to 10% of all gastric cancers worldwide. Latency I/II patterns of EBV gene expression are found in these cancers with approximately 50% expressing LMP-2A which activates the NF-κB survival pathway (IARC 2012).

Molecular studies in humans provide strong evidence of an association between EBV and some gastric cancers. These studies show that EBV is found as a monoclonal form in a subset of human gastric cancers. Moreover, the virus produces oncogenic proteins in gastric cancer tissue that promote cell division, cell survival, and oncogenic transformation, and produces a unique molecular profile in genomic studies of gastric tumors. Recent comprehensive molecular work by the Cancer Genome Atlas Research Network (2014) has resulted in the identification of four distinct molecular profiles of gastric cancer, as described below. Primary gastric tumors from 295 untreated patients were analyzed and blood or non-malignant gastric tissue was used as reference for somatic alterations in the tumors. Non-malignant gastric tissue was also collected for DNA methylation and expression analyses and six molecular testing platforms were used to analyze the tissue (Cancer Genome Atlas Research Network (2014)), reviewed by Gulley (2015)). Four distinct molecular profiles were discerned for gastric cancer: EBV-positive, microsatellite instability (MSI), chromosome instability (extensive somatic copy-number aberrations [SCNAs], and genomically stable. Molecular features unique to all EBV-positive gastric cancers were also identified: hypermethylation of promoter regions resulting in gene down-regulation or silencing, mutations and gene amplifications, and expression of multiple noncoding viral RNAs. The EBV-positive group had a distinctive genetic profile, marked CpG methylation, including CDKN2A (p16, tumor suppressor gene), a strong immune-cell presence, and evidence of an IL-12-mediated signaling response. Some of the more frequent genetic changes are listed in Table 4-3. Promoter hypermethylation affected genes involved in cell-cycle regulation (CDKN2A - p16), DNA repair (GSTP1), cell adhesion and metastases (TIMP1), apoptosis (bcl-2), and signal transduction (PTEN). JAK2 was amplified in 12% of the EBV-positive tumors. A gene locus, 9p24.1, was linked to overexpression and amplification of JAK2, and CD274 (PD-L1) and PDCD1LG2 (PD-L2) in approximately15% of the EBV tumor subgroup. PD-L1 and PD-L2 signaling cascades prevent T-cell proliferation and aid in escape of the cancer from immune surveillance. Further, EBV-positive tumors had mutations in PIK3CA (10% to 72%), ARID1A (47% to 55%), AKT2 (38%), TGFBR1 (25%), CCNA1 (25%), BCOR (23%) and MAP3K4 (21%), but rarely in TP53. In addition, multiple noncoding viral RNAs as well as viral LMP1, LMP2A, and EBNA1 were consistently expressed at low levels (Gulley 2015). From this unique molecular profile and the presence of activated EBV within gastric tissue, it is apparent that EBV is causal for tumor promotion. However, the pathogenesis of EBV activation in this form of gastric cancer has not been resolved.

Table 4-3 Properties of Some Known Signaling Pathways Altered with EBV-related Gastric Cancer

Signaling Pathway | Effects
MicroRNAs | Unknown
CDKN2A (p16) | Tumor suppressor gene; slows progression from G1 to S phase
JAK2 | Cell growth and division
PI3K/Akt | Cell growth and division; inhibits apoptosis, promotes genomic instability, cytoskeleton change; LMP-2 activates
ERBB2 | Cell growth and division
ARID1A | Cell-cycle progression
BCOR | Transcription and chromatin regulation
CD274 (PD-L1) | Immunosuppression
PDCD1LG2 (PD-L2) | Immunosuppression
IL-12 | Immune-cell stimulation in response to antigen
NF-κB | Resists apoptosis, cell proliferation; LMP-2A activates

Source: Gulley (2015).

### 4.3.7 Lymphoepithelial Cancer of Salivary Glands

Lymphoepithelial carcinomas and their association with EBV have been reported most frequently in gastric cancer and in cancer of the salivary glands but less frequently in some other epithelial malignancies such as lung and skin (IARC 1997a; 2012). For cancer of the salivary glands, it is hypothesized that the close proximity of the salivary glands to the oropharyngeal area would increase exposure of these glands to the lytic form of EBV in the saliva. IARC (1997a; 2012) reported a number of case-series studies detecting EBV DNA in lymphoepithelial carcinoma of the salivary glands and a case-case study presented evidence of EBV DNA in salivary tumors with lymphoepithelial histology, but not in salivary tumors of other histology (Wang et al. (2004), as reported in IARC (2012)). As reported by IARC, viral EBER RNA and LMP-1 protein were detected in tumor tissue from 10 cases of lymphoepithelial carcinoma of the salivary gland from a Chinese population (Leung et al. 1995). Clonal EBV termini were associated with undifferentiated carcinoma of the parotid glands (two tumors from American Inuit) and EBER-1 RNA, LMP-1 RNA and BamHI-A rightward reading frame were expressed in the malignant cells (Raab-Traub et al. 1991). In both studies, an episomal form of EBV was detected in the tumor tissue, but no EBV was detected in normal adjacent tissue. These data provide evidence for the presence of EBV in lymphoepithelial cancer of salivary glands. However, the level of evidence from mechanistic data is inadequate to assess whether EBV is carcinogenic in epithelial cells of the salivary gland since the mechanism has not been elucidated.

## 4.4 Synthesis

EBV is highly prevalent and results in a life-long latent infection that is refractory to immune recognition. Activated EBV transcription programs mimic B-cell proliferation and survival and in some cases result in cancer. However, as with other oncoviruses, EBV infection alone is necessary but not sufficient for cancer development.

The latency patterns of EBV are associated with specific cancers and factors including immunosuppression, infectious agents, regional differences in diet, and host genetic susceptibility; all of which potentially have a role in cancer development. In primary EBV infection of naïve B cells, growth and differentiation occur due to the latency III transcription pattern that is highly immunogenic. Factors causing immunosuppression such as HIV-1 infection or post-transplant therapies enable the latency III pattern to continue, resulting in dysregulation of cellular pathways leading to non-Hodgkin lymphoma or post-transplant lymphoproliferative disease.

Immune pressure promotes selection to latency II or I patterns, which are less immunogenic. Endemic Burkitt lymphoma is associated with co-infection with the malaria parasite, P. falciparum, which further enhances B-cell proliferation and genetic instability of latency I pattern, resulting in c-myc translocation and overexpression. Hodgkin lymphoma, NK/T-cell lymphoma, nasopharyngeal carcinoma, and some gastric and salivary gland lymphoepithelial cancers all express EBV latency II program. Expression of EBV latent genes LMP-1 and LMP-2 result in dysregulation of host cellular pathways and promotes oncogenesis. In addition, the genotypes of both the host and the virus, as well as dietary factors, have been linked to the prevalence of nasopharyngeal carcinoma.