# 3 Human Cancer Studies

## Introduction

The NTP independently evaluated the scientific evidence using the IARC monographs (1997a; 2012) on EBV as the resources for studies conducted up to and including 2008, together with any new human studies identified from 2009 to 2015. Seven tumor endpoints—Burkitt lymphoma, Hodgkin lymphoma, immunosuppression-related non-Hodgkin lymphoma, extranodal NK/T-cell lymphoma, nasopharyngeal carcinoma, gastric cancer, and lymphoepithelial carcinoma of the salivary gland—either identified in the IARC monographs or with an adequate database, are considered in the RoC monograph. Where available, IARC data tables of the effect estimates have informed the cancer hazard assessment (IARC 2012), with links to these tables made available in the text. When tables of individual studies were not available, forest plot summaries of the data have been provided.

EBV exposure is detected in the human studies via serological measures or from DNA in the tumor. Earlier studies included in the evaluation primarily used serological measures, while later studies used tumor DNA. (See Section 1.2 above for details on EBV detection methods.)

This evaluation of the human cancer hazard associated with EBV is divided into the following three parts. The first, a summary of the approach for selection of the studies is provided in Section 3.1. Second, the cancer hazard evaluation for each endpoint is presented in Sections 3.2 to 3.8. Lastly, a summary of the evaluations across endpoints is provided in Section 3.9.

## 3.1 Selection of the Literature

A systematic literature search of major databases, citations, and other authoritative sources for literature from 2009 to August 2015 was conducted. The literature search strategy (including the databases, search terms, and other sources for identifying literature) and procedures and results for selecting the literature (systematic screening procedures and inclusion/exclusion criteria) are described in Appendix A. For the EBV evaluation, all post-2008 case-control and cohort studies for the seven cancer endpoints were identified and included in the evaluation. These studies may range from broadly defined, non-matched hospital or population case-control designs to formal age-, sex-, and race-matched case-control designs. Previous studies reviewed by IARC were included in the overall assessment, but not evaluated in depth. Although summaries of multiple case report or case-series studies are noted and may be considered in the overall evaluation, case reports and case series were excluded from further review.

## 3.2 Cancer Evaluation: Burkitt Lymphoma

### 3.2.1 Background Information

Burkitt lymphoma includes three subtypes defined according to their incidence in populations: endemic, sporadic, and immunodeficiency-related Burkitt lymphoma. Endemic Burkitt lymphoma (also known as the African type) occurs primarily in children aged 5 to 9 years in equatorial Africa and Papua New Guinea. It occurs with an incidence rate of 5 to 10 cases per 100,000 in children under 16, and is responsible for 30% to 70% of all childhood cancers in equatorial Africa (IARC 1997a). Among endemic Burkitt lymphoma cases, EBV is detected in the tumor in more than 95% of cases (Thompson and Kurzrock 2004). In the case-series studies reviewed in IARC (1997a), there were a total of 191 cases of endemic Burkitt lymphoma, with EBV DNA or antibodies present in 185 of the cases.

Sporadic Burkitt lymphoma is found throughout the world. It is rare, with an incidence of 2 to 3 cases per million people in the United States. Sporadic Burkitt lymphoma is associated globally with a lower EBV prevalence, with approximately 20% to 30% of cases being positive in the tumor. Among the case series and reports previously reviewed by IARC (1997a), there were a total of 383 cases of sporadic Burkitt lymphoma, with EBV DNA or antibodies present in 192 cases. In the United States, 15% to 30% of sporadic Burkitt lymphoma cases are associated with EBV (Thompson and Kurzrock 2004). Immunodeficiency-related Burkitt lymphoma has been identified in approximately 40% of HIV-1-associated lymphomas (Gloghini et al. 2013; Stefan et al. 2011) and may also be associated with other factors resulting in immune suppression such as anti-rejection therapies or congenital immunodeficiency (Carbone et al. 2008). EBV has been detected in 30% to 64% of immunodeficiency-related Burkitt lymphoma cases (Young and Rickinson 2004).

### 3.2.2 Case-control Studies

Twelve case-control studies conducted since 1969 were identified that have investigated the association between EBV and Burkitt lymphoma. Eleven of these were included in the IARC (1997a; 2012) reviews.

Seven case-control studies of endemic Burkitt lymphoma, with a total of 904 cases, were reviewed by IARC (1997a; 2012), all showing a statistically significant, positive association between EBV and Burkitt lymphoma (Figure 3-1). These case-control studies found that those with Burkitt lymphoma were more likely to have detectible or elevated levels of EBV titers with odds ratios (ORs) ranging from 2.9 to 52 (Carpenter et al. 2008; Henle et al. 1969; Henle et al. 1971; Hirshaut et al. 1973; Klein et al. 1970; Mutalima et al. 2008). Moreover, four of the seven studies found a dose-response relationship between EBV titer levels and Burkitt lymphoma, with ORs increasing as titer levels increased (Carpenter et al. 2008; Henle et al. 1969; Henle et al. 1971; Mutalima et al. 2008). Additionally, the geometric mean titer levels of Burkitt lymphoma patients were significantly higher than controls in the three studies that reported these findings (Henle et al. 1969; Hirshaut et al. 1973; Nkrumah et al. 1976). These studies investigated a variety of EBV antibodies including viral capsid antigen (VCA) and early antigen (EA), while other studies (Henle et al. 1969; Hirshaut et al. 1973) did not specify the type of EBV antibody under study. Regardless of the type of EBV antibody investigated, a significant, positive relationship was seen between endemic Burkitt lymphoma and EBV. Figure 3-1 shows a forest plot with the ORs of the associations between endemic Burkitt lymphoma and EBV antibodies.

Figure 3-1

Forest Plot of Serological Case-control Studies of Endemic Burkitt Lymphoma and Epstein-Barr Virus

ORs in brackets ([]) were calculated by NTP; if OR could not be calculated due to a cell size of 0, 1 was added to each cell.

CI = confidence interval; EA = early antigen; OR = odds ratio; VCA = viral capsid antigen.

^a^Optical density (OD) measures were used as a surrogate measure for EBV VCA antigen.

Sources: All endemic Burkitt lymphoma studies were conducted in sub-Saharan Africa. (Henle et al. 1969) - Kenya, Uganda, Nigeria; (Klein et al. 1970) - country not specified; (Henle et al. 1971) - Uganda, Kenya; (Hirshaut et al. 1973) - Uganda; (Carpenter et al. 2008) - Uganda; (Mutalima et al. 2008) - Malawi; (Mulama et al. 2014) - Kenya. Note: One study, Nkrumah et al. (1976), reported mean levels of EBV antibodies only but not enough information to calculate an OR.

Since the publication of the second IARC review (2012), there has been one additional hospital-based case-control study in Kenya on the relationship between endemic Burkitt lymphoma and EBV. This study (Mulama et al. 2014) investigated the association between cellular EBV load and endemic Burkitt lymphoma among 89 children with confirmed Burkitt lymphoma with 213 controls frequency matched on age range and malaria exposure from the Naynza and Rift Valley provinces in Kenya. These control sites were chosen to approximate malarial exposure for cases because Naynza province has high malarial transmission rates while the Rift Valley province has low rates. Though not reported in the manuscript, based on individual case and control level data reported in the figures, children with endemic Burkitt lymphoma were statistically significantly more likely to have ≥2 log EBV copies per μg of human DNA than controls (OR = 16.2; 95% CI = 8.0 to 32.5). The results of this study are included in Figure 3-1.

Five case-control studies of sporadic Burkitt lymphoma, with a total of 113 cases, were reviewed by IARC (1997a): Ablashi et al. (1974); Cavdar et al. (1994); Gotleib-Stematsky et al. (1976); Hirshaut et al. (1973); Levine et al. (1972). Of the five studies, four investigated the relationship between Burkitt lymphoma and VCA antibodies, while one was unspecified (Hirshaut et al. 1973). Gotleib-Stematsky et al. (1976) also investigated EA antibodies in their analysis. Although four of these five case-control studies reported odds ratios of at least 2.0, only one reported a statistically significant association between the presence of EBV antibodies and Burkitt lymphoma (OR = 4; 95% CI = 1.3 to 12.0) (Levine et al. 1972). The ORs ranged from 1 to 6.9 for those with statistically non-significant findings. In contrast to endemic Burkitt lymphoma studies, many of these studies included small numbers of cases and controls and had limited statistical power. Three of the five studies found mean EBV titers to be significantly higher in cases than in controls (Ablashi et al. 1974; Cavdar et al. 1994; Levine et al. 1972), while the other two studies found no statistically significant differences in means between cases and controls (Gotleib-Stematsky et al. 1976; Hirshaut et al. 1973). These studies are presented in Figure 3-2, which shows a forest plot with the ORs of the associations between sporadic Burkitt lymphoma and EBV antibodies.

Figure 3-2

Forest Plot of Serological Case-control Studies of Sporadic Burkitt Lymphoma and Epstein-Barr Virus

CI = confidence interval, EA = early antigen, OR = odds ratio, VCA = viral capsid antigen.

Sources: Sporadic Burkitt lymphoma study locations: Levine et al. (1972) – U.S.A; Hirshaut et al. (1973) – U.S.A; Ablashi et al. (1974) – U.S.A; Gotleib-Stematsky et al. (1976) – Israel; Cavdar et al. (1994) – Turkey.

No case-control or cohort studies on immunodeficiency-related Burkitt lymphoma were reviewed by IARC (1997a; 2012) or have been published since the more recent review by IARC (2012). See HIV-1 monograph (Sections 4.2.1 and 3.3.4) for a discussion of Burkitt lymphoma risk with severe immunosuppression.

### 3.2.3 Cohort Studies

Only one cohort study has been identified that investigated the relationship between EBV and Burkitt lymphoma. This study was reviewed by IARC (1997a) and is briefly reviewed here. Beginning in 1972, a large-scale prospective study was begun in a Burkitt lymphoma-endemic area of northern Uganda, which collected blood samples from approximately 42,000 healthy children under age 8. The first follow-up of this cohort (1972 to 1977) was first presented by de Thé et al. (1978) which reported on 14 cases (13 histologically confirmed Burkitt lymphoma cases and one unclassified lymphoma), and the second follow-up of the cohort was presented by Geser et al. (1982) adding 2 additional cases to the analysis (1978 to 1979). Randomly selected controls, matched on age, gender, and location, were selected for a nested case-control analysis (de Thé et al. 1978). Statistically significantly higher titers of VCA antibodies were seen in the pre-diagnosis sera of the Burkitt lymphoma cases compared with the controls (geometric mean titer of Burkitt lymphoma cases = 425.5; control = 125.8, p = 0.01). When the additional two cases were added, the difference in VCA titers between cases and controls increased slightly (p < 0.001) (Geser et al. 1982). The mean values of EA and Epstein-Barr nuclear antigen (EBNA) in cases and matched controls were not provided; however, no statistically significant differences were seen in the titer levels for EA and EBNA antibodies between the Burkitt lymphoma cases and the matched controls. There were no differences between pre-diagnosis cases and controls in regard to malarial parasites or antibody titers to herpes simplex virus, cytomegalovirus, or measles reported by de Thé et al. (1978). A conditional regression analysis including all 16 cases was conducted by Geser et al. (1982) who found that the relative risk (RR) increased by a factor of 5.05 for each dilution for which the VCA titer is above the general population average. Moreover, the RR increased to 9.16 (95% CI not reported) when limited to cases that demonstrated the presence of EBV DNA in the tumor genome (N = 9). The results of this prospective cohort study demonstrate the temporality of the EBV/Burkitt lymphoma relationship by showing that elevated EBV antibodies, particularly VCA antibodies, precede the development and diagnosis of Burkitt lymphoma in this population.

### 3.2.4 Cofactors

Potential cofactors for endemic Burkitt lymphoma were reviewed by IARC (1997a; 2012). These cofactors include malaria, sickle-cell trait, and ingestion of Euphorbia tirucalli and other medicinal plants.

In earlier ecological studies, the geographic relationship between malaria and endemic Burkitt lymphoma was noted, with Burkitt lymphoma prevalence highest in areas with the highest malaria transmission rates (Morrow (1985) as cited in IARC (1997a)). The relationship between malaria and endemic Burkitt lymphoma was further apparent after the decline in endemic Burkitt lymphoma incidence following large-scale malaria eradication efforts. Geser et al. (1989) likewise confirmed this relationship in an intervention study designed to reduce Burkitt lymphoma incidence by reducing the prevalence of malaria. Moreover, two case-control studies published in 2008 found an increased risk of endemic Burkitt lymphoma as antibody titers to malaria increased (Carpenter et al. 2008; Mutalima et al. 2008). Based on the evidence from these studies, endemic Burkitt lymphoma is strongly associated with both EBV and with Plasmodium co-infection (IARC 2012); there may be a synergistic effect between malaria and EBV in the development of Burkitt lymphoma (Carpenter et al. 2008; Mutalima et al. 2008). There is additional evidence that malaria reduces the T-cell-mediated immunosurveillance of EBV-infected cells, leading to an increased viral load of EBV (Moormann et al. (2009), as cited in IARC (2012)).

A recent study (Mulama et al. 2014) did not find an association between sickle-cell trait and endemic Burkitt lymphoma (OR = 0.85; 95% CI = 0.61 to 1.17). Moreover, the lack of an association between sickle-cell trait genotype and EBV cellular viral load suggests that sickle-cell trait is not a cofactor in the relationship between EBV and Burkitt lymphoma.

The relationship between endemic Burkitt lymphoma and E. tirucalli and other medicinal plants is unclear, with few studies available to provide epidemiological evidence relevant to this relationship. Several case series and two case-control studies on these relationships were reviewed by IARC (1997a). Both case-control studies found a significant positive association between plant use and Burkitt lymphoma. Other studies have demonstrated that extracts of E. tirucalli and other related plants can induce the expression of EA and VCA antibodies, and increase EBV replication (Ito et al. (1981) and Lin et al. (1982), as cited in IARC (1997a)). No new studies on these relationships have been identified since the IARC (1997a) publication.

### 3.2.5 Integration of the Evidence

The epidemiological data suggest an association between EBV and both endemic and sporadic Burkitt lymphoma. All eight case-control studies and one cohort study of the relationship between endemic Burkitt lymphoma and EBV found positive, statistically significant relationships. There were five case-control studies on the relationship between sporadic Burkitt lymphoma and EBV. Although positive odds ratios ranging from 2.2 to 6.9 were seen for four of the five studies, only one OR was statistically significant. These studies on sporadic Burkitt lymphoma and EBV had limited power to detect an effect due to small numbers of cases and controls. The overall results of the individual studies are heterogeneous, particularly studies on endemic Burkitt lymphoma, for which ORs ranged from 2.9 to 52.1. One possible explanation is the variety of serological markers used by the different studies to detect EBV exposure. Another possible cause of the observed heterogeneity is the lack of variability in the exposure, particularly among cases, with up to 100% of cases exposed to EBV in some studies.

## 3.3 Cancer Evaluation: Hodgkin Lymphoma

### 3.3.1 Background Information

Hodgkin lymphoma is categorized into four histological subtypes (lymphocyte predominance, nodular sclerosis, mixed cellularity, and lymphocyte depletion). In the United States, the age-adjusted incidence rate for all types of Hodgkin lymphoma is 2.7 cases per 100,000 person-years, with a 5-year survival of 80% (SEER 2015). The relationship between EBV and Hodgkin lymphoma was first proposed in the 1960s (MacMahon 1966). Numerous case reports and case-series studies since that time have examined the association between EBV and primarily the mixed cellularity subtype, with approximately 75% of cases EBV positive; while approximately 20% of Hodgkin lymphoma cases with the nodular sclerosis subtype are EBV positive (Flavell and Murray 2000; Weiss 2000). These case reports and case series have reported that the association between EBV and Hodgkin lymphoma varies by age and geographic region. EBV-related Hodgkin lymphoma appears to be mostly highly associated with Hodgkin lymphoma incidence in middle adulthood in developed countries. In developing countries the EBV- Hodgkin lymphoma relationship shows a bimodal age distribution, with rates of EBV-related Hodgkin lymphoma highest in childhood and in older adults (Flavell and Murray 2000; Weiss 2000). EBV has been detected in 20% to 50% of Hodgkin lymphoma cases in North America and Europe, though the percentage differs by Hodgkin lymphoma subtype (Weiss 2000). EBV seropositivity in Asian Hodgkin lymphoma patients is around 65%, and 90% to 100% in South Americans and Africans. Additionally, Hodgkin lymphoma patients with HIV have a nearly 100% EBV infection rate (Weiss 2000).

EBV has been established as the cause of infectious mononucleosis, and a large body of studies has reported an increased risk of Hodgkin lymphoma among populations with infectious mononucleosis infection (Crawford 2001). Exposure to EBV later in life (after childhood) in developed countries is more likely to lead to symptomatic infectious mononucleosis infection, Thus, this timing for infection is suggested to be a risk factor for the development of Hodgkin lymphoma, particularly in younger adults (Ambinder and Cesarman (2007) and Jarrett (2003), as cited in IARC (2012)). Several case-control and cohort studies have investigated the relationship between EBV and Hodgkin lymphoma, as well as Hodgkin lymphoma and infectious mononucleosis, as described below.

### 3.3.2 Case-control Studies

Thirty-eight (38) published case-control studies were identified that investigated the relationship between Hodgkin lymphoma and EBV. All but one study was previously reviewed by IARC (1997a; 2012). These studies included a total of over 7,100 Hodgkin lymphoma cases. These studies have generally fallen into two categories: those investigating the relationship between Hodgkin lymphoma and EBV serology or EBV DNA directly, and those investigating this relationship indirectly via the association between Hodgkin lymphoma and infectious mononucleosis.

#### Hodgkin Lymphoma and EBV Serology or EBV DNA

Twenty-seven (27) of a total of 38 case-control studies on EBV and Hodgkin lymphoma were previously reviewed by IARC (1997a; 2012), with 1 new study (Linabery et al. 2014) that examined the relationship between EBV antibodies or DNA and Hodgkin lymphoma. Nineteen studies provided an OR for the relationship between Hodgkin lymphoma and EBV serology (Figure 3-3). In general, these studies investigated the association between high VCA titer levels among Hodgkin lymphoma cases and controls, with odds ratios ranging from 0.8 to 67; the majority of ORs were between 4 and 19. Findings from studies not specifying the type of EBV antibodies were consistent with the studies of specific antibodies; most studies (5/8) reported statistically significant ORs ranging from 4 to 11. Ten of the 21 total studies (on VCA or unspecified antigens) additionally analyzed the association between Hodgkin lymphoma and EA antibodies for cases and controls, with ORs ranging from 1.2 to infinity; however, when studies with no exposure variability (studies with either no unexposed cases, or no exposed controls) were excluded, the ORs ranged from 1.2 to 15. Six case-control studies also reported risk estimates (or information to calculate estimates) for elevated titers of EBNA and Hodgkin lymphoma. These included Lange et al. (1978) with an OR of 19.3 (95% CI = 5.5 to 67.6, for 15/28 exposed cases), Mochanko et al. (1979) with an OR of 5.4 (95% CI = 1.8 to 15.8, for 18/37 exposed cases), Merk et al. (1995) with an OR of 1.7 (95% CI = 0.8 to 3.6, for 16/61 exposed cases), and Berrington de Gonzalez et al. (2006)^1^ with an OR of 0.7 (95% CI = 0.3 to 1.4, for 21/83 exposed cases), and Rocchi et al. (1975), and Shope et al. (1982) reported OR of infinity (no controls had elevated titer). Three serological case-control studies did not provide enough data to calculate an odds ratio (Lennette et al. 1993; Lennette et al. 1995; Wutzler et al. 1983).^2^

1 This study did not report an OR for other antibodies.

2 This study did not report an OR for other antibodies.

Figure 3-3

Forest Plot of Serological Case-control Studies of Hodgkin Lymphoma and Epstein-Barr Virus

ORs in curly brackets ((Crawford 2001)) were calculated by IARC working group; ORs in square brackets ([]) were calculated by NTP.

CI = confidence interval; OR = odds ratio; VCA = viral capsid antigen.

^a^Exposed group – defined as any detectible EBV antibody.

^b^EBV antibody exposed group ≥160.

^c^EBV antibody exposed group ≥640.

^d^EBV antibody exposed group ≥1,280.

^e^EBV VCA antibody exposed group ≥5.

^f^EBV VCA antibody exposed group ≥160.

^g^EBV VCA antibody exposed group ≥320.

^h^EBV VCA antibody exposed group ≥1,280.

^i^Study also includes data on EA antibodies.

^j^Study also includes data on EBNA antibodies.

Source: Table 19 in IARC (1997a); Table 2.3 in IARC (2012). Note: Hilgers and Hilgers (1976) was not included.

In addition to the serology studies measuring antibody, three case-control studies reported ORs between EBV DNA in serum or lymph nodes and Hodgkin lymphoma; these studies found highly statistically significant associations, with ORs ranging from 120 to infinity; however, there was little variability in exposure (Dinand et al. 2007; Gallagher et al. 1999; Lei et al. 2000; Musacchio et al. 2006). Gallagher et al. (1999) also measured EBV DNA in serum of cases and controls, but it was not possible to calculate an OR as cases were pre-classified as EBV positive or negative.

The study by Linabery et al. (2014) examined a subset (69%) of the 517 cases of pediatric Hodgkin lymphoma for EBV RNA in the tumor. Overall, 16% (N = 84) were found to have tumors that were EBV RNA positive. This proportion increased in the younger age groups, with 23% (N = 5) of those aged 0 to 4 years and 29% (N = 36) of those aged 5 to 9 years EBV positive. EBV status among the controls was not available; therefore, no odds ratios could be calculated.

#### Hodgkin Lymphoma and Infectious Mononucleosis

Eleven of the 38 case-control studies (10 reported by IARC and 1 new study, Linabery et al. (2014)) reported on the association between infectious mononucleosis and Hodgkin lymphoma. These studies generally found a positive association between infectious mononucleosis and Hodgkin lymphoma, with ORs ranging between 0.3 and 13.1 (for subtype of Hodgkin lymphoma), with most falling between 1.3 and 2.5 (Alexander et al. 2000; Alexander et al. 2003; Bernard et al. 1987; Evans and Gutensohn 1984; Glaser et al. 2005; Gutensohn and Cole 1981; Gutensohn 1982; Henderson et al. 1979; Hjalgrim et al. 2007; Linabery et al. 2014; Serraino et al. 1991). Among these studies, six found a statistically significant association between Hodgkin lymphoma and infectious mononucleosis; Bernard et al. (1987) and Serraino et al. (1991) found significant associations in subpopulations, not reported in Figure 3-4. One study (Glaser et al. 2005) found a non-significant OR of 0.3 in a population of women, ages 19 to 79, with Hodgkin lymphoma. These studies are summarized in Figure 3-4. A number of these studies had limited statistical power to detect an effect. Additionally, studies that stratified Hodgkin lymphoma patients by age found a stronger, statistically significant association among younger adults (Bernard et al. (1987) [young adult males, OR = 4.9; p = 0.04; 95% CI not available], Alexander et al. (2000); Hjalgrim et al. (2007)).

Figure 3-4

Forest Plot of Case-control Studies of Hodgkin Lymphoma and Infectious Mononucleosis

*95% confidence interval unavailable.

CI = confidence interval; OR = odds ratio.

Two studies reported significant associations for cases with the nodular sclerosis subtype of Hodgkin lymphoma. Henderson et al. (1979) reported a non-significant OR of 1.5 (95% CI not reported), while Serraino et al. (1991) reported a statistically significant OR of 13.1 (1.0 to 176.6). The most recent study of children and adolescents (Linabery et al. 2014) reported a non-statistically significant increase in the odds of Hodgkin lymphoma among those diagnosed with infectious mononucleosis (OR = 1.5; 95% CI = 0.52 to 3.50 for 9/517 exposed cases); although power was limited by the small number of participants with a previous diagnosis of infectious mononucleosis (9 cases and 10 controls). When restricted to EBV-positive (EBV detected in the tumors) cases, they found a non-statistically significant 9-fold increase in the risk of Hodgkin lymphoma among those who had a history of infectious mononucleosis infection (OR = 9.1; 95% CI = 0.81 to 102.3 for 3/84 exposed cases).

### 3.3.3 Cohort Studies

Seven cohort studies and two nested case-control studies have investigated the association between EBV and Hodgkin lymphoma. These studies are summarized in Table 3-1. The seven cohort studies, conducted in the United States and Western Europe and published from 1973 to 2000, looked at the relationship between infectious mononucleosis (caused by EBV) and Hodgkin lymphoma. Six were reviewed in detail by IARC (1997a)—Carter et al. (1977); Connelly and Christine (1974); Kvale et al. (1979); Miller and Beebe (1973); Munoz et al. (1978); Rosdahl et al. (1974)—while one additional cohort study (Hjalgrim et al. 2000) was reviewed by IARC (2012). These studies included a total of over 80,000 participants with serologically confirmed infectious mononucleosis. A total of 83 cases of Hodgkin lymphoma were observed, with standardized incidence ratios (SIR) ranging from 2.0 to 5.0. All studies observed more cases of Hodgkin lymphoma than expected in the general population, with three of the seven studies reporting statistically significant SIRs (Hjalgrim et al. 2000; Munoz et al. 1978; Rosdahl et al. 1974) in the relationship between infectious mononucleosis and subsequent development of Hodgkin lymphoma. One study (Miller and Beebe 1973) did not find a statistically significant association, and the remaining studies (Carter et al. 1977; Connelly and Christine 1974; Kvale et al. 1979) did not report statistical significance in their risk estimates.

Table 3-1 Summary of Cohort and Nested Case-control Studies of Hodgkin Lymphoma and Epstein-Barr Virus

Reference | Age Group | RR^a^ | Comments
Infectious mononucleosis studies^b^
Miller and Beebe (1973) Connelly and Christine (1974) Rosdahl et al. (1974) Carter et al. (1977) Munoz et al. (1978) Kvale et al. (1979) Hjalgrim et al. (2000) | Adults Adults/children Adults/children Adults Adults/children Adults/children Adults/children | {2.0} {5.0} {2.8} {2.3} 4.0 {3.0}^b^ 2.6 | NS NR Lower CI > 1 NR Lower CI > 1 NR Lower CI > 1
EBV serology studies^c^
Mueller et al. (1989) Lehtinen et al. (1993) | NR Adults | VCA-IgG ≥320: 2.6 VCA-IgA ≥20: 3.7^d^ EBNA ≥80: 4.0 EA(D) ≥5: 2.6 NR | Lower CI > 1 Lower CI > 1 Lower CI > 1 Lower CI > 1 NR

Relative risks in curly brackets ({}) were calculated by the IARC Working Group (2012).

CI = 95% confidence interval; EA(D) = early antigen-diffuse; EBNA = EBV nuclear antigen; IM = infectious mononucleosis; NR = not reported; RR = relative risk; VCA = viral capsid antigen.

^a^ For IM cohort studies, RR reported is the standardized incidence ratio (SIR).

^b^ SIR at least one year from IM diagnosis.

^c^ All IM studies were cohort designs, while both serology studies were nested case-control designs.

^d^ Risk estimate was adjusted for IgM.

Two nested case-control studies investigated EBV serology prior to a Hodgkin lymphoma diagnosis (Lehtinen et al. 1993; Mueller et al. 1989). Mueller et al. (1989) analyzed 43 Hodgkin lymphoma patients and 96 matched controls from a cohort of over 235,000 participants. They found that titers to EBV antibodies (VCA IgA and EBNA) were statistically significantly increased among those with Hodgkin lymphoma, with relative risks equaling 2.7 and 2.5, respectively. Relative risks of antibody titers to VCA-IgG and EA were elevated but not significant. Additionally, they found that these associations were generally stronger in patients with a blood draw at least three years before Hodgkin lymphoma diagnosis. Lehtinen et al. (1993) conducted a similar nested case-control study among 39,000 adults with a blood draw who were followed for up to 12 years. Data for the association between Hodgkin lymphoma and EBV were not shown, but the authors reported an increased risk of antibody response to EBV among Hodgkin lymphoma patients.

### 3.3.4 Integration of the Evidence

Epidemiological data provide evidence of an association between EBV and Hodgkin lymphoma with 15 of the 22 case-control studies reporting ORs showing statistically significant associations based on serologic and DNA findings. Positive associations have been reported between EBV and Hodgkin lymphoma for both adults and young adults; however, the association between EBV and childhood Hodgkin lymphoma is unclear. Moreover, infectious mononucleosis (caused by EBV) is positively associated with Hodgkin lymphoma among adults, young adults, and children; although inconsistencies in the evidence are possibly due to the fact that few infectious mononucleosis studies provided data on EBV tumor status. The temporality of this association was seen in one nested case-control study, which reported statistically significantly elevated EBV titers prior to Hodgkin lymphoma diagnosis among cases compared with controls. The strength of the observed associations varied between studies with both indirect EBV exposure measurement (infectious mononucleosis studies), and with direct EBV measurement (serological and tumor DNA studies). ORs are generally higher in the serological studies compared to the infectious mononucleosis studies, and ORs in case-control studies using tumor DNA to detect EBV exposure were highest. The heterogeneity seen in the serology and tumor DNA case-control studies may partly be explained by differential sensitivity and specificity of these exposure markers. One serology case-control study (Gotlieb-Stematsky et al. 1975) had only one exposed control, while two of the four EBV DNA studies had no exposed controls, and a third had only one exposed control.

## 3.4 Cancer Evaluation: Immunosuppression-related Non-Hodgkin Lymphoma

### 3.4.1 Background Information

Three types of immunosuppression-related non-Hodgkin lymphoma have been reported in the EBV literature and were reviewed by IARC (1997a; 2012). These lymphomas occur with severe immunosuppression and are observed with post-transplant lymphoproliferative disorders (PTLD), HIV-1-associated lymphoproliferative disorders, and congenital immunodeficiencies. PTLD is a complication of both solid organ transplant and hematopoietic stem cell transplant and is one of the most common post-transplant malignancies. The incidence of PTLD varies by type of transplant, but is generally more common in children than adults, with incidence rates ranging from <1% to 13% in children and between 1% and 8% in adults (Garfin et al. 2015). The 5-year survival rate for adults and children is approximately 60% (Hauke et al. 2001). EBV has been associated with up to 50% to 70% of PTLD cases (Al-Mansour et al. 2013; Jimenez 2015).

HIV-1-lymphoproliferative disorder is a common type of non-Hodgkin lymphoma among those diagnosed with HIV-1. Non-Hodgkin lymphoma is designated a defining acquired immune deficiency syndrome (AIDS) condition. Those with HIV-1 are 70 times more likely to be diagnosed with non-Hodgkin lymphoma (Grulich et al. 2007b) while the 5-year survival rates of those with HIV-1-related non-Hodgkin lymphoma is low, at approximately 5% (Chow et al. 2001). HIV-1-associated lymphoproliferative disorder is discussed in further detail in the HIV-1 monograph (see Sections 3.3.1 and 3.3.4 of the HIV-1 monograph, NTP (2016)). EBV is present in the tumor cells in almost all cases of HIV-1-related primary central nervous system non-Hodgkin lymphoma, and in approximately 50% of HIV-1-related diffuse large cell and immunoblastic non-Hodgkin lymphoma (Grulich et al. 2007a).

### 3.4.2 Studies and Evaluation

IARC reported more than 20 case-series studies relating EBV to immunosuppression and non-Hodgkin lymphoma. Detection methods for EBV (such as DNA, in situ hybridization for EBV RNA, expression of LMP) varied. In nine case-series reports (totaling 142 cases) of HIV-1-associated primary central nervous system non-Hodgkin lymphoma, EBV was found in all cases in five studies and in the majority of cases in the remaining four studies (Table 14 in IARC (1997a)). In situ hybridization studies found that EBV RNA was found in most or all of the tumor cells whereas expression of LMP was more variable. EBV was also found in HIV-1-associated systemic non-Hodgkin lymphoma (Table 15 in IARC (1997a)). Sixteen studies identified EBV in some of the cases. In the cases positive for EBV, the number of EBV-positive cells in the tumor varied from 25% to 100%. Importantly, EBV was found to be monoclonal by terminal-repeat sequence analysis in four of these studies. In addition, seven studies investigated the presence of EBV in lymphomas from patients with congenital primary immune deficiency and all of the cases were positive for EBV (Table 16 in IARC (1997a)).

Only one case-control study has been identified that investigated the association between EBV and immunosuppression-related non-Hodgkin lymphoma. This study included cases with several types of lymphoma, including both Hodgkin and non-Hodgkin lymphomas. This study included 13 total cases of different cancer types, including two cases of PTLD and 35 healthy controls in Hong Kong (Lei et al. 2000). Plasma EBV DNA was detected in both PTLD cases, suggesting activated EBV; however, EBV plasma DNA was not detected in any of the controls.

One nested case-control study and no cohort studies were identified in which EBV titers were measured in immunosuppressed populations. In a U.K.-based nested case-control study, 67 HIV-1-positive, non-Hodgkin lymphoma patients participated in a trial of antiretroviral therapy with 67 matched controls (Newton et al. 2006). Controls were randomly selected from the trial participants among those who had not developed cancer after the same period of follow-up, and matched by trial, age group, sex, HIV-1 transmission group, treatment group, and ethnicity. Among cases, a statistically non-significant association between the risk of disease for a doubling of VCA-IgG antibodies to EBV was observed compared to controls (adjusted OR = 1.5, 95% CI = 0.9 to 2.3).

### 3.4.3 Integration of the Evidence

Severe immunosuppression from congenital, iatrogenic, or HIV-1/AIDS can result in EBV-associated non-Hodgkin lymphomas. Epidemiological data primarily from case studies provide consistent evidence of an association between EBV positive non-Hodgkin lymphoma and congenital immunodeficiencies. In HIV-1 patients almost all non-Hodgkin lymphomas of the central nervous system and a large number of systemic non-Hodgkin lymphomas are EBV related. There were some reports of monoclonality of the virus within the tumor, although all cells within the tumor were not positive for the activated virus. Further, EBV has been shown to be associated with over half of PTLD cases. The strength of these studies varied with detection method used, as some studies used a method that would detect EBV, but not necessarily an activated form of the virus.

## 3.5 Cancer Evaluation: Extranodal NK/T-cell Lymphoma, Nasal Type

Extranodal NK/T-cell lymphoma, nasal type is a rare type of non-Hodgkin lymphoma (also known as sinonasal angiocentric T-cell lymphoma). NK/T-cell lymphoma and NK/T-cell proliferative disease most often occur in adults, are more common in males than females, are most prevalent in Asia, South America, Central America, and Mexico, and represent 7% to 40% of all non-Hodgkin lymphomas, with a 5-year survival near 50% (Chan et al. 2001; Lee et al. 2006; Suwiwat et al. 2007).

NK/T-cell lymphoma is almost universally associated with EBV in tumor cells, irrespective of the ethnic origin of the patients; however, nasal type NK/T-cell lymphomas presenting in other organ locations have been most strongly associated with EBV in Asian patients (Chan et al. 2001; IARC 2012). In recent case-series studies in Asia and South America, the presence of EBV DNA has been identified in nearly 100% of nasal type NK/T-cell lymphoma tumor cells (Barrionuevo et al. 2007; He et al. 2007). Overall, more than 400 EBV-associated NK/T-cell lymphoma cases have been identified including both these studies and studies identified by IARC (1997a) (see Table 11, sinonasal angiocentric T-cell lymphoma). No cofactors have been identified.

Two case-control studies (which included 10 cases) found a positive association between EBV DNA in plasma and/or CD3^+^ (T) Cells and extranodal NK/T-cell lymphoma, nasal type. However, the temporal relationship between EBV and nasal extranodal NK/T-cell lymphoma has not been established. These studies are reviewed in Table 3-2.

Table 3-2 Summary of Case-comparison Studies of NK/T-Cell Lymphoma, Nasal Type and Epstein-Barr Virus

Reference | Exposure Category | OR | Exposed Cases: Exposed Controls
Lei et al. (2000) (Hong Kong) | EBV plasma DNA | ∞ | 4/4: 0/35
Suwiwat et al. (2007) (Thailand) | EBV plasma DNA CD3^+^ Cells CD3^−^ Cells | ∞ ∞ ∞ | 6/6: 0/45 6/6: 0/45 6/6 cases; 19/45

## 3.6 Cancer Evaluation: Nasopharyngeal Carcinoma

### 3.6.1 Background Information

Nasopharyngeal carcinoma is the predominant type of cancer in the nasopharynx. It is a rare cancer in most parts of the world. In the United States, incidence ranges from 0.5 to 2 per 100,000, with a 5-year survival of 36% to over 60% (Lee and Ko 2005). However, in areas like Southeast Asia, the Arctic, North Africa, and the Middle East, incidence rates can be much higher, ranging from 2.7 per 100,000 to 26 per 100,000 (Chin et al. 2015; Ferlay et al. 2015; Yu and Yuan 2002). Additionally, nasopharyngeal carcinoma is much more common in males than females throughout the world (Chang and Adami 2006; Chin et al. 2015). Nasopharyngeal carcinomas are classified into three types: keratinizing squamous-cell carcinoma, non-keratinizing carcinoma, and basaloid squamous-cell carcinoma (Chan et al. (2005), as cited in IARC (2012)). Nasopharyngeal carcinoma is associated with EBV, especially in EBV-endemic populations, with nearly universal EBV seropositivity among cases (Adham et al. 2012).

### 3.6.2 Case-control Studies

Fifteen (15) case-control studies (1976 to 2014) have been identified that investigated the association between nasopharyngeal carcinoma and EBV. These 15 studies include over 1,900 cases of nasopharyngeal carcinoma, conducted primarily in Southeast Asia, although several studies included cases from Europe (Chan et al. 1991; Lennette et al. 1993), North Africa (de Thé et al. 1978), and the United States (Chan et al. 1991; Lanier et al. 1980; Pearson et al. 1983). These studies may be divided into those that investigated the relationship between nasopharyngeal carcinoma and EBV serology, and those that investigated EBV DNA in the tumor.

Eleven (11) of the 15 case-control studies on the association between nasopharyngeal carcinoma and EBV were serological studies. Using a variety of serological markers and tumor DNA analyses, the majority of these studies generally found a strong and statistically significant association between nasopharyngeal carcinoma and EBV. These studies are summarized in Figure 3-5. The ORs ranged from 21 to ∞, although when studies with no exposure variability, i.e., studies with no non-exposed cases or no exposed controls, were removed, the ORs ranged from 21 to 138 and were all statistically significant. Three studies did not provide enough information to calculate ORs; however, the geometric mean titers of anti-EBV antibodies were statistically significantly higher in cases than in controls (de Thé et al. 1978; Hilgers and Hilgers 1976; Lennette et al. 1995). Another study, Tiwawech et al. (2008) reported on 75 nasopharyngeal carcinoma cases in Thailand and 44 matched controls. They found all cases and controls were exposed to EBNA-2 and LMP-1; however, they found the LMP-1 deletion type subtype to be more common in cases than in controls (OR = 2.5; 95% CI = 1.1 to 5.8). The six case-control studies of EBV DNA in nasopharyngeal carcinoma tumors reported statistically significant increases in EBV DNA with ORs ranging from 86 to ∞, or 86 to 820 when studies with no exposure variability are removed.

Figure 3-5

Forest Plot of Serological Case-control Studies of Nasopharyngeal Carcinoma and Epstein-Barr Virus

CI = confidence interval; EA = early antigen; EBNA = EBV nuclear antigen; IgG/A/M = immunoglobulin G/A/M; OR = odds ratio; VCA = viral capsid antigen.

^a^ORs or RRs and 95% CIs in curly brackets ({}) were calculated by IARC (1997a; 2012) working groups; ORs or RRs and 95% CIs in square brackets ([]) were calculated by NTP.

Source: Table 25 in IARC (1997a); Tables 2.6 and 2.7 in IARC (2012); except Chan et al. (1991); Chen et al. (1987); Lanier et al. (1980); Lennette et al. (1993).

### 3.6.3 Cohort Studies

Two nested case-control studies and two cohort studies were identified that investigated the association between nasopharyngeal carcinoma and EBV. The two nested case-control studies included a total of 14 nasopharyngeal carcinoma cases; one was a study of 7 cases among Alaska Natives (Lanier et al. 1980) and the other among a general population in the United States (Chan et al. 1991). Both investigated whether EBV antibodies were present prior to a nasopharyngeal carcinoma diagnosis, with follow-up times ranging from 1 to 12 years. Neither study found a statistically significant relationship between EBV antibodies prior to diagnosis and nasopharyngeal carcinoma. The two prospective cohort studies (Chien et al. 2001; Ji et al. 2007) had over 51,000 participants and a total of 168 cases of nasopharyngeal carcinoma, with follow-up times up to 16 years. Both studies reported statistically significant associations and nasopharyngeal carcinoma incidence between those designated seropositive and seronegative at baseline, with relative risks of 22 (95% CI = 7.3 to 66.9) for Ji et al. (2007) and 9.4 (95% CI = 6.7 to 13.3) for Chien et al. (2001). Chien et al. (2001) also found a statistically significant relationship between EBV DNase antibodies and nasopharyngeal carcinoma with a relative risk of 3.5 (95% CI = 1.4 to 8.7). These studies are summarized in Figure 3-5.

### 3.6.4 Cofactors

Two potential cofactors in the association between EBV and nasopharyngeal carcinoma were reviewed by IARC (1997a): dietary factors (such as Cantonese-style salted fish, other preserved foods, and deficits of fruits and vegetables), and genetic factors. These cofactors are reviewed briefly here. See IARC (1997a) for an in-depth review.

No new studies on dietary factors as cofactors in the association between EBV and nasopharyngeal carcinoma have been identified since the previous IARC reviews (1997a; 2012). Earlier case-control studies found the consumption of Cantonese-style salted fish, particularly during childhood, to be associated with a diagnosis of nasopharyngeal carcinoma, with ORs ranging from 1.5 to 38; these were generally statistically significant (Armstrong and Armstrong 1983; Geser et al. 1978; Henderson and Louie 1978; Ning et al. 1990; Sriamporn et al. 1992; Yu et al. 1986; Yu et al. 1989; Yu et al. 1988; Zheng et al. 1994a; Zheng et al. 1994b). Those studies that did not find a statistically significant association did not include childhood consumption in their analysis (Chen et al. 1988; Lee et al. 1994). Other types of salted fish were not significantly associated with nasopharyngeal carcinoma; however, other preserved foods, particularly salted foods, were associated with nasopharyngeal carcinoma in several case-control studies, with ORs ranging from 1.2 to 8.6. The results of studies investigating the relationship between deficits of fresh fruits and vegetables and nasopharyngeal carcinoma were mixed, some finding no association and others finding statistically significantly lower levels of certain vitamins among nasopharyngeal carcinoma patients. Although none of the studies specifically evaluated the relationship between EBV and dietary factors, they might be potential cofactors as mechanistic studies (reviewed by IARC (1997a)) found that Cantonese-style salted fish, along with other preservatives, contained substances capable of activating EBV in latently infected cells (Poirier et al. (1989) and Shao et al. (1988), as cited in IARC (1997a)).

Genetic factors have also been suggested as cofactors for nasopharyngeal carcinoma, with multiple susceptible genetic loci identified. EBV interacts with the host-cell genes implicated in nasopharyngeal carcinoma development, influencing cell signaling and host gene regulation, and predisposing the cell for nasopharyngeal carcinoma (Aldred and Eng (2006), as cited in Lung et al. (2014)). No epidemiological studies on the associations between nasopharyngeal carcinoma, EBV, and genetic factors have been identified; however, five new studies since 2008 have demonstrated that genetic variation in certain genes is associated with the risk of nasopharyngeal carcinoma. Two of these studies (Chin et al. 2015; Zhao et al. 2012) found increased susceptibility for nasopharyngeal carcinoma associated with the HLA-A locus in Chinese cases of nasopharyngeal carcinoma. This is consistent with previous research that has found an increased risk of nasopharyngeal carcinoma associated with the HLA-A and HLA-B loci among Chinese populations. These previous studies were reviewed by IARC (1997a), along with studies in non-Chinese populations. Two new case-control studies investigated the association between nasopharyngeal carcinoma and the genes for the cytokines interleukin-2 (Wei et al. 2010) and interleukin-18 (Nong et al. 2009) among Chinese populations. Significant differences were found between the genotypes and allele frequencies of these cytokines between cases and controls in both studies. Moumad et al. (2013) studied 492 nasopharyngeal carcinoma patients in North Africa and found significant associations between nasopharyngeal carcinoma and polymorphisms of genes for pattern recognition receptors (Toll-like receptor TLR3, C-type lectin receptor CD209, retinoic acid-inducible gen I-like receptor [DDX58]).

### 3.6.5 Integration of the Evidence

The epidemiological data, primarily a large body of case-control studies, consistently report statistically significant, positive associations between EBV seropositivity and nasopharyngeal carcinoma. A number of these studies were conducted among populations with a high prevalence of nasopharyngeal carcinoma. ORs of 20 or higher were seen for most case-control studies, using both serological and tumor DNA EBV detection methods. Two cohort studies have also shown positive associations between EBV seropositivity and nasopharyngeal carcinoma incidence, and demonstrated the temporality of the relationship, with EBV seropositivity preceding development and diagnosis of nasopharyngeal carcinoma. Long follow-up times between study enrollment (when EBV seropositivity is determined) and diagnosis may lead to some misclassification; those developing EBV seropositivity after enrollment but before diagnosis would be misclassified as seronegative. Two cofactors, dietary factors and genetic factors, have been suggested to have an influence on the relationship between EBV and nasopharyngeal carcinoma.

## 3.7 Cancer Evaluation: Gastric Cancer

### 3.7.1 Background Information on Gastric Cancer

Gastric cancer is one of the most common cancers worldwide, with 7.5 cases per 100,000 people diagnosed each year in the United States. The 5-year survival rate for gastric cancer is 20% or less (Crew and Neugut 2006). Epstein-Barr virus was first detected (via polymerase chain reaction) in a patient with gastric cancer in 1990 (Burke et al. 1990).

### 3.7.2 Case-series Analyses and Pooled Analyses

EBV-related gastric cancer is defined as detection of EBV in the gastric cancer tumor, through a variety of detection methods, such as in situ hybridization or polymerase chain reaction. A case series of 138 U.S. patients (Shibata and Weiss (1992), as cited in IARC (1997a)) found the prevalence of EBV-related gastric cancer to be 16%. In a systematic review of 47 case series and case-control studies, Chen et al. (2015) found EBV DNA in 5% to 18% of gastric cancer cases when detected by in situ hybridization. A pooled analysis of case reports and case series found the global prevalence of EBV-related gastric cancer to be around 8.3% to 8.7% (Murphy et al. 2009; Sousa et al. 2008). These analyses also found the highest prevalence of EBV-related gastric cancer in North and South America (13%) and the lowest in Southeast Asia (7.8%) (Sousa et al. 2008). Additionally, in their meta-analysis based on 15,952 cases of gastric cancer worldwide, Murphy et al. (2009) noted a twofold difference in EBV-related gastric cancer by sex, with a prevalence of 11.1% in males and 5.2% in females. Pooling studies with various EBV detection methodologies, this meta-analysis also identified differences in EBV-related gastric cancer prevalence based on anatomic location of the gastric cancer tumor. Tumors originating in the gastric cardia or corpus (body) were twice as likely to be EBV positive compared with tumors in the pyloric antrum. Moreover, EBV prevalence was 4 times higher for tumors arising in postsurgical gastric stump/remnants compared to the pooled prevalence of EBV positivity. Additionally, over 90% of lymphoepithelioma-like carcinomas of the stomach were EBV positive.

### 3.7.3 Case-control Studies and Case-case Analyses

There have been three case-control studies and one case-case comparison study published that investigated the association between EBV and gastric cancer (de Aquino et al. 2012; Lo et al. 2001; Shinkura et al. 2000) (Table 3-3). Among the three case-control studies, there were a total of 77 EBV-positive gastric cancer cases out of 184 total gastric cancer cases. Two of these studies were reviewed by IARC (2012). In a population of 123 gastric cancer cases (64 cases with EBV-positive tumors) and 73 healthy controls in Japan, Shinkura et al. (2000) calculated the EBV seroprevalence of cases compared with controls. Cases were 7.1 (95% CI = 2.4 to 25.6) times more likely to be VCA-IgA positive and 19.9 (95% CI = 6.6 to 70) times more likely to be EA-IgG positive than healthy controls (ORs calculated by IARC working group, available in IARC (2012), Table 2.9). The authors also conducted a case-case comparison between patients with EBV-positive and EBV-negative tumors and found the geometric mean of EBV VCA-IgG (p < 0.001), EBV VCA-IgA (p = 0.006), and EA-IgG (p < 0.001) to be significantly higher among EBV-positive cases compared to EBV-negative cases; however, there was no difference in EBNA antibodies. EBV-positive cases were 3.4 (95% CI = 1.3 to 8.8) and 6.6 (95% CI = 2.7 to 16.3) times more likely to be seropositive for VCA-IgA and EA-IgG, respectively, compared to EBV-negative cases. It is noteworthy that cases with EBV-negative tumors were 4.9 times more likely to be seropositive for EA-IgG than healthy controls, and the geometric mean titer of VCA-IgG was significantly higher for EBV-negative cases than in healthy controls.

Table 3-3 Summary of Case-control Studies of Gastric Cancer and Epstein-Barr Virus

Reference | OR | Comments
Case-control Studies
Shinkura et al. (2000) | VCA-IgA: {7.1}^a^ EA-IgG: {19.9}^a^ | Lower 95% CI > 1.0 Lower 95% CI > 1.0
Lo et al. (2001) | EBV DNA (EBV+ tumor): ∞ EBV DNA (EBV− tumor, EBV+ lymphocytes): {352.9} | 5/5 EBER+ cases EBV DNA+, 13/14 EBER− cases EBV DNA+, 7/197 controls EBV DNA+ Lower CI > 1.0
de Aquino et al. (2012) | EBV DNA: ∞ | 8/10 cases EBV+, 0/6 control EBV+

CI = confidence interval; EA = early antigen; IgG/A = immunoglobulin G/A; OR = odds ratio; VCA = viral capsid antigen.

^a^ ORs in curly brackets ({}) were calculated by the IARC Working Group (2012).

Lo et al. (2001) investigated serum EBV DNA in 51 gastric cancer cases (5 patients EBV-encoded small RNA [EBER]-positive, 14 EBER-negative but with occasional infiltrating lymphocytes that were EBER-positive, and 32 with no evidence of EBV) in Hong Kong compared with 197 healthy controls. They found that EBV DNA was detectable in all EBV-encoded small RNA (EBER)-positive cases (5/5), in all but one EBER-negative case with occasional infiltrating lymphocytes (13/14), and 0/32 EBV-negative cases, compared to 3.6% of healthy controls.

One new case-control study has been published since 2008 that investigated the prevalence of EBV DNA in the tumors of 10 gastric cancer patients in Brazil compared to a convenience sample of biopsies from 6 cancer-free control subjects obtained during endoscopies (de Aquino et al. 2012). EBV DNA, detected by polymerase chain reaction, was present in 8 of 10 gastric cancer cases and in none of the control subjects.

Boysen et al. (2011) conducted a nationwide case-case comparison study in Denmark that included 18 EBER-positive EBV gastric cancer cases out of 186 total gastric cancer cases, both with and without pernicious anemia. In comparison with gastric cancer patients without pernicious anemia, gastric cancer patients with pernicious anemia (N = 8) were 2.5 (95% CI = 0.88 to 7.14) times more likely to be EBV positive when adjusting for gender, age at diagnosis, and year of diagnosis; when further adjusted for lymphocytic infiltration, those with pernicious anemia were 2.9 (95% CI = 0.99 to 8.67) times more likely to be EBV positive.

### 3.7.4 Nested Case-control Studies

Levine et al. (1995) examined serum samples collected and banked prior to the diagnosis of 54 (14 EBV-positive and 40 EBV-negative) cases of gastric adenocarcinoma patients of Japanese ancestry selected from the Honolulu Heart Cohort study, along with 54 controls matched on age and date of blood collection. This study found a non-statistically significant increased risk between EBV seropositivity and subsequent development of gastric adenocarcinoma, as well as significantly elevated geometric mean titers of VCA or of EBNA in EBV-associated cases compared to controls (Table 3-4).

Table 3-4 Summary of Nested Case-control Studies of Gastric Cancer and Epstein-Barr Virus

Reference | OR | Comments
Levine et al. (1995) | VCA-IgG: 1.4 VCA-IgA: 3.9 EBNA: 0.72 EA(D): 1.2 EA(R): 1.9 VCA-IgG (mean) EBNA (mean) | NS; high (1,280+) versus low (≤640) titers NS; high (20+) versus low (≤20) titers NS; high (640+) versus low (≤320) titers NS; high (5+) versus low (≤5) titers NS; high (5+) versus low (≤5) titers p < 0.05; EBV-associated cases versus controls p < 0.05; EBV-associated cases versus non-EBV-associated tumors
Koshiol et al. (2007) | EBNA: 0.46^a^ VCA-IgA: 0.69 EA-D IgG: 0.95 EA-R IgG: 0.52 High EBNA: 0.91 | Upper CI < 1. Survival among individuals with high vs. low EBNA. Seropositivity and development of gastric cancer. All non-significant.
Kim et al. (2009) | EBNA IgG: 0.90 | NS; OR of gastric cancer risk of highest titer levels compared to lowest. NS; OR of gastric cancer risk of highest titer levels compared to lowest.

CI = confidence interval; EA = early antigen; EA-D = early antigen-diffuse; EA-R = early antigen-restricted; EBNA = EBV nuclear antigen; IgG/A = immunoglobulin G/A; NS = not statistically significant; OR = odds ratio; RR = relative risk; VCA = viral capsid antigen.

^a^ Hazard Ratio reported.

In another nested case-control study (Koshiol et al. 2007) among 185 cases of gastric cancer and 200 controls in China, EBV seropositivity prior to diagnosis was found to be unrelated to the incidence of gastric cancer (ORs less than 1). Follow-up time between enrollment and diagnosis was as long as 15 years. The study also found no difference in EBV seropositivity between cardia and non-cardia gastric cancer cases (see Table 3-4). However, this study did find that cardia gastric cancer cases with high baseline EBNA IgG titers (prior to diagnosis) had longer survival (hazard ratio = 0.46, 95% CI = 0.29 to 0.74) than either cardia gastric cancer cases with low baseline EBNA titers or all non-cardia gastric cancer cases. No interpretation for this finding was given.

In a third nested case-control study based in South Korea, Kim et al. (2009) studied 100 incident gastric cancer cases from a cohort of 14,000 participants in a multicenter cohort with 200 controls matched on year of enrollment, age, gender, and area of residence. Follow-up time between enrollment and gastric cancer diagnosis ranged from 0 to 9 years. The OR between EBV antibody levels prior to diagnosis and subsequent risk of gastric cancer, including among patients, was 1.37 (95% CI = 0.62 to 3.06) with the highest titers of VCA-IgG and 0.87 (95% CI = 0.51 to 1.46) for EBNA IgG. However, no dose-response relationship was observed (Table 3-4).

### 3.7.5 Cofactors

Currently, there are no identified cofactors for the association between EBV and gastric cancer.

### 3.7.6 Integration of the Evidence

The data from the three case-control studies suggest a positive association between EBV and gastric cancer, although two of those studies reported little exposure variability. In one study, all cases were EBV positive while in another there were no exposed controls. This lack of variability may account for heterogeneity seen in the results. In the three nested case-control studies, EBV titer levels prior to diagnosis were not significantly associated with an increased risk of gastric cancer; nevertheless, two studies found non-significant associations for VCA and EA antigens (Kim et al. 2009; Levine et al. 1995). None of the prospective studies typed the tumor DNA for EBV; therefore, it is unknown if those with EBV seropositivity prior to diagnosis were true EBV-positive gastric cancer cases. Also, follow-up times were long between enrollment and diagnosis for some cases resulting in non-differential exposure misclassification. Those who developed EBV seropositivity between enrollment and diagnosis would not have been counted as EBV-positive and thus would bias the findings toward the null.

## 3.8 Cancer Evaluation: Lymphoepithelial Carcinoma of the Salivary Gland

Lymphoepithelial carcinoma of the salivary gland is a rare carcinoma that accounts for less than 1% of all head and neck cancers and is histologically similar to nasopharyngeal carcinoma (Tsai et al. 1996; Tsang and Chan 2005). Based on the five case reports and case series published between 1982 and 1996 reviewed by IARC (1997a) 25 out of 27 total salivary gland lymphoepithelial carcinoma cases tested positive for EBV in tumor cells (IARC 1997a). Additional case-series studies of lymphoepithelial carcinoma of the parotid gland were reported in the later IARC (2012) review with 208 of 209 cases of parotid gland lymphoepithelial carcinoma reporting EBV DNA in the tumor. These EBV-positive cases of lymphoepithelial carcinoma of the salivary gland are predominantly of Eskimo/Inuit, Greenlandic, or Chinese (mainly southern) populations, which have higher incidences of nasopharyngeal carcinoma (Saku et al. 2003; Wang et al. 2004). Of the few reported cases of lymphoepithelial carcinoma of the salivary gland identified outside these geographical locations, EBV has not been consistently detected (Bialas et al. 2002; Saqui-Salces et al. 2006; Zhan et al. 2016).

### 3.8.1 Case-case Study

Only one case-case study of salivary gland lymphoepithelial carcinoma has been identified in the published literature. Wang et al. (2004) compared 16 cases of salivary gland lymphoepithelial carcinoma to 12 cases of other types of salivary gland tumors in Taiwan between 1977 and 2001. EBV DNA was present in the tumors of all 16 salivary gland lymphoepithelial carcinoma cases and in none of the other types of salivary gland tumors. Cases of lymphoepithelial carcinoma (all of which were EBV positive) had a better prognosis than cases of other tumor types. The lymphoepithelial carcinoma patients had a 5-year survival rate of 86% with treatment. Patients with other salivary gland tumor types who underwent treatment had a 5-year survival of only 36%.

### 3.8.2 Cofactors

No cofactors have been identified.

### 3.8.3 Integration of the Evidence

No case-control, cohort, or nested case-control studies have been identified on the association between EBV and lymphoepithelial carcinoma of the salivary gland. Thus, notwithstanding the evidence of a positive association between EBV and salivary gland lymphoepithelial carcinoma in several case reports and case series, there is insufficient epidemiological evidence to evaluate this endpoint.

## 3.9 Synthesis across Cancer Endpoints

A summary of the evidence for EBV infection and the different cancer endpoints from epidemiological studies is provided in Table 3-5. The level of evidence from cancer studies in humans also considers studies of tissues from humans in addition to epidemiological studies and is provided in Section 5.

Table 3-5 Summary of EBV Cancer Endpoints and Strength of the Epidemiological Evidence

Cancer Endpoint | Strength of Evidence
Burkitt lymphoma (endemic) (sporadic) | • Consistent evidence across multiple studies. All epidemiological studies report significant associations. • Elevated pre-diagnosis titers seen to one EBV antigen (VCA) in one prospective study. • Dose-response relationships observed in several studies. • Generally elevated, but non-significant ORs. One study found a significant association. • No prospective studies identified.
Hodgkin lymphoma | • Evidence of an association between EBV and Hodgkin lymphoma in 15 of the 22 case-control studies reporting statistically significant ORs. • EBV DNA studies show a very strong association with tumor DNA. • One EBV serology nested case-control study shows temporal relationship. • Evidence for an association between infectious mononucleosis and Hodgkin lymphoma is less clear.
Immunosuppression-related NHL | • Case series indicate EBV is consistently found in cases of immunosuppression-related non-Hodgkin lymphoma. • Two epidemiological studies, one prospective, found evidence of an association, though not statistically significant.
Extranodal NK/T-cell lymphoma, nasal type | • Consistent association of nasal NK/T-cell lymphoma with EBV in tumor cells in case series; over 400 cases. • Two case-comparison studies found EBV DNA in the plasma or CD3+ (T cells) cells from cases but not from controls.
Nasopharyngeal carcinoma | • Consistent evidence of a strong association between EBV and NPC. Most ORs were 20 or higher. All case-control ORs were significant. • Two cohort studies showed a temporal association between EBV and NPC.
Gastric cancer | • Three case-control studies found strong associations with both EBV serology and DNA. • Elevated but non-statistically significant increased risks were found in two of three serological nested case-control studies.
LEC of the salivary gland | • No case-control or cohort studies of LEC of the salivary gland available although a case-case study found EBV DNA in salivary gland lymphoepithelial carcinoma tumors but not other type of salivary gland tumors; EBV DNA detected in tumors among over 200 cases of parotid salivary gland lymphoepithelial carcinoma in Asian or Eskimo populations in several case-series or case reports. • No epidemiological studies were available for review.

LEC = lymphoepithelial carcinoma; NHL = non-Hodgkin lymphoma; NPC = nasopharyngeal carcinoma.