# 2 Human Exposure

This section discusses transmission and prevalence (Section 2.1) and non-cancer diseases, prevention, and treatment for Epstein-Barr virus (EBV) (Section 2.2). The material presented in Sections 2.1 and 2.2 is summarized in Section 2.3.

## 2.1 Transmission and Prevalence

Transmission of EBV is primarily via saliva, although the primary infection does not occur in the salivary glands (IARC 2012). The presence of EBV in peripheral blood suggests that transmission via blood is also possible, and transmission among transfusion recipients and organ recipients has been reported. Infected cells, primarily resting memory B cells in peripheral blood, provide a permanent reservoir for progeny to disseminate within the body and infect other hosts. EBV transmission via breast milk (Daud et al. 2015) and genital secretions (Thomas et al. 2006) has also been reported.

More than 90% of adults worldwide are infected with EBV (IARC 2012). Age at primary infection varies, occurring during infancy in developing countries and during adolescence and young adulthood in developed countries, perhaps due to better hygienic conditions, and other socioeconomic and demographic factors (e.g., household size and population density), which result in later age of exposure to infected saliva (Dowd et al. 2013; IARC 2012). The two major types of EBV (EBV-1 and EBV-2) (see Section 1) differ in geographic distribution (IARC 2012). Immunocompromised subjects more often harbor both types; EBV-2 may be more common in Africa and in men who have sex with men.

The seroprevalence of EBV antibody in the United States based on NHANES data collected in 2009 and 2010 ranged from 50% in 6-to-8-year-olds to 89% in 18-to-19-year-olds (Balfour et al. 2013; Dowd et al. 2013). Lower prevalence of EBV antibody has been shown to be associated with higher socioeconomic status within race/ethnicity groups. An analysis of 782 serum samples from Minnesota children 18 months to 19.9 years old indicated that a combination of genetics, family practices, and home environment were responsible for racial/ethnic differences in EBV antibody prevalence among young children and noted that the route of EBV transmission to preadolescents remains unclear (Condon et al. 2014). The risk for infectious mononucleosis and Hodgkin lymphoma (see Section 3.3) in younger age groups resulting from infection with EBV has been suggested to be greater in people with a higher socioeconomic background (ACS 2015b; Gutensohn 1982). One theory proposed for this relationship is that exposure to EBV later in life for children from more affluent families might somehow increase their risk for these diseases.

## 2.2 Non-cancer Diseases, Prevention, Treatment

Most individuals who are infected with EBV remain otherwise healthy and are asymptomatic (IARC 2012). Infection is life-long and is subclinical when it occurs in early childhood (IARC 2012); however, it results in infectious mononucleosis in at least 25% of teenagers and young adults infected with EBV (CDC 2014b). Oral hairy leukoplakia results from infection with EBV in the context of immunosuppression (e.g., human immunodeficiency virus type 1 [HIV-1]) or immunosenescence (aging) (Auwaerter 2015). Chronic uncontrolled EBV (with high EBV DNA in blood) very rarely occurs in the United States and Europe, and is more frequent but still uncommon in Asia and South America (Cohen 2009; Maia and Peace-Brewer 2000). Its etiology is unknown, but is believed to involve environmental cofactors and/or rare genetic abnormalities that impair immune control of EBV infection (Cohen 2009).

Because EBV transmission is associated with EBV shedding in saliva, avoiding salivary exposure (e.g., not kissing or sharing drinks, food, or personal items like toothbrushes with people who have EBV infection) may theoretically prevent transmission (CDC 2014a).

Some drugs have been reported to reduce or inhibit EBV shedding (e.g., see Auwaerter 2015); currently, the FDA has not approved any drugs for treatment of EBV infection. Currently, there is no vaccine against EBV; efforts to develop a vaccine are ongoing (ACS 2015a; Balfour 2014; CDC 2011; Cohen 2015; FDA 2015).

## 2.3 Summary

The high seroprevalence rate for Epstein-Barr virus (EBV) in the U.S. population indicates that a significant number of people living in the United States are exposed to EBV. Estimates for the seroprevalence of EBV in the United States range from 50% for 6-to-8-year-olds to 89% for 18-to-19-year-olds, based on detection of the EBV antibody; however, these levels vary based on socioeconomic status and within race/ethnicity groups. EBV is transmitted primarily via saliva, but transmission via blood is possible since EBV is present in peripheral blood and transmission among transfusion recipients and organ recipients has been reported. The infection rate worldwide is very high, likely exceeding 90%, but the age at primary infection varies geographically, with more developed countries having higher ages for primary infection due to better hygiene. EBV infections tend to be asymptomatic for most individuals, but the infection is life-long and results in infectious mononucleosis in at least 25% of teenagers and young adults infected with EBV. Prevention of transmission of EBV can theoretically be achieved by limiting exposure to saliva from kissing or sharing drinks, food, or personal items like toothbrushes between infected and non-infected individuals. There is currently no vaccine against EBV, although efforts to develop a vaccine are ongoing.