# 1 Properties and Detection Methods

This section reviews the biological properties (Section 1.1) and methods for detection (Section 1.2) of the Epstein-Barr virus (EBV). The material presented in Sections 1.1 and 1.2 is summarized in Section 1.3.

## 1.1 Biological Properties

The following section reviews the types of EBV, its structure, life cycle, and course of infection.

### 1.1.1 Family and Type

EBV is a human herpesvirus in the gammaherpesvirus subfamily and is the prototype of the Lymphocryptovirus genus (IARC 2012). The formal designation of EBV is human herpesvirus 4 (HHV-4). EBV was the first human tumor virus to be discovered and was detected in Burkitt lymphoma cells in 1964. The two major types of EBV (EBV-1 and EBV-2) differ in their gene sequences of nuclear antigens (EBNA-2, -3A, -3B). Different viral strains within the two major types are created by DNA polymorphisms at other DNA sites.

### 1.1.2 Viral Structure and Genome

The Epstein-Barr virus is composed of a nucleocapsid surrounded by an envelope with glycoprotein spikes protruding from its outer surface; the nucleocapsid and envelope are separated by tegument proteins (Figure 1-1) (IARC 2012). Inside the nucleocapsid is a double stranded DNA (dsDNA) genome approximately 172 kb in length, wrapped around a protein core. The genome encodes over 85 genes; the open reading frames (ORFs) are divided into latent and lytic genes. ORF nomenclature is based on the BamHI restriction fragment in which they are found. The genome has a series of 0.5 kb terminal direct repeats at each end as well as internal repeat sequences dividing the genome into long and short unique sequences that have most of the coding capacity. EBV forms multiple episomes within the cell nucleus that are circularized by joining their terminal repeats. Latent EBV infections of clonal origin have the same number of terminal repeats. The following section will discuss how EBV uses different combinations of latent viral gene expression to progress from initial infection to long-term persistence within the memory B-cell pool. Latent EBV proteins have a primary role in EBV-associated oncogenesis and are discussed in Section 4.2.

Figure 1-1

Epstein-Barr Virus Structure

Source: Provided by Wikipedia (2015).

### 1.1.3 Infection and Replication

Like other herpes viruses, the EBV replication cycle in B lymphocytes, also called B cells, and epithelial cells includes a latent phase and a lytic phase, corresponding to a quiescent infection and active replication, respectively. Humans are the only natural host for EBV (IARC 2012). Latent infection is divided into several phases based on the viral genes that are expressed (latency 0, I, II, and III) (Table 1-1).

Table 1-1 EBV Transcription Programs in Normal B Cells and in Associated Malignancies

Transcription Program^a^ | Gene Products | Function in Normal B-cell Type^b^ | Associated Malignancies
Latency 0 | EBERs | Resting peripheral memory B cells; lifetime infection | None
Latency I | EBNA-1, EBERs | Dividing peripheral memory B cells | Burkitt lymphoma and gastric carcinoma^c^
Latency II | EBNA-1, LMP-1, LMP-2A, EBERs | Activated B-cell differentiates into memory cell in germinal center | NPC, Hodgkin lymphoma, NK and T-cell lymphoma, nasal type^d^
Latency III | EBNA-1, -2, -3A, -3B, -3C, -LP, LMP-1, LMP-2A, LMP-2B, EBERs | Naïve B-cell infected and activated | Immunosuppression-related NHL (AIDS-associated, post-transplant disorder, iatrogenic)
Lytic | Immediate-early, early, and late gene products^e^ | Replicates in plasma cell | May be present in some malignancies^f^

Source: Adapted from IARC (2012); Yau et al. (2014).

EBER = EBV-encoded small RNA; EBNA = EBV nuclear antigen; EBNA-LP = EBV nuclear antigen leader protein; LMP = latent membrane protein; LEC = lymphoepithelial cancer; NHL = non-Hodgkin lymphoma; NPC = nasopharyngeal carcinoma.

^a^ In latency I, II, III microRNAs (at least 22) are expressed in various amounts.

^b^ Cell types are primarily restricted to lymphoid tissue of Waldeyer ring (i.e., tonsillar tissue in the oropharynx).

^c^ Variable expression of EBNA-2, LMP-1, and BZLF1 (lytic gene) in endemic Burkitt lymphoma (Niedobitek et al. 1995); and of lytic genes and LMP-2A in gastric carcinoma.

^d^ Previously called sinonasal angiocentric T-cell lymphoma.

^e^ Products of immediate-early genes: BZLF1, BRLF1, BI’LF4; early genes: BMRF1, BALF2, BALF5, BORF2, BARF1, BXLF1, BGLF5, BSLF1, BBLF4, BKRF3; late genes: BLLF1, BXLF2, BKRF2, BZLF2, BALF4, BDLF3, BILF2, BCRF1, BHRF1.

^f^ EBV lytic genes expressed in human lymphoblastoid cell lines (Arvey et al. 2012).

In a primary infection, EBV spreads through the saliva and infects the B cells in the tonsil, and oropharyngeal epithelial mucosa by a poorly understood mechanism (IARC 2012; Raab-Traub et al. 1991). Within the oropharyngeal epithelium the infection is primarily lytic (it is unknown whether epithelial cells support latent infection) leading to amplification of the number of viruses. Within the tonsil, EBV infects local naïve B lymphocytes entering the germinal center in the underlying lymphoid tissues by interaction of the viral envelope protein gp350/220 with the CD21 protein on B lymphocytes. Viral entry into B cells requires a complex of viral glycoproteins gH, gL, and gp42 with gp42 binding to class II human leukocyte antigen on the lymphocyte (IARC 2012; Tugizov et al. 2003). Virions containing only the gH-gL complex can infect epithelial cells while virions require the gH-gL-gp42 complex to infect naïve B cells (Tugizov et al. 2003). Inside the B lymphocytes, the virus enters the latency III phase where replication is suppressed by the expression of three EBV nuclear antigens (EBNA-3A, -3B, and -3C). The B lymphocytes then can enter a germinal center in the tonsils and, in the immunocompetent host, are destroyed by cytotoxic T cells specific for viral proteins expressed during latency III (Thorley-Lawson and Gross 2004).

Germinal centers are structures in the lymphoid tissues where antibody affinity maturation occurs through clonal proliferation of antigen-exposed B lymphocytes, diversification of antigen affinity through somatic hypermutation of immunoglobulin genes, and of antibody type through class switch recombination (Ponce et al. 2014). While in the germinal center, the EBV infection enters latency II, a phase in which gene expression is focused on survival signals. Within the germinal center, lymphocytes differentiate to memory B cells and antibody-producing plasma cells, both of which enter the peripheral circulation. Within resting B memory cells, the EBV infection is in the latency 0 phase, no genes are expressed with the exception of those coding for EBV-encoded small RNAs (EBER-1 and -2). Occasionally, memory B cells will replicate and EBV will enter latency I, where expression of EBV nuclear antigen 1 (EBNA1) allows for replication and segregation of the viral episome to daughter cells. B cells that are activated and differentiate into antibody-producing plasma cells allow EBV to express lytic genes and enter the lytic cycle of replication. Lytic genes comprise 3 immediate-early genes that initiate the lytic cycle, 10 early genes that enable virus replication, and 9 genes that enable packaging and release of the virion from the host cell (see IARC (2012) for discussion of lytic genes). Complete viral lytic replication does not occur in tissues other than mucosa-associated lymphoid tissue (MALT) and tonsillar tissue in the oropharynx (termed Waldeyer’s ring). In these tissues lytic replication occurs along with cell death and shedding of virions into the saliva or re-infection of B lymphocytes repeating the cycle (Figure 1-2). While the EBV infection is in the latent I, II, or III phase, EBV-specific cytotoxic T cells and NK cells are able to recognize the expressed viral proteins and limit the infection; within resting memory B cells (latency 0 phase), the virus is able to evade immune detection and provide a site for maintenance of long-term EBV infection (Thorley-Lawson and Gross 2004).

Figure 1-2

Epstein-Barr Virus Life Cycle

Source: Vetsika and Callan (2004), used with permission.

Although EBV usually infects B lymphocytes through a CD21-dependent pathway, it also can infect some types of epithelial cells and T cells by several CD21-independent pathways (IARC 2012). Primary epithelial cells in culture can be infected with EBV only by co-culturing with EBV-producing B lymphoblastoid cells, suggesting that cell-to-cell contact is necessary for infection of epithelial cells (Imai et al. 1998). It has been demonstrated that viral envelope proteins (gH-gL) can interact with an integrin complex on the epithelial cell surface, triggering cell entry, and that gp42 interferes with binding to the integrin complex (Borza and Hutt-Fletcher 2002; Chesnokova and Hutt-Fletcher 2011). Additionally, virions released from epithelial cells express gp42 on their surface, whereas those released from lymphocytes do not have this protein marker. It is believed that this dual cell tropism enables the virus to shuttle between lymphocytes and epithelial cells. Other research using polarized basal epithelial cells identified another EBV glycoprotein, BMRF2, which enabled infection via interaction with epithelial cell marker α5β1 (Tugizov et al. 2003). Further, they showed that EBV virions could also be transmitted by direct cell-to-cell contact of B lymphocytes to apical epithelial cell membranes, and epithelial cell-to-cell infection could occur via lateral membrane transmission.

During latency, the virus can express a variable pattern of viral genes that are essential for host adaptation and in some cases also promote carcinogenesis or disease; different EBV latent gene expression patterns are associated with different types of cancers (Table 1-1) (IARC 2012). The role of latent and lytic EBV genes in the pathogenesis of cancer is an active area of investigation. In order to understand the contribution of viral and host factors in development of lymphomas, humanized mouse models using transplanted human fetal hematopoietic stem cells and lymphoid tissue are under development (Cocco et al. 2008; Ma et al. 2011).

## 1.2 Detection

EBV-specific serologic methods or amplification of EBV DNA from peripheral white blood cells can be used to detect EBV infection in healthy carriers (Table 1-2). In developed countries, healthy carriers are negative for EBV DNA in serum (cell-free) by the quantitative polymerase chain reaction (Q-PCR) method (IARC 2012). A positive result using the latter method indicates EBV-associated diseases or EBV reactivation. EBV infection results in production of IgG, IgM, and occasionally IgA antibodies against viral proteins and glycoproteins (e.g., viral capsid antigen [VCA] or EBNA-1). These can be detected using antigen-antibody binding assays such as enzyme immunoassays (EIA) to determine antibody titer.

Table 1-2 Methods of EBV Detection

Biomarker | Detection Method | Examples | Tissue
Antibodies to VCA, EBNA-1, CF/S antigens, neutralizing anti-gp350, EA | Serologic, indirect IFA, EIA | Detected in healthy EBV carriers, EA detected in some carriers; higher titers with Burkitt lymphoma | Serum
EBV DNA | PCR | Detection in healthy carriers | White blood cells
Cell-free EBV DNA | Quantitative PCR | EBV-associated diseases or EBV reactivation; healthy carriers are negative | Serum
EBV DNA | Quantitative PCR | Determination of viral load per cell | Tumor cells, white blood cells
EBER-1, EBER-2 RNAs | Reverse transcription-PCR and in situ hybridization | EBV infection; highly sensitive for Hodgkin disease detection | Tumor cells, tissue biopsy
EBNA-1 and BARF1 RNA | Reverse transcription-PCR | NPC detection | NPC biopsy or brushing

Source: Adapted from IARC (2012).

BARF1 = BamHI A rightward fragment 1 (micro RNA); BL = Burkitt lymphoma; CF/S = complement-fixing soluble antigen; EA = early antigens (EA-D encoded by BMRF-1 and EA-R encoded by BHRF-1); EBER = small nuclear EBV-encoded RNA; EBNA = EBV nuclear antigen; EIA = enzyme immunoassay; gp350 = glycoprotein 350; IFA = indirect immunofluorescence assay; LMP-1 = Latent membrane protein; NPC = nasopharyngeal carcinoma; PCR = polymerase chain reaction; VCA = viral capsid antigen.

Detection methods are also used to determine EBV viral load, reactivation, response to treatment, and presence in tumor cells (IARC 2012). In general, high antibody titers to some EBV antigens (e.g., VCA) are detected in patients with endemic Burkitt lymphoma. Historically, early markers used for detection of EBV in Burkitt lymphoma were antibodies to early antigen (EA) and VCA. Determination of viral load can give an indication of the degree of infection or of response to treatment and can be determined in tumor cells or in lymphocytes by Q-PCR. For example, nasopharyngeal carcinoma brushings from patients can be used to determine viral load by Q-PCR, and reverse transcriptase PCR can detect EBNA-1 or BARF1 RNA in nasopharyngeal cells in these samples. In contrast, no EBV RNA is found in healthy donors. In addition, in situ hybridization and RT-PCR are highly sensitive methods for EBV detection in Hodgkin disease.

## 1.3 Summary

Epstein-Barr virus (EBV), also called human herpesvirus 4 (HHV-4), is an enveloped dsDNA virus in the gammaherpesvirus subfamily and consists of two major types (EBV-1, and EBV-2). Like other herpes viruses, the EBV replication cycle in B lymphocytes, also called B cells, and epithelial cells includes a latent phase and a lytic phase, corresponding to a quiescent infection and active replication, respectively. Humans are the only natural host for EBV. Infection of epithelial cells is primarily lytic, which results in destruction of the infected cell with completion of the lytic cycle, whereas infection of B cells is primarily latent. Antibody-producing B cells, also known as plasma cells, allow EBV to enter the lytic phase and replicate (Ponce et al. 2014). EBV predominantly enters the host through contact with saliva and infects B cells in the tonsils. The virus circularizes upon infection of B cells and persists as an episome. During lytic replication, large DNA concatemers are formed. The latent phase is complex and changes depending on the status of the host cells (latency 0, I, II, III). EBV proteins expressed on infected cells can be recognized by cytotoxic T cells and NK cells, which attack and destroy them. However, EBV in latency 0 phase, typically found in resting memory B cells, does not express proteins on infected cells, which enables it to evade immune recognition. EBV infection can be detected by measuring anti-EBV antibodies in serum and EBV DNA or RNA in peripheral white blood cells, which can indicate viral load.