# Abbreviations

  AIDS: acquired immune deficiency syndrome
  AKT: serine/threonine kinase Akt (also known as protein kinase B or PKB)
  BARF1: BamHI A rightward fragment 1 (micro RNA)
  BL: Burkitt lymphoma
  CDC: Centers for Disease Control and Prevention
  CF/S: complement-fixing soluble antigen
  CI: confidence interval
  CNS: central nervous system
  DNA: deoxyribonucleic acid
  EA: early antigen
  EA(D): early antigen-diffuse
  EBER: EBV-encoded small RNA
  EBNA: EBV nuclear antigen
  EBNA-LP: EBV nuclear antigen leader protein
  EBV: Epstein-Barr virus
  EIA: enzyme immunoassays
  GC: germinal center
  HHV4: human herpesvirus 4
  HIV: human immunodeficiency virus
  IARC: International Agency for Research on Cancer
  HLA: human leukocyte antigen
  IFA: indirect immunofluorescence assay
  IgA: immunoglobulin A
  IgG: immunoglobulin G
  IgM: immunoglobulin M
  LEC: lymphoepithelial cancer
  LMP: latent membrane protein
  LMP-1: latent membrane protein 1
  LMP-2: latent membrane protein 2
  LMP-2B: latent membrane protein 2B
  MALT: mucosa-associated lymphoid tissue
  NHL: non-Hodgkin lymphoma
  NPC: nasopharyngeal carcinoma
  NHANES: National Health and Nutrition Examination Survey
  NR: not reported
  NS: not statistically significant
  NTP: National Toxicology Program
  OD: optical density
  OR: odds ratio
  ORF: open reading frames
  PCR: polymerase chain reaction
  PI3K: phosphatidylinositol-4,5-bisphosphate 3-kinase
  PTEN: phosphatase and tensin homologue
  PTLD: post-transplant lymphoproliferative disorders
  Q-PCR: quantitative polymerase chain reaction
  RNA: ribonucleic acid
  RR: relative risk
  RT-PCR: reverse transcriptase-polymerase chain reaction
  SCNA: somatic copy-number aberrations
  SEER: Surveillance, Epidemiology, and End Results Program
  SIR: standardized incidence ratios
  USA: United States of America
  VCA: viral caspid anigen